# Executive Summary

## Introduction

Since the 1980s, stimulant use has wreaked havoc on individuals and communities across the United States and has prompted strong responses from federal, state, and local governments and organizations. For example, the relatively minor problems caused by cocaine use in the 1960s and 1970s have grown to become major medical and law enforcement issues.

Similarly, the increasing use of methamphetamine (MA) has led policymakers, public officials, and service providers to increase efforts to fight its spread. For example, concerns that MA use would become epidemic led to passage of the Combat Methamphetamine Epidemic Act of 2005 and the incorporation of MA-specific provisions in the Comprehensive Addiction and Recovery Act of 2016. Misuse of prescription stimulants such as methylphenidate has also become a growing concern.

The explosive growth of stimulant use has also triggered a flurry of research. The results are tremendous advances in understanding stimulant use disorders, the basic functioning of the brain, and substance use disorders (SUDs) in general. Yet reports that describe the fundamentals of stimulant use disorder treatment and the success of various treatment interventions are still needed.

This Treatment Improvement Protocol (TIP) reviews what is currently known about treating the medical, psychiatric, and SUD-related problems associated with the use of cocaine and MA and the misuse of prescribed stimulants (such as those for the treatment of attention deficit hyperactivity disorder [ADHD]).

The scientifically based information in this TIP is presented in a manner that makes it accessible and relevant to behavioral health service clinicians and other frontline SUD treatment providers, including healthcare service providers (e.g., in primary care settings, in emergency departments). The TIP offers recommendations on treatment approaches, strategies for planning and initiating treatment, recommendations on how to maximize treatment engagement and retention, and strategies for initiating and maintaining abstinence. Also included are recommendations for the medical management of people who use stimulants and recommendations regarding special populations and settings.

The Substance Abuse and Mental Health Services Administration (SAMHSA) first published this TIP in 1999. SAMHSA implemented a full-scale review and revision of the original TIP. Content now addresses:

• Recent research on stimulant use disorders.
• The increasing number of overdose deaths in the United States attributable to cocaine and MA (especially when combined with other substances, like synthetic and semisynthetic opioids).
• The rise in the use and misuse of prescription stimulants (leading to increased risk and incidence of diversion).

This TIP revision:

• Uses terminology that is person centered and aligned with language in the latest edition of the Diagnostic and Statistical Manual of Mental Disorders.
• Incorporates findings from research published since 2010 (and where possible, since 2016).
• Includes key messages at the beginning of every chapter to guide readers in understanding from the outset the core content they are about to read.
• Updates statistics and related information about stimulant use, treatment, overdose, and legislation in the United States.
• Provides a more focused discussion of the neurobiology of stimulant use disorders than the original TIP's broad primer on the topic.
• Reflects updated empirical evidence that supports using contingency management (CM), cognitive–behavioral therapy (CBT), community reinforcement, and motivational interviewing (MI) to treat stimulant use disorders—as well as recent evidence for other nonpharmacologic treatments with some support (like exercise and mindfulness techniques).
• Includes no discussion of pharmacotherapy options, given that all prescribing for stimulant use disorders is done off label (that is, no Food and Drug Administration [FDA]-approved medication for any stimulant use disorder currently exists).
• Expands the discussion of special populations with unique treatment needs to cover racial/ethnic minorities, women (including those who are pregnant), men who have sex with men (MSM), transgender and gender nonbinary community members, adolescents, people experiencing homelessness/unstable housing, rural populations, people involved with the criminal justice system, people taking opioid use disorder medication, people who inject drugs, people with or at risk for HIV/AIDS, people with or at risk for hepatitis, and individuals with co-occurring mental disorders.

The purpose of this TIP is to advance the understanding of treating the SUDs associated with the use of cocaine and MA and the misuse of prescription stimulants. This TIP is organized to guide behavioral health service providers, healthcare service providers, and other addiction and allied professionals sequentially through the primary components of proper identification and management of stimulant use disorders. The TIP is divided into seven chapters so that readers can easily find the material they need most. Below is a summary of the TIP's main points and brief summaries of the first six chapters. (The seventh chapter is a listing of resources.)

## Overall Key Messages

Stimulant use disorders are a growing problem in the United States, with more than 5 million people age 12 and older reporting past-year cocaine use, nearly 2 million reporting MA use, and almost 5 million reporting prescription stimulant misuse in 2019. Stimulant-related overdose fatalities are also on the rise, with the incidence of stimulant-related deaths more than tripling between 2010 and 2017.

Stimulant use disorders have a powerful neurobiological basis that includes changes in brain chemistry and functioning that in turn help drive stimulant use behaviors. But stimulant use disorders also have a social and environmental component that clinicians need to consider in trying to understand patients' stimulant use behaviors, difficulties in achieving and maintaining abstinence, and potential unwillingness to engage in formal SUD treatment.

Healthcare providers need to understand the medical complications of stimulant use, their clinical signs and symptoms, and appropriate management approaches. Behavioral health service providers should learn to recognize the medical complications of stimulant use so they can make quick and successful referrals to medical treatment as needed.

Ample research supports the use of CM as the primary psychosocial treatment for stimulant use disorders. The lack of FDA-approved pharmacotherapies for stimulant use disorders makes it vital for clinicians to learn about and offer psychosocial interventions (e.g., CM, CBT) and other nonpharmacologic services that have empirical support (e.g., mindfulness practices, family/couples counseling, the Matrix model of treatment).

Clinicians should consider a variety of factors in assessing why people with stimulant use disorders have sought treatment and what their individual treatment needs are. Clinicians can make treatment engagement—as well as treatment completion—more likely by maximizing access; addressing treatment ambivalence; training staff on how to provide respectful, patient-centered services; developing a well-thought-out treatment plan; and using techniques that help patients initiate and maintain abstinence.

Certain populations may be at an increased risk for stimulant use or, once they start using stimulants, may be at higher risk for negative outcomes (like contracting HIV). Such populations—including women, people living in rural areas, people of diverse racial/ethnic backgrounds, MSM, and people experiencing homelessness/housing instability—may benefit from targeted treatment engagement techniques, interventions, and monitoring approaches that are tailored to their unique needs and challenges.

## Content Overview

This TIP is divided into seven chapters designed to thoroughly cover all relevant aspects of stimulant use disorders.

### Chapter 1: Introduction

This chapter provides a broad introduction to stimulant use disorders and trends in stimulant use in the United States. The chapter also describes the goals and scope of the TIP as well as its intended audiences.

In Chapter 1, readers will learn about:

• Current rates of stimulant use disorders and overdose in the United States, including overdose involving the combination of stimulants with synthetic opioids (e.g., fentanyl) or semisynthetic opioids (e.g., heroin).
• Recent trends that are making stimulant use more lethal, such as the use of stimulants in combination with opioids or the increasing purity and decreasing price of cocaine and MA.
• The ongoing unmet treatment needs of people with stimulant use disorders, as well as the need for efforts to improve treatment retention.
• Rates of prescription stimulant misuse and how prescribers can help combat diversion.
• Legislation and regulations relevant to patients with stimulant use disorders and behavioral health and healthcare service providers who work with them.

### Chapter 2: How Stimulants Affect the Brain and Behavior

This chapter reviews the ways in which brain structures, functions, and neurochemistry are altered in the presence of stimulants. The chapter also looks at the role of these alterations in the development and persistence of a stimulant use disorder.

In Chapter 2, readers will learn that:

• Neurological reinforcement systems (i.e., the reward system, the stress system) and other brain structures and mechanisms underlie the occurrence of stimulant use disorders and influence key aspects of stimulant use disorders, like craving and memory dysfunction.
• Brain imaging technology has played an important role in helping researchers and clinicians understand the ways in which short- and long-term stimulant use can affect the brain.
• Stimulants alter the dopamine system in ways that can affect substance use. For instance, increased feelings of pleasure and euphoria when using a stimulant can reinforce its use.
• Providers should be aware of the specific medical and psychological acute and chronic effects of each of the three main types of stimulants generally used by individuals with stimulant use disorders: cocaine, MA, and prescription stimulant medication, such as methylphenidate for ADHD.

### Chapter 3: Medical Aspects of Stimulant Use Disorders

This chapter describes medical and psychological signs, symptoms, and complications associated with stimulant use and stimulant use disorders and how to best manage common complications.

In Chapter 3, readers will learn that:

• The signs, symptoms, and harmful effects of stimulant use will vary depending on route of administration, dose, drug purity, level of intoxication, experience of withdrawal, chronicity, use history, and more.
• Medical complications of stimulant use can be serious and in some cases life threatening; these complications include cardiovascular disease, respiratory effects, cerebrovascular dysfunction, muscular and renal toxicity, gastrointestinal complaints, infections (including HIV), and hepatitis.
• Psychological complications include psychosis, aggression, and violence.
• People with stimulant use disorders often grapple with co-occurring disorders and conditions that can complicate diagnosis, treatment, and recovery. These disorders and conditions are secondary substance use (especially co-occurring opioid use), specific mental disorders (e.g., depression, anxiety, ADHD), medical conditions (e.g., dental problems, vein and nerve damage in the arm, cardiovascular disorders), and traumatic injury (e.g., due to violence/physical altercations).
• Patients' psychological reactions to stimulant use, like psychosis and violent behaviors, can also result in self-harm or harm to others if not managed properly.
• Coordinated care between medical and SUD treatment programs is a major aspect of properly identifying and treating co-occurring disorders and conditions of people with stimulant use disorders. Many patients will first appear for treatment or services in non-SUD settings—mainly primary care clinics and emergency departments.

### Chapter 4: Approaches to Treatment

This chapter describes the best supported nonpharmacologic approaches to helping patients begin and sustain recovery from stimulant use disorders.

In Chapter 4, readers will learn that:

• There are no FDA-approved medications for managing stimulant use disorders. This makes understanding available nonpharmacologic treatment options imperative.
• CM is by far the psychosocial treatment with the greatest scientific support. In some studies, CM is even more effective when used in combination with other psychosocial treatments, like community reinforcement.
• After CM, the three other psychosocial interventions with the most support are CBT, community reinforcement, and MI.
• Other forms of psychosocial treatment with less but still some support are the Matrix model, behavioral family or couples therapy, and case management/coordinated care.
• There is growing evidence that physical exercise, mindfulness, and transmagnetic cranial stimulation also may help people with stimulant use disorders reduce their stimulant use or otherwise improve their health and well-being.
• Not all people with stimulant use disorders will be interested in formal SUD treatment. Offering harm reduction tools and strategies is critical because they can help people who continue to use stimulants stay alive. Harm reduction involves providing access to or information about:
  – Needle/syringe exchanges.
  – Fentanyl test strips (to determine whether drugs have been laced with fentanyl).
  – The opioid overdose reversal agent naloxone.
  – HIV prevention education.
• Rather than using a cookie-cutter approach to treatment selection (e.g., sending all patients to 60-day residential treatment), clinicians should consider each individual's unique SUD history and treatment needs and preferences. The American Society of Addiction Medicine's patient placement criteria can help guide the treatment selection process.

### Chapter 5: Practical Application of Treatment Strategies

This chapter briefly summarizes techniques clinicians can use to help engage patients in SUD treatment and maximize their chances of sustaining long-term recovery.

In Chapter 5, readers will learn that:

• People seek treatment for any number of reasons, and clinicians will better understand how to help their patients engage and stay in treatment if they know why their patients are entering treatment.
• Factors that can make treatment engagement more likely include:
  – Identifying barriers to treatment engagement.
  – Making treatment highly accessible.
  – Providing support for treatment participation.
  – Offering multiple treatment options.
  – Discussing with patients their expectations for treatment and any ambivalence they may have about treatment.
  – Working collaboratively with patients to develop a clear, flexible treatment framework.
• Staff should be educated about how to provide person-centered, respectful, empathic services, which can help encourage patients to stay engaged in treatment.
• To start treatment off “on the right foot,” clinicians should work with patients to set their treatment goals, fully assess their clinical needs, discuss reducing or discontinuing all substance use, and help them manage stimulant withdrawal symptoms.
• Treatment retention is critical. Simply put, people are less likely to die when in treatment than when not in treatment. Any amount of time people with stimulant use disorders remain in treatment is an opportunity for them to stay alive and improve their health.
• Many strategies can help patients maintain progress in recovery, such as teaching functional analysis of stimulant use; reinforcing positive behaviors with incentives; teaching strategies to avoid high-risk situations; offering relapse prevention techniques; and promoting connections to family, friends, and the community.
• Other services that can help patients maintain recovery are vocational counseling, social skills training, relationship counseling, mutual-help support programs, and wellness counseling. Clinicians should offer referrals for these services as needed.

### Chapter 6: Treatment Considerations for Special Populations

This chapter discusses numerous populations that may be at increased risk for developing a stimulant use disorder or for experiencing negative outcomes associated with stimulant use (e.g., contracting HIV or hepatitis) and prescription stimulant misuse. These populations may require tailored assessment, treatments, or education to meet their unique needs and circumstances.

In Chapter 6, readers will learn that:

• Vulnerable populations are people of diverse racial/ethnic backgrounds, women (including those who are pregnant), MSM, transgender and gender nonbinary communities, adolescents, people experiencing homelessness/unstable housing, rural populations, people involved in the criminal justice system, people taking medication for opioid use disorder, people who inject drugs, people with or at risk for HIV/AIDS and hepatitis, and individuals with co-occurring mental disorders.
• Populations that experience health disparities related to systems of care and engagement in care may have higher rates of stimulant use disorder and increased issues accessing care for stimulant use disorders. They may also be more likely to experience secondary negative consequences related to these vulnerabilities (e.g., trauma or communicable diseases).
• By understanding the needs, SUD care access issues, and treatment considerations of these populations, clinicians will be more likely to provide patient-centered, effective care that maximizes rapport and treatment engagement.
• Services can be tailored to each of these populations to account for their unique risk factors, patterns of use, and health considerations. Clinicians may need to seek guidance from experts in these populations when tailoring treatment.