# Bibliography

Abdul-Karim, R., Ryan, C., Rangel, C., & Emmett, M. (2013). Levamisole-induced vasculitis. Baylor University Medical Center Proceedings, 26(2), 163–165.23543977
Abdul-Khabir, W., Hall, T., Swanson, A. N., & Shoptaw, S. (2014). Intimate partner violence and reproductive health among methamphetamine-using women in Los Angeles: A qualitative pilot study. Journal of Psychoactive Drugs, 46(4), 310–316.25188701
Abdul-Quader, A. S., Feelemyer, J., Modi, S., Stein, E. S., Briceno, A., Semaan, S., … Des Jarlais, D. C. (2013). Effectiveness of structural-level needle/syringe programs to reduce HCV and HIV infection among people who inject drugs: A systematic review. AIDS and Behavior, 17(9), 2878–2892.23975473
A.D.A.M. Medical Encyclopedia (2021). Rhabdomyolysis. Retrieved May 17, 2021, from https://medlineplus.gov/ency/article/000473.htm
Admon, L. K., Bart, G., Kozhimannil, K. B., Richardson, C. R., Dalton, V. K., & Winkelman, T. (2019). Amphetamine- and opioid-affected births: Incidence, outcomes, and costs, United States, 2004–2015. American Journal of Public Health, 109(1), 148–154.30496001
Agrawal, P. R., Scarabelli, T. M., Saravolatz, L., Kini, A., Jalota, A., Chen-Scarabelli, C., … Halperin, J. L. (2015). Current strategies in the evaluation and management of cocaine-induced chest pain. Cardiology in Review, 23(6), 303–311.25580707
Aharonovich, E., Hasin, D. S., Nunes, E. V., Stohl, M., Cannizzaro, D., Sarvet, A., … Genece, K. G. (2018). Modified cognitive behavioral therapy (M-CBT) for cocaine dependence: Development of treatment for cognitively impaired users and results from a Stage 1 trial. Psychology of Addictive Behaviors, 32(7), 800–811.30346186
Ahmad, S. I., Owens, E. B., & Hinshaw, S. P. (2019). Little evidence for late-onset ADHD in a longitudinal sample of women. Journal of Consulting and Clinical Psychology, 87(1), 112–117.30570306
Akwe, J. A. (2017). Pulmonary effects of cocaine use. Journal of Lung, Pulmonary, and Respiratory Research, 4(2), 54–58.
Alexander, P. D., Gicas, K. M., Willi, T. S., Kim, C. N., Boyeva, V., Procyshyn, R. M., … Barr, A. M. (2017). A comparison of psychotic symptoms in subjects with methamphetamine versus cocaine dependence. Psychopharmacology, 234(9–10), 1535–1547.28190084
Ali, M. M., Nye, E., & West, K. (2020). Substance use disorder treatment, perceived need for treatment, and barriers to treatment among parenting women with substance use disorder in US rural counties. Journal of Rural Health. Advance online publication. 10.1111/jrh.12488
Allain, F., Minogianis, E.-A., Roberts, D. C. S., & Samaha, A.-N. (2015). How fast and how often: The pharmacokinetics of drug use are decisive in addiction. Neuroscience and Biobehavioral Reviews, 56, 166–179.26116543
Al-Tayyib, A., Koester, S., Langegger, S., & Raville, L. (2017). Heroin and methamphetamine injection: An emerging drug use pattern. Substance Use and Misuse, 52(8), 1051–1058.28323507
American College of Obstetricians and Gynecologists Committee on Health Care for Underserved Women (2011). Committee Opinion No. 479: Methamphetamine abuse in women of reproductive age. Obstetrics and Gynecology, 117(3), 751–755.21343793
American Psychiatric Association (2000). Diagnostic and statistical manual of mental disorders (4th ed., text rev.).
American Psychiatric Association (2013). Diagnostic and statistical manual of mental disorders (5th ed.).
American Psychological Association (2008). Sexual orientation & homosexuality. https://www.apa.org/topics/lgbt/orientation
American Psychological Association (2009). Report of the APA Task Force on Appropriate Therapeutic Responses to Sexual Orientation. https://www.apa.org/pi/lgbt/resources/sexual-orientation
American Psychological Association (2015). Guidelines for psychological practice with transgender and gender nonconforming people. American Psychologist, 70(9), 832–864.
American Society of Addiction Medicine (2015a). The ASAM national practice guideline for the use of medications in the treatment of addiction involving opioid use.
American Society of Addiction Medicine. (2015b, May 13). What are the ASAM levels of care? https://www.asamcontinuum.org/knowledgebase/what-are-the-asam-levels-of-care
American Society of Addiction Medicine (2020). The ASAM national practice guideline for the treatment of opioid use disorder: 2020 focused update. Journal of Addiction Medicine, 14(2S), 1–91.
Anbalagan, S., & Mendez, M. D. (2021). Neonatal abstinence syndrome. In StatPearls. https://www.ncbi.nlm.nih.gov/books/NBK551498/
Andermann, A. (2016). Taking action on the social determinants of health in clinical practice: A framework for health professionals. CMAJ, 188(17–18), E474–E483.27503870
Anderson, J. E., Brown, I. E., Olson, K. A., Iverson, K., Cocanour, C. S., & Galante, J. M. (2018). Nonocclusive mesenteric ischemia in patients with methamphetamine use. Journal of Trauma and Acute Care Surgery, 84(6), 885–892.
Anderson, J. L., Adams, C. D., Antman, E. M., Bridges, C. R., Califf, R. M., Casey, Jr., D. E., … Riegel, B. (2007). ACC/AHA 2007 guidelines for the management of patients with unstable angina/non–ST-elevation myocardial infarction: A report of the American College of Cardiology/American Heart Association Task Force on practice guidelines. Journal of the American College of Cardiology, 50(7), e1–e157.17692738
Anderson, K. N., Ailes, E. C., Danielson, M., Lind, J. N., Farr, S. L., Broussard, C. S., & Tinker, S. C. (2018). Attention-deficit/hyperactivity disorder medication prescription claims among privately insured women aged 15–44 years—United States, 2003–2015. Morbidity and Mortality Weekly Report, 67(2), 66–70.29346342
Anderson-Carpenter, K. D., Fletcher, J. B., Swendeman, D., & Reback, C. J. (2019). Associations between sociodemographic characteristics and substance use disorder severity among methamphetamine-using men who have sex with men. Substance Use and Misuse, 54(11), 1763–1773.31075997
Andrade, C. (2018). Risk of major congenital malformations associated with the use of methylphenidate or amphetamines in pregnancy. Journal of Clinical Psychiatry, 79(1), 18f12108.
Anker, A. L., & Crowley, T. J. (1982). Use of contingency contracts in specialty clinics for cocaine abuse. NIDA Research Monograph, 41, 452–459.6811933
Arkowitz, H., Miller, W. R., & Rollnick, S. (Eds.). (2015). Motivational interviewing in the treatment of psychological problems. Guilford Press.
Armenian, P., Effron, Z., Garbi, N., Dirks, R., Benowitz, N. L., & Gerona, R. R. (2019). Stimulant drugs are associated with violent and penetrating trauma. American Journal of Emergency Medicine, 37(4), 645–650.
Arria, A. M., & DuPont, R. L. (2018). Prescription stimulant use and misuse: Implications for responsible prescribing practices. American Journal of Psychiatry, 175(8), 707–708.
ARUP Laboratories (2019). Drug plasma half-life and urine detection windows.
AshaRani, P. V., Hombali, A., Seow, E., Ong, W. J., Tan, J. H., & Subramaniam, M. (2020). Non-pharmacological interventions for methamphetamine use disorder: A systematic review. Drug and Alcohol Dependence, 212, 108060.32445927
Ashok, A. H., Mizuno, Y., Volkow, N. D., & Howes, O. D. (2017). Association of stimulant use with dopaminergic alterations in users of cocaine, amphetamine, or methamphetamine: A systematic review and meta-analysis. JAMA Psychiatry, 74(5), 511–519.28297025
Asser, A., & Taba, P. (2015). Psychostimulants and movement disorders. Frontiers in Neurology, 6, 75.25941511
Attaran, H. (2017). Fatal small intestinal ischemia due to methamphetamine intoxication: Report of a case with autopsy results. Acta Medica Iranica, 55(5), 344–347.28724276
Bachi, K., Mani, V., Jeyachandran, D., Fayad, Z. A., Goldstein, R. Z., & Alia-Klein, N. (2017). Vascular disease in cocaine addiction. Atherosclerosis, 262, 154–162.28363516
Bahdila, D., Aldosari, M., Abdullah, A., Nelson, J. L., Hegazi, F., Badamia, R., … Agaku, I. T. (2020). Cocaine, polysubstance abuse, and oral health outcomes, NHANES 2009 to 2014. Journal of Periodontology. Advance online publication. 10.1002/JPER.19-0509
Bailey, Z. D., Krieger, N., Agénor, M., Graves, J., Linos, N., & Bassett, M. T. (2017). Structural racism and health inequities in the USA: Evidence and interventions. Lancet, 389(10077), 1453–1463.28402827
Baldwin, J. A., Eaves, E. R., Brown, B. G., Elwell, K., & Williamson, H. J. (2020). The behavioral health of American Indian/Alaska Native populations: Risk and resiliency. In B. L. Levin & A. Hanson (Eds.), Foundations of behavioral health (pp. 205–230). Springer.
Baldwin, J. A., Johnson, J. L., & Benally, C. C. (2009). Building partnerships between indigenous communities and universities: Lessons learned in HIV/AIDS and substance abuse prevention research. American Journal of Public Health, 99(Suppl. 1), S77–S82.19246672
Ballester, J., Valentine, G., & Sofuoglu, M. (2017). Pharmacological treatments for methamphetamine addiction: Current status and future directions. Expert Review of Clinical Pharmacology, 10(3), 305–314.27927042
Balsam, K. F., Huang, B., Fieland, K. C., Simoni, J. M., & Walters, K. L. (2004). Culture, trauma, and wellness: A comparison of heterosexual and lesbian, gay, bisexual, and two-spirit Native Americans. Cultural Diversity and Ethnic Minority Psychology, 10(3), 287–301.15311980
Baltes, A., Akhtar, W., Birstler, J., Olson-Streed, H., Eagen, K., Seal, D., … Brown, R. (2020). Predictors of skin and soft tissue infections among sample of rural residents who inject drugs. Harm Reduction Journal, 17(1), 96.33267848
Baradhi, K. M., Pathireddy, S., Bose, S., & Aeddula, N. R. (2019). Methamphetamine (N-methylamphetamine)-induced renal disease: Underevaluated cause of end-stage renal disease (ESRD). BMJ Case Reports, 12(9), e230288.
Baral, S. D., Poteat, T., Strömdahl, S., Wirtz, A. L., Guadamuz, T. E., & Beyrer, C. (2013). Worldwide burden of HIV in transgender women: A systematic review and meta-analysis. Lancet: Infectious Diseases, 13(3), 214–222.23260128
Barker, S. L., & Maguire, N. (2017). Experts by experience: Peer support and its use with the homeless. Community Mental Health Journal, 53(5), 598–612.28176210
Barrenger, S. L., Hamovitch, E. K., & Rothman, M. R. (2019). Enacting lived experiences: Peer specialists with criminal justice histories. Psychiatric Rehabilitation Journal, 42(1), 9–16.30265065
Barry, C. L., Martin, A., & Busch, S. H. (2012). ADHD medication use following FDA risk warnings. Journal of Mental Health Policy and Economics, 15(3), 119–125.
Bashshur, R. L., Shannon, G. W., Bashshur, N., & Yellowlees, P. M. (2016). The empirical evidence for telemedicine interventions in mental disorders. Telemedicine Journal and E-Health, 22(2), 87–113.26624248
Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
Batchelder, A. W., Safren, S., Mitchell, A. D., Ivardic, I., & O'Cleirigh, C. (2017). Mental health in 2020 for men who have sex with men in the United States. Sexual Health, 14(1), 59–71.28055823
Bauermeister, J. A., Eaton, L., Meanley, S., & Pingel, E. S., on behalf of the UHIP Partnership. (2017). Transactional sex with regular and casual partners among young men who have sex with men in the Detroit metro area. American Journal of Men's Health, 11(3), 498–507.
Baxter, A. J., Tweed, E. J., Katikireddi, S. V., & Thomson, H. (2019). Effects of Housing First approaches on health and well-being of adults who are homeless or at risk of homelessness: Systematic review and meta-analysis of randomised controlled trials. Journal of Epidemiology and Community Health, 73(5), 379–387.30777888
Beard, C., Hsu, K. J., Rifkin, L. S., Busch, A. B., & Björgvinsson, T. (2016). Validation of the PHQ-9 in a psychiatric sample. Journal of Affective Disorders, 193, 267–273.26774513
Beiter, R. M., Peterson, A. B., Abel, J., & Lynch, W. J. (2016). Exercise during early, but not late abstinence, attenuates subsequent relapse vulnerability in a rat model. Translational Psychiatry, 6(4), e792.27115123
Bekkering, G. E., Mariën, D., Parylo, O., & Hannes, K. (2016). The effectiveness of self-help groups for adolescent substance misuse: A systematic review. Journal of Child and Adolescent Substance Abuse, 25(3), 229–244.
Benishek, L. A., Dugosh, K. L., Kirby, K. C., Matejkowski, J., Clements, N. T., Seymour, B. L., & Festinger, D. S. (2014). Prize-based contingency management for the treatment of substance abusers: A meta-analysis. Addiction, 109(9), 1426–1436.24750232
Benotsch, E. G., Zimmerman, R., Cathers, L., McNulty, S., Pierce, J., Heck, T., … Snipes, D. (2013). Non-medical use of prescription drugs, polysubstance use, and mental health in transgender adults. Drug and Alcohol Dependence, 132(1–2), 391–394.23510637
Benson, K., Flory, K., Humphreys, K. L., & Lee, S. S. (2015). Misuse of stimulant medication among college students: A comprehensive review and meta-analysis. Clinical Child and Family Psychology Review, 18(1), 50–76.25575768
Bentley, K. H., Sakurai, H., Lowman, K. L., Rines-Toth, L., McKowen, J., Pedrelli, P., … Yule, A. M. (2021). Validation of brief screening measures for depression and anxiety in young people with substance use disorders. Journal of Affective Disorders, 282, 1021–1029.33601674
Berenz, E. C., & Coffey, S. F. (2012). Treatment of co-occurring posttraumatic stress disorder and substance use disorders. Current Psychiatry Reports, 14(5), 469–477.22825992
Berridge, K. C., & Kringelbach, M. L. (2015). Pleasure systems in the brain. Neuron, 86(3), 646–664.25950633
Berry, M. S., Bruner, N. R., Herrmann, E. S., Johnson, P. S., & Johnson, M. W. (2020). Methamphetamine administration dose effects on sexual desire, sexual decision making, and delay discounting. Experimental and Clinical Psychopharmacology. Advance online publication. 10.1037/pha0000398
Bhide, A., Shah, P. S., & Acharya, G. (2018). A simplified guide to randomized controlled trials. Acta Obstetricia et Gynecologica Scandinavica, 97(4), 380–387.29377058
Bhuvaneswar, C. G., Chang, G., Epstein, L. A., & Stern, T. A. (2008). Cocaine and opioid use during pregnancy: Prevalence and management. Primary Care Companion to the Journal of Clinical Psychiatry, 10(1), 59–65.
Black, D. S., & Amaro, H. (2019). Moment-by-Moment in Women's Recovery (MMWR): Mindfulness-based intervention effects on residential substance use disorder treatment retention in a randomized controlled trial. Behaviour Research and Therapy, 120, 103437.31419610
Black, J. C., Bau, G. E., Iwanicki, J. L., & Dart, R. C. (2021, February 2). Association of medical stimulants with mortality in the US from 2010 to 2017. JAMA Internal Medicine, 181(5):707–709.33523100
Blanco, C., Compton, W. M., Saha, T. D., Goldstein, B. I., Ruan, W. J., Huang, B., & Grant, B. F. (2017). Epidemiology of DSM-5 bipolar I disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions–III. Journal of Psychiatric Research, 84, 310–317.27814503
Blanco, C., Okuda, M., Markowitz, J. C., Liu, S. M., Grant, B. F., & Hasin, D. S. (2010). The epidemiology of chronic major depressive disorder and dysthymic disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. Journal of Clinical Psychiatry, 71(12), 1645–1656.
Blevins, C. A., Weathers, F. W., Davis, M. T., Witte, T. K., & Domino, J. L. (2015). The posttraumatic stress disorder checklist for DSM–5 (PCL–5): Development and initial psychometric evaluation. Journal of Traumatic Stress, 28(6), 489–498.26606250
Blonigen, D. M., Finney, J. W., Wilbourne, P. L., & Moos, R. H. (2015). Psychosocial treatments for substance use disorders. In P. E. Nathan & J. M. Gorman (Eds.), A guide to treatments that work (pp. 731–761). Oxford University Press.
Board, A. R., Guy, G., Jones, C. M., & Hoots, B. (2020). Trends in stimulant dispensing by age, sex, state of residence, and prescriber specialty—United States, 2014–2019. Drug and Alcohol Dependence, 217, 108297.32961454
Bohnert, K. M., Ilgen, M. A., Louzon, S., McCarthy, J. F., & Katz, I. R. (2017). Substance use disorders and the risk of suicide mortality among men and women in the US Veterans Health Administration. Addiction, 112(7), 1193–1201.28301070
Boileau, I., McCluskey, T., Tong, J., Furukawa, Y., Houle, S., & Kish, S. J. (2016). Rapid recovery of vesicular dopamine levels in methamphetamine users in early abstinence. Neuropsychopharmacology, 41(4), 1179–1187.26321315
Bolloni, C., Badas, P., Corona, G., & Diana, M. (2018). Transcranial magnetic stimulation for the treatment of cocaine addiction: Evidence to date. Substance Abuse and Rehabilitation, 9, 11–21.29849473
Bond Edmond, M., Aletraris, L., & Roman, P. M. (2015). Rural substance use treatment centers in the United States: An assessment of treatment quality by location. American Journal of Drug and Alcohol Abuse, 41(5), 449–457.
Bourne, A., & Weatherburn, P. (2017). Substance use among men who have sex with men: Patterns, motivations, impacts and intervention development need. Sexually Transmitted Infections, 93(5), 342–346.28400466
Bramness, J. G., Gundersen, Ø. H., Guterstam, J., Rognli, E. B., Konstenius, M., Løberg, E. M., … Franck, J. (2012). Amphetamine-induced psychosis—A separate diagnostic entity or primary psychosis triggered in the vulnerable? BMC Psychiatry, 12, 221.23216941
Bramness, J. G., & Rognli, E. B. (2016). Psychosis induced by amphetamines. Current Opinion in Psychiatry, 29(4), 236–241.27175554
Bramson, H., Des Jarlais, D. C., Arasteh, K., Nugent, A., Guardino, V., Feelemyer, J., & Hodel, D. (2015). State laws, syringe exchange, and HIV among persons who inject drugs in the United States: History and effectiveness. Journal of Public Health Policy, 36(2), 212–230.25590514
Braunwarth, W.-D., Christ, M., Dirks, H., Dyba, J., Härtel-Petri, R., Harfst, T., … Krampe-Scheidler, A. (2016). S3 practice guideline: Methamphetamine-related disorders. Ärztliche Zentrum für Qualität in der Medizin.
Brecht, M. L., & Herbeck, D. (2013). Methamphetamine use and violent behavior: User perceptions and predictors. Journal of Drug Issues, 43(4), 468–482.26594058
Brecht, M. L., & Herbeck, D. (2014). Time to relapse following treatment for methamphetamine use: A long-term perspective on patterns and predictors. Drug and Alcohol Dependence, 139(1), 18–25.24685563
Brewer, J. A., Elwafi, H. M., & Davis, J. H. (2013). Craving to quit: Psychological models and neurobiological mechanisms of mindfulness training as treatment for addictions. Psychology of Addictive Behaviors, 27(2), 366–379.22642859
Brinkley-Rubinstein, L. (2015). Understanding the effects of multiple stigmas among formerly incarcerated HIV-positive African American men. AIDS Education and Prevention, 27(2), 167–179.25915701
British Columbia Center for Disease Control (2011). Acidifier (ascorbic acid) and injection drug use: Questions and answers.
Bromberg-Martin, E. S., Matsumoto, M., & Hikosaka, O. (2010). Dopamine in motivational control: Rewarding, aversive, and alerting. Neuron, 68(5), 815–834.21144997
Bronson, J., Stroop, J., Zimmer, S., & Berzofsky, M. (2017). Drug use, dependence, and abuse among state prisoners and jail inmates, 2007–2009 (NCJ 250546). U.S. Department of Justice, Bureau of Justice Statistics.
Brooks, R. A., Landovitz, R. J., Kaplan, R. L., Lieber, E., Lee, S. J., & Barkley, T. W. (2012). Sexual risk behaviors and acceptability of HIV pre-exposure prophylaxis among HIV-negative gay and bisexual men in serodiscordant relationships: A mixed methods study. AIDS Patient Care and STDs, 26(2), 87–94.22149764
Brown, H. D., & DeFulio, A. (2020). Contingency management for the treatment of methamphetamine use disorder: A systematic review. Drug and Alcohol Dependence, 216, 108307.33007699
Brown, R. A., Dickerson, D. L., & D'Amico, E. J. (2016). Cultural identity among urban American Indian/Alaska Native youth: Implications for alcohol and drug use. Prevention Science, 17(7), 852–861.27450682
Browne, T., Priester, M. A., Clone, S., Iachini, A., DeHart, D., & Hock, R. (2016). Barriers and facilitators to substance use treatment in the rural South: A qualitative study. Journal of Rural Health, 32(1), 92–101.
Bruccoleri, R. E., & Burns, M. M. (2016). A literature review of the use of sodium bicarbonate for the treatment of QRS widening. Journal of Medical Toxicology, 12(1), 121–129.26159649
Bruggisser, M., Bodmer, M., & Liechti, M. E. (2011). Severe toxicity due to injected but not oral or nasal abuse of methylphenidate tablets. Swiss Medical Weekly, 141, w13267.21984207
Buck, S. A., Torregrossa, M. M., Logan, R. W., & Freyberg, Z. (2021). Roles of dopamine and glutamate co-release in the nucleus accumbens in mediating the actions of drugs of abuse. FEBS Journal, 288(5), 1462–1474.
Burch, A. E., Rash, C. J., & Petry, N. M. (2017). Cocaine-using substance abuse treatment patients with and without HIV respond well to contingency management treatment. Journal of Substance Abuse Treatment, 77, 21–25.28476266
Bureau of Justice Statistics (2020). Data collected under the First Step Act, 2019 (NCJ 254268). U.S. Department of Justice, Office of Justice Programs.
Butler, A. J., Rehm, J., & Fischer, B. (2017). Health outcomes associated with crack-cocaine use: Systematic review and meta-analyses. Drug and Alcohol Dependence, 180, 401–416.28982092
Cachay, E. R., Moini, N., Kosakovsky Pond, S. L., Pesano, R., Lie, Y. S., Aiem, H., … Smith, D. M. (2007). Active methamphetamine use is associated with transmitted drug resistance to non-nucleoside reverse transcriptase inhibitors in individuals with HIV infection of unknown duration. Open AIDS Journal, 1, 5–10.
Cain, M. A., Bornick, P., & Whiteman, V. (2013). The maternal, fetal, and neonatal effects of cocaine exposure in pregnancy. Clinical Obstetrics and Gynecology, 56(1), 124–132.23314714
California Correctional Health Care Services (2020). CCHCS care guide: Intoxication and withdrawal.
Calsyn, D. A., Cousins, S. J., Hatch–Maillette, M. A., Forcehimes, A., Mandler, R., Doyle, S. R., & Woody, G. (2010). Sex under the influence of drugs or alcohol: Common for men in substance abuse treatment and associated with high–risk sexual behavior. American Journal on Addictions, 19(2), 119–127.
Campbell, A. N. C., Nunes, E. V., Matthews, A. G., Stitzer, M., Miele, G. M., Polsky, D., … Ghitza, U. E. (2014). Internet-delivered treatment for substance abuse: A multisite randomized controlled trial. American Journal of Psychiatry, 171, 683–690.
Cantrell, F. L., Ogera, P., Mallett, P., & McIntyre, I. M. (2014). Fatal oral methylphenidate intoxication with postmortem concentrations. Journal of Forensic Sciences, 59(3), 847–849.24502813
Carlin, N., Nguyen, N., & DePasquale, J. R. (2014). Multiple gastrointestinal complications of crack cocaine abuse. Case Reports in Medicine, 2014, 512939.24839446
Carmack, S. A., Koob, G. F., & Anagnostaras, S. G. (2017). Learning and memory in addiction. In J. H. Byrne (Ed.), Learning and memory: A comprehensive reference (2nd ed., pp. 523–538). Elsevier.
Carrico, A. W., Flentje, A., Kober, K., Lee, S., Hunt, P., Riley, E. D., … Aouizerat, B. E. (2018). Recent stimulant use and leukocyte gene expression in methamphetamine users with treated HIV infection. Brain, Behavior, and Immunity, 71, 108–115.
Carrico, A. W., Hunt, P. W., Neilands, T. B., Dilworth, S. E., Martin, J. N., Deeks, S. G., & Riley, E. D. (2019). Stimulant use and viral suppression in the era of universal antiretroviral therapy. Journal of Acquired Immune Deficiency Syndromes, 80(1), 89–93.30272634
Carrico, A. W., Neilands, T. B., Dilworth, S. E., Evans, J. L., Gómez, W., Jain, J. P., … Moskowitz, J. T. (2019). Randomized controlled trial of a positive affect intervention to reduce HIV viral load among sexual minority men who use methamphetamine. Journal of the International AIDS Society, 22(12), e25436.31860172
Carrico, A. W., Shoptaw, S., Cox, C., Stall, R., Li, X., Ostrow, D. G., … Plankey, M. W. (2014). Stimulant use and progression to AIDS or mortality after the initiation of highly active anti-retroviral therapy. Journal of Acquired Immune Deficiency Syndromes, 67(5), 508–513.25271387
Carroll, K. M., Nich, C., Petry, N. M., Eagan, D. A., Shi, J. M., & Ball, S. A. (2016). A randomized factorial trial of disulfiram and contingency management to enhance cognitive behavioral therapy for cocaine dependence. Drug and Alcohol Dependence, 160(1), 135–142.26817621
Carroll, K. M., Nich, C., Shi, J. M., Eagan, D., & Ball, S. A. (2012). Efficacy of disulfiram and Twelve Step facilitation in cocaine-dependent individuals maintained on methadone: A randomized placebo-controlled trial. Drug and Alcohol Dependence, 126(1–2), 224–231.22695473
Carroll, K. M., Rounsaville, B. J., & Gawin, F. H. (1991). A comparative trial of psychotherapies for ambulatory cocaine abusers: Relapse prevention and interpersonal psychotherapy. American Journal of Drug and Alcohol Abuse, 17, 229–247.
Carroll, K. M., Rounsaville, B. J., Gordon, L. T., Nich, C., Jatlow, P., Bisighini, R. M., & Gawin, F. H. (1994). Psychotherapy and pharmacotherapy for ambulatory cocaine abusers. Archives of General Psychiatry, 51, 177–187.8122955
Carroll, K. M., Rounsaville, B. J., & Keller, D. S. (1991). Relapse prevention strategies for the treatment of cocaine abusers. American Journal of Drug and Alcohol Abuse, 17, 249–265.
Carroll, K. M., Rounsaville, B. J., Nich, C., Gordon, L. T., Wirtz, P. W., & Gawin, F. (1994). One-year followup of psychotherapy and pharmacotherapy for cocaine dependence. Archives of General Psychiatry, 51, 989–997.7979888
Carson, E. A. (2020). Prisoners in 2019 (NCJ 255115). U.S. Department of Justice.
Castillo-Mancilla, J. R., Brown, T. T., Erlandson, K. M., Palella, Jr., F. J., Gardner, E. M., Macatangay, B. J. C., … Wada, N. I. (2016). Suboptimal adherence to combination antiretroviral therapy is associated with higher levels of inflammation despite HIV suppression. Clinical Infectious Diseases, 63(12), 1661–1667.27660234
Center for Behavioral Health Statistics and Quality (2016). Results from the 2015 National Survey on Drug Use and Health: Detailed tables. Substance Abuse and Mental Health Services Administration.
Center for Behavioral Health Statistics and Quality (2017). Treatment Episode Data Set (TEDS): 2005–2015. National admissions to substance abuse treatment services. BHSIS Series S-91, HHS Publication No. (SMA) 17-5037. Substance Abuse and Mental Health Services Administration.
Center for Behavioral Health Statistics and Quality (2019). Treatment Episode Data Set (TEDS): 2017—Admissions to and discharges from publicly-funded substance use treatment. Substance Abuse and Mental Health Services Administration.
Center for Behavioral Health Statistics and Quality (2020a). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/data/
Center for Behavioral Health Statistics and Quality (2020b). Treatment Episode Data Set (TEDS). Based on administrative data reported by states to TEDS through July 1, 2020. Substance Abuse and Mental Health Services Administration. https://wwwdasis.samhsa.gov/webt/newmapv1.htm#
Center for Integrated Healthcare (2013). Cocaine. Information for behavioral health providers in primary care. U.S. Department of Veterans Affairs.
Center for Substance Abuse Treatment (2000). Integrating substance abuse treatment and vocational services. Treatment Improvement Protocol (TIP) Series 38. HHS Publication No. (SMA) 12–4216. Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2005). Substance abuse treatment for adults in the criminal justice system. Treatment Improvement Protocol (TIP) Series 44. HHS Publication No. (SMA) 13-4056. Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2006). Counselor's treatment manual: Matrix intensive outpatient treatment for people with stimulant use disorders. HHS Publication No. (SMA) 13-4152. Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2012). A provider's introduction to substance abuse treatment for lesbian, gay, bisexual, and transgender individuals. HHS Publication No. (SMA) 12–4104. Substance Abuse and Mental Health Services Administration.
Centers for Disease Control and Prevention. (n.d.-a). About opioid use during pregnancy. https://www.cdc.gov/pregnancy/opioids/basics.html
Centers for Disease Control and Prevention. (n.d.-b). Estimated per-act probability of acquiring HIV from an infected source, by exposure act. https://www.cdc.gov/hiv/risk/estimates/riskbehaviors.html
Centers for Disease Control and Prevention. (n.d.-c). Frequently asked questions: Hepatitis A outbreaks. https://www.cdc.gov/hepatitis/outbreaks/FAQs-HepAOutbreaks.htm
Centers for Disease Control and Prevention. (n.d.-d). Pregnancy and oral health. https://www.cdc.gov/oralhealth/publications/features/pregnancy-and-oral-health.html
Centers for Disease Control and Prevention. (n.d.-e). Prevent bacterial and fungal infections in patients who inject drugs. U.S. Department of Health and Human Services.
Centers for Disease Control and Prevention. (n.d.-f). Syringe services programs (SSPs) FAQs. https://www.cdc.gov/ssp/syringe-services-programs-faq.html
Centers for Disease Control and Prevention. (n.d.-g). What is viral hepatitis? https://www.cdc.gov/hepatitis/abc/index.htm
Centers for Disease Control and Prevention. (2011). Hepatitis C virus infection among adolescents and young adults: Massachusetts, 2002–2009. Morbidity and Mortality Weekly Report, 60(17), 537–541.21544042
Centers for Disease Control and Prevention. (2014). HIV and young men who have sex with men. U.S. Department of Health and Human Services.
Centers for Disease Control and Prevention. (2015). Epidemiology and prevention of vaccine-preventable diseases (13th ed.). Public Health Foundation.
Centers for Disease Control and Prevention. (2016). Proven HIV prevention methods [Fact sheet]. U.S. Department of Health and Human Services. https://www.cdc.gov/nchhstp/newsroom/docs/factsheets/HIV-Proven-Prevention-Methods-508.pdf
Centers for Disease Control and Prevention. (2018, April 16). Surveillance for viral hepatitis—United States, 2016. https://www.cdc.gov/hepatitis/statistics/2016surveillance/commentary.htm
Centers for Disease Control and Prevention. (2019). Annual surveillance report of drug-related risks and outcomes—United States, 2019. U.S. Department of Health and Human Services.
Centers for Disease Control and Prevention. (2020a, May 26). What can decrease HIV risk? https://hivrisk.cdc.gov/can-decrease-hiv-risk/
Centers for Disease Control and Prevention. (2020b, August 18). People experiencing homelessness and viral hepatitis. https://www.cdc.gov/hepatitis/populations/peh.htm
Centers for Disease Control and Prevention. (2020c, December 17). CDC Health Advisory: Increase in fatal drug overdoses across the United States driven by synthetic opioids before and during the COVID-19 pandemic (CDCHAN-00438). https://emergency.cdc.gov/han/2020/han00438.asp
Centers for Disease Control and Prevention. (2021a). Estimated HIV incidence and prevalence in the United States, 2015–2019. (HIV Surveillance Supplemental Report, 26 [No. 1]).
Centers for Disease Control and Prevention. (2021b). HIV and people who inject drugs. https://www.cdc.gov/hiv/group/hiv-idu.html
Centers for Disease Control and Prevention. (2021c). Viral hepatitis surveillance report 2019: Hepatitis A. https://www.cdc.gov/hepatitis/statistics/2019surveillance/HepA.htm
Centers for Disease Control and Prevention. (2021d). Viral hepatitis surveillance report 2019 – Introduction. https://www.cdc.gov/hepatitis/statistics/2019surveillance/Introduction.htm
Centers for Disease Control and Prevention. (2021e, March 29). Widespread person-to-person outbreaks of hepatitis A across the United States. https://www.cdc.gov/hepatitis/outbreaks/2017March-HepatitisA.htm
Centers for Medicare & Medicaid Services (2016). Drug diversion: What is a prescriber's role in preventing the diversion of prescription drugs? U.S. Department of Health and Human Services.
Cepeda, J. A., Vickerman, P., Bruneau, J., Zang, G., Borquez, A., Farrell, M., … Martin, N. K. (2020). Estimating the contribution of stimulant injection to HIV and HCV epidemics among people who inject drugs and implications for harm reduction: A modeling analysis. Drug and Alcohol Dependence, 213, 108135.32603976
Charnigo, R., Noar, S. M., Garnett, C., Crosby, R., Palmgreen, P., & Zimmerman, R. S. (2013). Sensation seeking and impulsivity: Combined associations with risky sexual behavior in a large sample of young adults. Journal of Sex Research, 50(5), 480–488.22456443
Chartier, K. G., Carmody, T., Akhtar, M., Stebbins, M. B., Walters, S. T., & Warden, D. (2015). Hispanic subgroups, acculturation, and substance abuse treatment outcomes. Journal of Substance Abuse Treatment, 59, 74–82.26362001
Chen, H.-Y., Albertson, T. E., & Olson, K. R. (2016). Treatment of drug-induced seizures. British Journal of Clinical Pharmacology, 81(3), 412–419.26174744
Chen, J., Feeney, E., & Chung, R. (2014). HCV and HIV co-infection: Mechanisms and management. Nature Reviews Gastroenterology and Hepatology, 11(6), 362–371.24535328
Chen, L. Y., Crum, R. M., Strain, E. C., Alexander, G. C., Kaufmann, C., & Mojtabai, R. (2016). Prescriptions, nonmedical use, and emergency department visits involving prescription stimulants. Journal of Clinical Psychiatry, 77(3), e297–e304.
Cheng, W. S., Garfein, R. S., Semple, S. J., Strathdee, S. A., Zians, J. K., & Patterson, T. L. (2010). Binge use and sex and drug use behaviors among HIV(−), heterosexual methamphetamine users in San Diego. Substance Use and Misuse, 45(1–2), 116–133.20025442
Chermack, S. T., Bonar, E. E., Goldstick, J. E., Winters, J., Blow, F. C., Friday, S., … Walton, M. A. (2019). A randomized controlled trial for aggression and substance use involvement among veterans: Impact of combining motivational interviewing, cognitive behavioral treatment and telephone-based continuing care. Journal of Substance Abuse Treatment, 98, 78–88.30665608
Chermack, S. T., Grogan-Kaylor, A., Perron, B. E., Murray, R. L., De Chavez, P., & Walton, M. A. (2010). Violence among men and women in substance use disorder treatment: A multi-level event-based analysis. Drug and Alcohol Dependence, 112(3), 194–200.20667666
Chettiar, J., Shannon, K., Wood, E., Zhang, R., & Kerr, T. (2010). Survival sex work involvement among street-involved youth who use drugs in a Canadian setting. Journal of Public Health (Oxford, England), 32(3), 322–327.
Chiesa, A., & Serretti, A. (2014). Are mindfulness-based interventions effective for substance use disorders? A systematic review of the evidence. Substance Use and Misuse, 49(5), 492–512.23461667
Childress, A. C., Komolova, M., & Sallee, F. R. (2019). An update on the pharmacokinetic considerations in the treatment of ADHD with long-acting methylphenidate and amphetamine formulations. Expert Opinion on Drug Metabolism and Toxicology, 15(11), 937–974.31581854
Childress, A. R., Mozley, P. D., McElgin, W., Fitzgerald, J., Reivich, M., & O'Brien, C. P. (1999). Limbic activation during cue-induced cocaine craving. American Journal of Psychiatry, 156(1), 11–18.
Chin, J. M., & Bartholomew, M. L. (2020). Methamphetamine use in pregnant women in Hawai'i: A case series. Hawai'i Journal of Health and Social Welfare, 79(5 Suppl. 1), 40–43.
Chiu, V. M., & Schenk, J. O. (2012). Mechanism of action of methamphetamine within the catecholamine and serotonin areas of the central nervous system. Current Drug Abuse Reviews, 5(3), 227–242.22998621
Choi, K., Imrie, A., Lourie, R., & Cross, T. (2019). Intestinal ischemia due to methamphetamine use: A case report. International Journal of Surgery Case Reports, 58, 11–13.30986641
Chou, R., Korthuis, P. T., McCarty, D., Coffin, P., Griffin, J., Davis-O'Reilly, C., … Daya, M. (2017). Management of suspected opioid overdose with naloxone by emergency medical services personnel (AHRQ Publication No. 17-EHC025-EF). Agency for Healthcare Research and Quality.
Christine, C. W., Garwood, E. R., Schrock, L. E., Austin, D. E., & McCulloch, C. E. (2010). Parkinsonism in patients with a history of amphetamine exposure. Movement Disorders, 25(2), 228–231.20063432
Ciccarone, D. (2011). Stimulant abuse: Pharmacology, cocaine, methamphetamine, treatment, attempts at pharmacotherapy. Primary Care: Clinics in Office Practice, 38(1), 41–58.21356420
Ciccarone, D., & Harris, M. (2015). Fire in the vein: Heroin acidity and its proximal effect on users' health. International Journal on Drug Policy, 26(11), 1103–1110.
Clague, J., Belin, T. R., & Shetty, V. (2017). Mechanisms underlying methamphetamine-related dental disease. Journal of the American Dental Association, 148(6), 377–386.28457476
Clarke, K., Harris, D., Zweifler, J. A., Lasher, M., Mortimer, R. B., & Hughes, S. (2016). The significance of harm reduction as a social and health care intervention for injecting drug users: An exploratory study of a needle exchange program in Fresno, California. Social Work in Public Health, 31(5), 398–407.27167664
Clary, E., Ribar, C., & Weigensberg, E. (2020). Challenges in providing substance use disorder treatment to child welfare clients in rural communities. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation.
Clemow, D. B., & Walker, D. J. (2014). The potential for misuse and abuse of medications in ADHD: A review. Postgraduate Medicine, 126(5), 64–81.25295651
Closson, E. F., Mitty, J. A., Malone, J., Mayer, K. H., & Mimiaga, M. J. (2018). Exploring strategies for PrEP adherence and dosing preferences in the context of sexualized recreational drug use among MSM: A qualitative study. AIDS Care, 30(2), 191–198.28830220
Cockroft, J. D., Adams, S. M., Bonnet, K., Matlock, D., McMillan, J., & Schlundt, D. (2019). “A scarlet letter”: Stigma and other factors affecting trust in the health care system for women seeking substance abuse treatment in a community setting. Substance Abuse, 40(2), 170–177.30759047
Coe, M. A., Jufer Phipps, R. A., Cone, E. J., & Walsh, S. L. (2018). Bioavailability and pharmacokinetics of oral cocaine in humans. Journal of Analytical Toxicology, 42(5), 285–292.29462364
Colaneri, N., Keim, S., & Adesman, A. (2017). Physician practices to prevent ADHD stimulant diversion and misuse. Journal of Substance Abuse Treatment, 74, 26–34.28132697
Cole, C., Jones, L., McVeigh, J., Kicman, A., Syed, Q., & Bellis, M. A. (2010). CUT: A guide to adulterants, bulking agents, and other contaminants found in illicit drugs. Liverpool John Moores University, Faculty of Health and Applied Social Sciences, Centre for Public Health.
Coleman, E., Bockting, W., Botzer, M., Cohen-Kettenis, P., DeCuypere, G., Feldman, J., … Zucker, K. (2012). Standards of care for the health of transsexual, transgender, and gender-nonconforming people. World Professional Association for Transgender Health.
Colledge, S., Larney, S., Bruno, R., Gibbs, D., Degenhardt, L., Yuen, W. S., … Peacock, A. (2020). Profile and correlates of injecting-related injuries and diseases among people who inject drugs in Australia. Drug and Alcohol Dependence, 216, 108267.32916518
Compton, W. M., Han, B., Blanco, C., Johnson, K., & Jones, C. M. (2018). Prevalence and correlates of prescription stimulant use, misuse, use disorders, and motivations for misuse among adults in the United States. American Journal of Psychiatry, 175(8), 741–755.
Conner, K. O. (2020). Exploring the intersections of historical trauma and race in criminal justice and behavioral health. [Handout showing PowerPoint slides]. https://www.usf.edu/cbcs/mhlp/tac/documents/florida-main/cjmhsa-tac-quarterly-conf-calls/conner-intersection-of-historical-trauma-race-bh-cj-august-2020.pdf
Connolly, D., & Gilchrist, G. (2020). Prevalence and correlates of substance use among transgender adults: A systematic review. Addictive Behaviors, 111, 106544.32717497
Cook, J., Lloyd-Jones, M., Arunogiri, S., Ogden, E., & Bonomo, Y. (2017). Managing attention deficit hyperactivity disorder in adults using illicit psychostimulants: A systematic review. Australian and New Zealand Journal of Psychiatry, 51(9), 876–885.
Cook, J. A. (2011). Associations between use of crack cocaine and HIV-1 disease progression: Research findings and implications for mother-to-infant transmission. Life Sciences, 88(21–22), 931–939.21219914
Cooper, B. E., & Sejnowski, C. A. (2013). Serotonin syndrome: Recognition and treatment. AACN Advanced Critical Care, 24(1), 15–20.23343808
Copersino, M. L., Schretlen, D. J., Fitzmaurice, G. M., Lukas, S. E., Faberman, J., Sokoloff, J., & Weiss, R. D. (2012). Effects of cognitive impairment on substance abuse treatment attendance: Predictive validation of a brief cognitive screening measure. American Journal of Drug and Alcohol Abuse, 38(3), 246–250.
Corral-Verdugo, V., & Frias-Armenta, M. (2016). The sustainability of positive environments. Environment, Development and Sustainability, 18(4), 965–984.
Corsi, K. F., Rinehart, D. J., Kwiatkowski, C. F., & Booth, R. E. (2010). Case management outcomes for women who use crack. Journal of Evidence-Based Social Work, 7(1), 30–40.20178023
Cortese, S., Panei, P., Arcieri, R., Germinario, E. A., Capuano, A., Margari, L., … Curatolo, P. (2015). Safety of methylphenidate and atomoxetine in children with attention-deficit/hyperactivity disorder (ADHD): Data from the Italian National ADHD Registry. CNS Drugs, 29(10), 865–877.26293742
Cos, T. A., LaPollo, A. B., Aussendorf, M., Williams, J. M., Malayter, K., & Festinger, D. S. (2020). Do peer recovery specialists improve outcomes for individuals with substance use disorder in an integrative primary care setting? A program evaluation. Journal of Clinical Psychology in Medical Settings, 27(4), 704–715.31520183
Cosottile, D. W., & DeFulio, A. (2020). The compatibility of employment-based contingency management and vocational services at the Department of Veterans Affairs. Psychology of Addictive Behaviors, 34(1), 111–116.31219265
Courtney, K. E., & Ray, L. A. (2014). Methamphetamine: An update on epidemiology, pharmacology, clinical phenomenology, and treatment literature. Drug and Alcohol Dependence, 143, 11–21.25176528
Cousijn, J., Luijten, M., & Feldstein Ewing, S. W. (2018). Adolescent resilience to addiction: A social plasticity hypothesis. Lancet Child and Adolescent Health, 2(1), 69–78.30169197
Cox, K. B., Malte, C. A., & Saxon, A. J. (2017). Characteristics and service utilization of homeless veterans entering VA substance use treatment. Psychological Services, 14(2), 208–213.28481606
Craig, S. G., Davies, G., Schibuk, L., Weiss, M. D., & Hechtman, L. (2015). Long-term effects of stimulant treatment for ADHD: What can we tell our patients? Current Developmental Disorders Reports, 2(1), 1–9.
Crane, C. A., Oberleitner, L. M. S., Devine, S., & Easton, C. J. (2014). Substance use disorders and intimate partner violence perpetration among male and female offenders. Psychology of Violence, 4(3), 322–333.27011885
Crawford, S., & Bath, N. (2013). Peer support models for people with a history of injecting drug use undertaking assessment and treatment for hepatitis C Virus infection. Clinical Infectious Diseases, 57(Suppl. 2), S75–S79.23884070
Cruickshank, C. C., & Dyer, K. R. (2009). A review of the clinical pharmacology of methamphetamine. Addiction, 104(7), 1085–1099.19426289
Cucciare, M. A., Ounpraseuth, S. T., Curran, G. M., & Booth, B. M. (2019). Predictors of substance use disorder and mental health treatment use among rural adults using stimulants over three years. Substance Abuse, 40(3), 363–370.30810499
Cumming, C., Kinner, S. A., McKetin, R., Li, I., & Preen, D. (2020). Methamphetamine use, health and criminal justice system outcomes: A systematic review. Drug and Alcohol Review, 39(5), 505–518.32212214
Cunha-Oliveira, T., Rego, A. C., Carvalho, F., & Oliveira, C. R. (2013). Medical toxicology of drugs of abuse. In P. M. Miller, S. A. Ball, M. E. Bates, A. W. Blume, K. M. Kampman, D. J. Kavanagh, M. E. Larimer, N. M. Petry, & P. De Witte (Eds.), Comprehensive addictive behaviors and disorders: Vol. 1. Principles of addiction (pp. 159–175). Academic Press.
Cunha-Oliveira, T., Rego, A. C., & Oliveira, C. (2014). Cocaine as a neurotoxin. In R. Kostrzewa (Ed.), Handbook of neurotoxicity (pp. 277–297). Springer.
Cunningham, C. O., Giovanniello, A., Kunins, H. V., Roose, R. J., Fox, A. D., & Sohler, N. L. (2013). Buprenorphine treatment outcomes among opioid-dependent cocaine users and non-users. American Journal on Addictions, 22(4), 352–357.
Cunningham, E. B., Amin, J., Feld, J. J., Bruneau, J., Dalgard, O., Powis, J., … Grebely, J. (2018). Adherence to sofosbuvir and velpatasvir among people with chronic HCV infection and recent injection drug use: The SIMPLIFY study. International Journal of Drug Policy, 62, 14–23.30352330
Dakwar, E., & Levin, F. R. (2013). Individual mindfulness-based psychotherapy for cannabis or cocaine dependence: A pilot feasibility trial. American Journal on Addictions, 22(6), 521–526.
Dakwar, E., Nunes, E. V., Hart, C. L., Foltin, R. W., Mathew, S. J., Carpenter, K. M., … Levin, F. R. (2019). A single ketamine infusion combined with mindfulness-based behavioral modification to treat cocaine dependence: A randomized clinical trial. American Journal of Psychiatry, 176(11), 923–930.
Dallery, J., Raiff, B. R., Grabinski, M. J., & Marsch, L. A. (2019). Technology-based contingency management in the treatment of substance-use disorders. Perspectives on Behavior Science, 42(3), 445–464.31976444
Damon, W., McNeil, R., Milloy, M. J., Nosova, E., Kerr, T., & Hayashi, K. (2019). Residential eviction predicts initiation of or relapse into crystal methamphetamine use among people who inject drugs: A prospective cohort study. Journal of Public Health, 41(1), 36–45.29425315
Danielson, M. L., Bitsko, R. H., Ghandour, R. M., Holbrook, J. R., Kogan, M. D., & Blumberg, S. J. (2018). Prevalence of parent-reported ADHD diagnosis and associated treatment among U.S. children and adolescents, 2016. Journal of Clinical Child and Adolescent Psychology, 47(2), 199–212.29363986
Dasgupta, S., Tie, Y., Lemons-Lyn, A., Broz, D., Buchacz, K., & Shouse, R. L. (2020). HIV-positive persons who inject drugs experience poor health outcomes and unmet needs for care services. AIDS Care. Advance online publication. 10.1080/09540121.2020.1826396
da Silva Maia, A. F., Martins, F. T., da Silva Neto, L., Alves, R. B., & De Fátima, Â. (2017). Cocaethylene, the in vivo product of cocaine and ethanol, is a narcotic more potent than its precursors. Acta Crystallographica Section C: Structural Chemistry, 73(Pt. 10), 780–783.
Davidow, J. Y., Foerde, K., Galván, A., & Shohamy, D. (2016). An upside to reward sensitivity: The hippocampus supports enhanced reinforcement learning in adolescence. Neuron, 92(1), 93–99.27710793
Daw, N. D., & Tobler, P. N. (2013). Value learning through reinforcement: The basis of dopamine and reinforcement learning. In P. W. Glimcher & E. Fehr (Eds.), Neuroeconomics: Decision making and the brain (2nd ed., pp. 283–298). Elsevier.
De Crescenzo, F., Ciabattini, M., D'Alò, G. L., De Giorgi, R., Del Giovane, C., Cassar, C., … Cipriani, A. (2018). Comparative efficacy and acceptability of psychosocial interventions for individuals with cocaine and amphetamine addiction: A systematic review and network meta-analysis. PLoS Medicine, 15(12), e1002715.30586362
De Giorgi, R., Cassar, C., Loreto D'Alò, G., Ciabattini, M., Minozzi, S., Economou, A., … De Crescenzo, F. (2018). Psychosocial interventions in stimulant use disorders: A systematic review and qualitative synthesis of randomized controlled trials. Rivista di Psichiatria, 53(5), 233–255.30353199
Delaney, F. T., Stanley, E., & Bolster, F. (2020). The needle and the damage done: Musculoskeletal and vascular complications associated with injected drug use. Insights into Imaging, 11(1), 1–14.31901171
dela Peña, I., Gevorkiana, R., & Shi, W. X. (2015). Psychostimulants affect dopamine transmission through both dopamine transporter-dependent and independent mechanisms. European Journal of Pharmacology, 764, 562–570.26209364
Del Río, F. J., Cabello, F., & Fernández, I. (2015). Influence of substance use on the erectile response in a sample of drug users. International Journal of Clinical and Health Psychology, 15(1), 37–43.30487819
Deng, X., Huang, Z., Li, X., Li, Y., Wang, Y., Wu, D., … Yang, X. (2012). Long-term follow-up of patients treated for psychotic symptoms that persist after stopping illicit drug use. Shanghai Archives of Psychiatry, 24(5), 271–278.25328350
Department of Health and Human Services. (2021, June 2). U.S. statistics. https://www.hiv.gov/hiv-basics/overview/data-and-trends/statistics
Department of Housing and Urban Development (2021). The 2020 Annual Homeless Assessment Report (AHAR) to Congress: Pt. 1. Point-in-time estimates of homelessness. https://www.hudexchange.info/resource/6291/2020-ahar-part-1-pit-estimates-of-homelessness-in-the-us/
Des Jarlais, D. C. (2017). Harm reduction in the USA: The research perspective and an archive to David Purchase. Harm Reduction Journal, 14(1), 51.28747189
Des Jarlais, D. C., Feelemyer, J. P., Modi, S. N., Abdul-Quader, A., & Hagan, H. (2013). High coverage needle/syringe programs for people who inject drugs in low and middle income countries: A systematic review. BMC Public Health, 13, 53.23332005
De Sousa, A. (2013). Repetitive transcranial magnetic stimulation (rTMS) in the management of alcohol dependence and other substance abuse disorders: Emerging data and clinical relevance. Basic and Clinical Neuroscience, 4(3), 271–275.25337357
DeVito, E. E., Babuscio, T. A., Nich, C., Ball, S. A., & Carroll, K. M. (2014). Gender differences in clinical outcomes for cocaine dependence: Randomized clinical trials of behavioral therapy and disulfiram. Drug and Alcohol Dependence, 145, 156–167.25457739
Dezman, Z. D. W., Gorelick, D. A., Buchanan, L., & Soderstrom, C. A. (2020). 20-year mortality after discharge in a cohort of 1,099 former trauma inpatients with and without substance use disorders. Injury, 51(12), 2930–2937.33092854
Diaz, M., Tenney, C., Boyd, K. E., & Ford, J. A. (2021). Sexual identity and motivations for prescription drug misuse among U.S. adults. LGBT Health, 8(2), 107–115.33566728
Diaz, N., Horton, E. G., & Weiner, M. (2012). Dysthymia, major depression, and double depression among individuals receiving substance abuse treatment. Health, 4(12), 1229–1237.
Dinger, J., Hinner, P., Reichert, J., & Rüdiger, M. (2017). Methamphetamine consumption during pregnancy—Effects on child health. Pharmacopsychiatry, 50(3), 107–113.28178739
Ditmore, M. H. (2013). When sex work and drug use overlap: Considerations for advocacy and practice. Harm Reduction International.
Dodds, D., Koch, K., Buitrago-Mogollon, T., & Horstmann, S. (2019). Successful implementation of the eat sleep console model of care for infants with NAS in a community hospital. Hospital Pediatrics, 9(8), 632–638.31340986
Dos Santos, J. F., de Melo Bastos Cavalcante, C., Barbosa, F. T., Gitaí, D., Duzzioni, M., Tilelli, C. Q., … de Castro, O. W. (2018). Maternal, fetal and neonatal consequences associated with the use of crack cocaine during the gestational period: A systematic review and meta-analysis. Archives of Gynecology and Obstetrics, 298(3), 487–503.29951712
Dougherty, D. M., Olvera, R. L., Acheson, A., Hill-Kapturczak, N., Ryan, S. R., & Mathias, C. W. (2016). Acute effects of methylphenidate on impulsivity and attentional behavior among adolescents comorbid for ADHD and conduct disorder. Journal of Adolescence, 53, 222–230.27816696
Dougherty, M. M., & Marraffa, J. M. (2014). Phenothiazines. In P. Wexler (Ed.), Encyclopedia of toxicology (3rd ed., pp. 881–883). Academic Press.
Drug Enforcement Administration (2017). Colombian cocaine production expansion contributes to rise in supply in the United States (DEA-DCT-DIB-014-17).
Drug Enforcement Administration (2018). Deadly contaminated cocaine widespread in Florida (DEA-MIA-BUL-039-18).
Drug Enforcement Administration (2019). 2019 National Drug Threat Assessment (DEA DCT DIR 007-20). U.S. Department of Justice.
Drug Enforcement Administration (2021). 2020 National Drug Threat Assessment (DEA PRB 01-12-21-43). U.S. Department of Justice.
Drug Enforcement Administration, Diversion Control Division. (n.d.). Controlled substance schedules. https://www.deadiversion.usdoj.gov/schedules/
Drug Enforcement Administration, Diversion Control Division (2019a). Cocaine (street names: coke, snow, crack, rock). U.S. Department of Justice.
Drug Enforcement Administration, Diversion Control Division (2019b). NFLIS-Drug Special Report: Methamphetamine reported in NFLIS, 2001–2017. U.S. Department of Justice. Retrieved June 9, 2021, through https://www.nflis.deadiversion.usdoj.gov/publicationsRedesign.xhtml
Ducci, F., & Goldman, D. (2012). The genetic basis of addictive disorders. Psychiatric Clinics of North America, 35(2), 495–519.
Dufour, M., Nguyen, N., Bertrand, K., Perreault, M., Jutras-Aswad, D., Morvannou, A., … Roy, É. (2016). Gambling problems among community cocaine users. Journal of Gambling Studies, 32(3), 1039–1053.26983825
Dumont, D. M., Allen, S. A., Brockmann, B. W., Alexander, N. E., & Rich, J. D. (2013). Incarceration, community health, and racial disparities. Journal of Health Care for the Poor and Underserved, 24(1), 78–88.23377719
Duncan, D. T., Goedel, W. C., Stults, C. B., Brady, W. J., Brooks, F. A., Blakely, J. S., & Hagen, D. (2018). A study of intimate partner violence, substance abuse, and sexual risk behaviors among gay, bisexual, and other men who have sex with men in a sample of geosocial-networking smartphone application users. American Journal of Men's Health, 12(2), 292–301.
Dunn, A., & Gauthier, T. (2020). An introductory guide for assessing and understanding common wounds with people who inject drugs.
Duong, J., Elia, C., Takayanagi, A., Lanzilotta, T., Ananda, A., & Miulli, D. (2018). The impact of methamphetamines in patients with traumatic brain injury, a retrospective review. Clinical Neurology and Neurosurgery, 170, 99–101.29763809
Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
Edelman, E. J., Cole, C. A., Richardson, W., Boshnack, N., Jenkins, H., & Rosenthal, M. S. (2016). Stigma, substance use and sexual risk behaviors among HIV-infected men who have sex with men: A qualitative study. Preventive Medicine Reports, 3, 296–302.27556006
Ehlers, C. L., Gizer, I. R., Gilder, D. A., & Yehuda, R. (2013). Lifetime history of traumatic events in an American Indian community sample: Heritability and relation to substance dependence, affective disorder, conduct disorder and PTSD. Journal of Psychiatric Research, 47(2), 155–161.23102628
Eisinger, R. W., Dieffenbach, C. W., & Fauci, A. S. (2019). HIV viral load and transmissibility of HIV infection: Undetectable equals untransmittable. JAMA, 321(5), 451–452.30629090
Elkafrawi, D., Sisti, G., Araji, S., Khoury, A., Miller, J., & Rodriguez Echevarria, B. (2020). Risk factors for neonatal/maternal morbidity and mortality in African American women with placental abruption. Medicina, 56(4), 174.
Elliott, R., Bohart, A. C., Watson, J. C., & Murphy, D. (2018). Therapist empathy and client outcome: An updated meta-analysis. Psychotherapy (Chicago, Ill.), 55(4), 399–410.
Ellis, C., Hoffman, W., Jaehnert, S., Plagge, J., Loftis, J. M., Schwartz, D., & Huckans, M. (2016). Everyday problems with executive dysfunction and impulsivity in adults recovering from methamphetamine addiction. Addictive Disorders and Their Treatment, 15(1), 1.27034621
Ellis, M. S., Kasper, Z. A., & Cicero, T. J. (2018). Twin epidemics: The surging rise of methamphetamine use in chronic opioid users. Drug and Alcohol Dependence, 193, 14–20.30326396
Elramah, M., Einstein, M., Mori, N., & Vakil, N. (2012). High mortality of cocaine-related ischemic colitis: A hybrid cohort/case-control study. Gastrointestinal Endoscopy, 75(6), 1226–1232.22482921
Ersche, K. D., Williams, G. B., Robbins, T. W., & Bullmore, E. T. (2013). Meta-analysis of structural brain abnormalities associated with stimulant drug dependence and neuroimaging of addiction vulnerability and resilience. Current Opinion in Neurobiology, 23(4), 615–624.23523373
Ethier, A. R., Kim, H. S., Hodgins, D. C., & McGrath, D. S. (2020). High rollers: Correlates of problematic cocaine use among a community sample of gamblers. Journal of Gambling Studies, 36(2), 513–525.32219672
Evans, M. K., Rosenbaum, L., Malina, D., Morrissey, S., & Rubin, E. J. (2020). Diagnosing and treating systemic racism. New England Journal of Medicine, 383(3), 274–276.
Evans-Campbell, T., Walters, K. L., Pearson, C. R., & Campbell, C. D. (2012). Indian boarding school experience, substance use, and mental health among urban two-spirit American Indian/Alaska natives. American Journal of Drug and Alcohol Abuse, 38(5), 421–427.
Fakhoury, M. (2014). The addicted human brain: An overview of imaging studies and their treatment implications. Open Access Library Journal, 1(7), 1–7.
Fallin-Bennett, A., Elswick, A., & Ashford, K. (2020). Peer support specialists and perinatal opioid use disorder: Someone that's been there, lived it, seen it. Addictive Behaviors, 102, 106204.31794901
Famutimi, O., & Thompson, K. (2018). Trends in substance use treatment admissions among the homeless in the United States: 2005–2015. Journal of Public Health Issues and Practices, 2, 1–8.
Farabee, D. (2018). Current and promising pharmacotherapies for substance use disorders among justice-involved populations. European Journal on Criminal Policy and Research, 24(2), 145–153.
Farabee, D., Cousins, S. J., Brecht, M. L., Antonini, V. P., Lee, A. B., Brummer, J., … Rawson, R. A. (2013). A comparison of four telephone-based counseling styles for recovering stimulant users. Psychology of Addictive Behaviors, 27(1), 223–229.22867295
Farabee, D., McCann, M., Brecht, M. L., Cousins, S. J., Antonini, V. P., Lee, A. B., … Rawson, R. A. (2013). An analysis of relapse prevention factors and their ability to predict sustained abstinence following treatment completion. American Journal on Addictions, 22(3), 206–211.
Farkas, J. (2021, April 5). The Internet book of critical care. Sympathomimetic intoxication. https://emcrit.org/ibcc/symp/
Farooque, U., Okorie, N., Kataria, S., Shah, S. F., & Bollampally, V. C. (2020). Cocaine-induced headache: A review of pathogenesis, presentation, diagnosis, and management. Cureus, 12(8), e10128.33005542
Farrell, M., Martin, N. K., Stockings, E., Bórquez, A., Cepeda, J. A., Degenhardt, L., … McKetin, R. (2019). Responding to global stimulant use: Challenges and opportunities. Lancet, 394(10209), 1652–1667.31668409
Farren, C. K., Hill, K. P., & Weiss, R. D. (2012). Bipolar disorder and alcohol use disorder: A review. Current Psychiatry Reports, 14(6), 659–666.
Farronato, N. S., Dürsteler-Macfarland, K. M., Wiesbeck, G. A., & Petitjean, S. A. (2013). A systematic review comparing cognitive-behavioral therapy and contingency management for cocaine dependence. Journal of Addictive Diseases, 32(3), 274–287.24074193
Federal Bureau of Prisons. (2021, June 5). Offenses. Retrieved June 10, 2021, from https://www.bop.gov/about/statistics/statistics_inmate_offenses.jsp
Ferrucci, M., Limanaqi, F., Ryskalin, L., Biagioni, F., Busceti, C. L., & Fornai, F. (2019). The effects of amphetamine and methamphetamine on the release of norepinephrine, dopamine and acetylcholine from the brainstem reticular formation. Frontiers in Neuroanatomy, 13, 48.31133823
Flanagan, J. C., Korte, K. J., Killeen, T. K., & Back, S. E. (2016). Concurrent treatment of substance use and PTSD. Current Psychiatry Reports, 18(8), 70.27278509
Fleming, T., Barker, A., Ivsins, A., Vakharia, S., & McNeil, R. (2020). Stimulant safe supply: A potential opportunity to respond to the overdose epidemic. Harm Reduction Journal, 17(1), 1–6.31906957
Flentje, A., Heck, N. C., & Sorensen, J. L. (2014). Characteristics of transgender individuals entering substance abuse treatment. Addictive Behaviors, 39(5), 969–975.24561017
Fletcher, J. B., Shoptaw, S., Peck, J. A., & Reback, C. J. (2014). Contingency management reduces symptoms of psychological and emotional distress among homeless, substance-dependent men who have sex with men. Mental Health and Substance Use, 7(4), 420–430.25364379
Fletcher, J. B., Swendeman, D., & Reback, C. J. (2018). Mental health and substance use disorder comorbidity among methamphetamine-using men who have sex with men. Journal of Psychoactive Drugs, 50(3), 206–213.29608132
Fluyau, D., Mitra, P., & Lorthe, K. (2019). Antipsychotics for amphetamine psychosis: A systematic review. Frontiers in Psychiatry, 10, 740.31681046
Foltin, R. W., Haney, M., Bedi, G., & Evans, S. M. (2016). Modafinil decreases cocaine choice in human cocaine smokers only when the response requirement and the alternative reinforcer magnitude are large. Pharmacology, Biochemistry, and Behavior, 150–151, 8–13.
Foltin, R. W., Haney, M., Rubin, E., Reed, S. C., Vadhan, N., Balter, R., & Evans, S. M. (2015). Development of translational preclinical models in substance abuse: Effects of cocaine administration on cocaine choice in humans and non-human primates. Pharmacology, Biochemistry, and Behavior, 134, 12–21.
Fong, C., Matusow, H., Cleland, C. M., & Rosenblum, A. (2015). Characteristics of non-opioid substance misusers among patients enrolling in opioid treatment programs: A latent class analysis. Journal of Addictive Diseases, 34(2–3), 141–150.26075932
Food and Drug Administration. (2017, September 14). FDA permits marketing of mobile medical application for substance use disorder [Press release]. https://www.fda.gov/news-events/press-announcements/fda-permits-marketing-mobile-medical-application-substance-use-disorder
Food and Drug Administration. (2019, October 3). FDA approves second drug to prevent HIV infection as part of ongoing efforts to end the HIV epidemic [Press release]. https://www.fda.gov/news-events/press-announcements/fda-approves-second-drug-prevent-hiv-infection-part-ongoing-efforts-end-hiv-epidemic
Forray, A., & Foster, D. (2015). Substance use in the perinatal period. Current Psychiatry Reports, 17(11), 91.26386836
Foster, M. A., Hofmeister, M. G., Kupronis, B. A., Lin, Y., Xia, G.-L., Yin, S., & Teshale, E. (2019). Increase in hepatitis A virus infections – United States, 2013–2018. Morbidity and Mortality Weekly Report, 68(18), 413–415.
Foulds, J. A., Boden, J. M., McKetin, R., & Newton-Howes, G. (2020). Methamphetamine use and violence: Findings from a longitudinal birth cohort. Drug and Alcohol Dependence, 207, 107826.31927159
Fratto, G., & Manzon, L. (2014). Use of psychotropic drugs and associated dental diseases. International Journal of Psychiatry in Medicine, 48(3), 185–197.25492713
Frazer, Z., McConnell, K., & Jansson, L. M. (2019). Treatment for substance use disorders in pregnant women: Motivators and barriers. Drug and Alcohol Dependence, 205, 107652.31704383
Freeborn, K., & Portillo, C. J. (2018). Does pre-exposure prophylaxis for HIV prevention in men who have sex with men change risk behaviour? A systematic review. Journal of Clinical Nursing, 27(17–18), 3254–3265.28771856
Friedman, S. M., Margo, C. E., Konicki, M., Campanelli, M., Jampol, L. M., & Plous, O. Z. (2010). Bilateral vascular occlusions of the anterior visual pathway and cocaine abuse. Retinal Cases and Brief Reports, 4(2), 95–98.25390373
Friesen, B. J., Cross, T. L., Jivanjee, P., Thirstrup, A., Bandurraga, A., Gowen, L. K., & Rountree, J. (2015). Meeting the transition needs of urban American Indian/Alaska Native youth through culturally based services. Journal of Behavioral Health Services and Research, 42(2), 191–205.25388647
Galloway, G. P., Singleton, E. G., Buscemi, R., Baggott, M. J., Dickerhoof, R. M., & Mendelson, J. E. (2010). An examination of drug craving over time in abstinent methamphetamine users. American Journal on Addictions, 19(6), 510–514.
Garg, L., Akbar, G., Agrawal, S., Agarwal, M., Khaddour, L., Handa, R., … Dalal, B. D. (2017). Drug-induced pulmonary arterial hypertension: A review. Heart Failure Reviews, 22(3), 289–297.28417295
Garofalo, R., Hotton, A. L., Kuhns, L. M., Gratzer, B., & Mustanski, B. (2016). Incidence of HIV infection and sexually transmitted infections and related risk factors among very young men who have sex with men. Journal of Acquired Immune Deficiency Syndromes, 72(1), 79–86.26745827
Gastfriend, D. R. (2018, March 14). Contingency management: The greatest unused treatment in opioid use disorder [Webinar handout]. Florida Alcohol and Drug Abuse Association.
Geisner, I. M., Huh, D., Cronce, J. M., Lostutter, T. W., Kilmer, J., & Larimer, M. E. (2016). Exploring the relationship between stimulant use and gambling in college students. Journal of Gambling Studies, 32(3), 1001–1016.26691633
Genberg, B. L., Astemborski, J., Vlahov, D., Kirk, G. D., & Mehta, S. H. (2015). Incarceration and injection drug use in Baltimore, Maryland. Addiction, 110(7), 1152–1159.25845621
George, T. C., Freet, D. J., Cross, J. M., & Huzar, T. F. (2019). Levamisole-induced vasculitis. Journal of the American Academy of Physician Assistants, 32(1), 23–27.
Gerstein, D. R., Johnson, R. A., Harwood, H. J., Fountain, D., Suter, N., & Malloy, K. (Eds.). (1994). Evaluating recovery services: The California Drug and Alcohol Treatment Assessment (CALDATA). California Department of Alcohol and Drug Programs, Resource Center.
Gibson, B. A., Ghosh, D., Morano, J. P., & Altice, F. L. (2014). Accessibility and utilization patterns of a mobile medical clinic among vulnerable populations. Health and Place, 28, 153–166.24853039
Giorgetti, R., Tagliabracci, A., Schifano, F., Zaami, S., Marinelli, E., & Busardò, F. P. (2017). When “chems” meet sex: A rising phenomenon called “chemsex.” Current Neuropharmacology, 15(5), 762–770.27855594
Giovazolias, T., & Themeli, O. (2014). Social learning conceptualization for substance abuse: Implications for therapeutic interventions. European Journal of Counselling Psychology, 3(1), 69–88.
Gizzi, M. C., & Gerkin, P. (2010). Methamphetamine use and criminal behavior. International Journal of Offender Therapy and Comparative Criminology, 54(6), 915–936.19910511
Glasner-Edwards, S., & Mooney, L. J. (2014). Methamphetamine psychosis: Epidemiology and management. CNS Drugs, 28(12), 1115–1126.25373627
Glasner-Edwards, S., Mooney, L. J., Ang, A., Garneau, H. C., Hartwell, E., Brecht, M. L., & Rawson, R. A. (2017). Mindfulness-Based Relapse Prevention for stimulant dependent adults: A pilot randomized clinical trial. Mindfulness, 8(1), 126–135.28191264
Glasner-Edwards, S., Mooney, L. J., Ang, A., Hillhouse, M., & Rawson, R. (2013). Does posttraumatic stress disorder (PTSD) affect post-treatment methamphetamine use? Journal of Dual Diagnosis, 9(2), 123–128.24065875
Glass, J. E., Nunes, E. V., & Bradley, K. A. (2020, March 11). Contingency management: A highly effective treatment for substance use disorders and the legal barriers that stand in its way. Health Affairs Blog. https://www.healthaffairs.org/do/10.1377/hblog20200305.965186/full/
Glynn, T. R., & van den Berg, J. J. (2017). A systematic review of interventions to reduce problematic substance use among transgender individuals: A call to action. Transgender Health, 2(1), 45–59.28861547
Godinet, M. T., McGlinn, L., Nelson, D., & Vakalahi, H. O. (2020). Factors contributing to substance misuse treatment completion among Native Hawaiians, Other Pacific Islanders, and Asian Americans. Substance Use and Misuse, 55(1), 133–146.31846599
Goel, N., Pullman, J. M., & Coco, M. (2014). Cocaine and kidney injury: A kaleidoscope of pathology. Clinical Kidney Journal, 7(6), 513–517.25859366
Goldstein, R. B., Smith, S. M., Chou, S. P., Saha, T. D., Jung, J., Zhang, H., … Grant, B. F. (2016). The epidemiology of DSM-5 posttraumatic stress disorder in the United States: Results from the National Epidemiologic Survey on Alcohol and Related Conditions–III. Social Psychiatry and Psychiatric Epidemiology, 51(8), 1137–1148.27106853
González-Baeza, A., Dolengevich-Segal, H., Pérez-Valero, I., Cabello, A., Téllez, M. J., Sanz, J., … Ryan, P. (2018). Sexualized drug use (chemsex) is associated with high-risk sexual behaviors and sexually transmitted infections in HIV-positive men who have sex with men: Data from the U-SEX GESIDA 9416 study. AIDS Patient Care and STDs, 32(3), 112–118.29620925
Gouin, K., Murphy, K., Shah, P. S., & Knowledge Synthesis Group on Determinants of Low Birth Weight and Preterm Births. (2011). Effects of cocaine use during pregnancy on low birthweight and preterm birth: Systematic review and meta-analyses. American Journal of Obstetrics and Gynecology, 204(4), 340.e1–340.e12.21257143
Gould, T. J. (2010). Addiction and cognition. Addiction Science and Clinical Practice, 5(2), 4–14.22002448
Government Accountability Office. (n.d.). Tribal and Native American issues. https://www.gao.gov/tribal-and-native-american-issues
Gowin, J. L., Ernst, M., Ball, T., May, A. C., Sloan, M. E., Tapert, S. F., & Paulus, M. P. (2019). Using neuroimaging to predict relapse in stimulant dependence: A comparison of linear and machine learning models. NeuroImage: Clinical, 21, 101676.30665102
Granado, N., Ares-Santos, S., & Moratalla, R. (2013). Methamphetamine and Parkinson's disease. Parkinson's Disease, 2013, 308052.
Grant, B. F., Chou, S. P., Saha, T. D., Pickering, R. P., Kerridge, B. T., Ruan, W. J., … Hasin, D. S. (2017). Prevalence of 12-month alcohol use, high-risk drinking, and DSM-IV alcohol use disorder in the United States, 2001–2002 to 2012–2013: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. JAMA Psychiatry, 74(9), 911–923.28793133
Grant, B. F., Goldstein, R. B., Saha, T. D., Chou, S. P., Jung, J., Zhang, H., … Hasin, D. S. (2015). Epidemiology of DSM-5 alcohol use disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions–III. JAMA Psychiatry, 72(8), 757–766.26039070
Grant, B. F., Saha, T. D., Ruan, W. J., Goldstein, R. B., Chou, S. P., Jung, J., … Hasin, D. S. (2016). Epidemiology of DSM-5 drug use disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions–III. JAMA Psychiatry, 73(1), 39–47.26580136
Grant, J. M., Mottet, L. A., Tanis, J., Harrison, J., Herman, J. L., & Keisling, M. (2011). Injustice at every turn: A report of the National Transgender Discrimination Survey. National Center for Transgender Equality and National Gay and Lesbian Task Force.
Grant, S., Colaiaco, B., Motala, A., Shanman, R., Booth, M., Sorbero, M., & Hempel, S. (2017). Mindfulness-Based Relapse Prevention for substance use disorders: A systematic review and meta-analysis. Journal of Addiction Medicine, 11(5), 386–396.28727663
Greydanus, D. E. (2006). Stimulant misuse: Strategies to manage a growing problem. In Use and misuse of stimulants: A guide for school health professionals (pp. 17–23). American College Health Association.
Griffin, D., & Cha, S. (2019). Cocaine: A provoking risk factor in venous thromboembolism. Cureus, 11(12), e6520.32025439
Grigg, J., Manning, V., Arunogiri, S., Volpe, I., Frei, M., Phan, V., … Lubman D. I. (2018). Methamphetamine treatment guidelines: Practice guidelines for health professionals (2nd ed.). Turning Point.
Grund, J.-P., Coffin, P., & Jauffret-Roustide, M., Dijkstra, M., Bruin, D., & Blanken, P. (2010). The fast and furious: Cocaine, amphetamines and harm reduction. In T. Rhodes & D. Hedrich (Eds.), Harm reduction: Evidence, impact and challenges (pp. 205–254). Publications Office of the European Union.
Guck, D., & Munyon, R. (2018). Bilateral spontaneous pneumothoraces with spontaneous pneumomediastinum: An intravenous methamphetamine complication. Respiratory Medicine Case Reports, 25, 4–5.29872631
Guina, J., & Merrill, B. (2018). Benzodiazepines I: Upping the care on downers—The evidence of risks, benefits, and alternatives. Journal of Clinical Medicine, 7(2), 17.
Hadland, S. E., Yule, A. M., Levy, S. J., Hallett, E., Silverstein, M., & Bagley, S. M. (2021). Evidence-based treatment of young adults with substance use disorders. Pediatrics, 147(Suppl. 2), S204–S214.33386323
Hall, M. G., Alhassoon, O. M., Stern, M. J., Wollman, S. C., Kimmel, C. L., Perez-Figueroa, A., & Radua, J. (2015). Gray matter abnormalities in cocaine versus methamphetamine-dependent patients: A neuroimaging meta-analysis. American Journal of Drug and Alcohol Abuse, 41(4), 290–299.
Hall, M. G., Hauson, A. O., Wollman, S. C., Allen, K. E., Connors, E. J., Stern, M. J., … Grant, I. (2018). Neuropsychological comparisons of cocaine versus methamphetamine users: A research synthesis and meta-analysis. American Journal of Drug and Alcohol Abuse, 44(3), 277–293.
Halpin, L. E., Collins, S. A., & Yamamoto, B. K. (2014). Neurotoxicity of methamphetamine and 3,4-methylenedioxymethamphetamine. Life Sciences, 97(1), 37–44.23892199
Hammoud, M. A., Vaccher, S., Jin, F., Bourne, A., Haire, B., Maher, L., … Prestage, G. (2018). The new MTV generation: Using methamphetamine, Truvada^TM^, and Viagra^TM^ to enhance sex and stay safe. International Journal of Drug Policy, 55, 197–204.29526546
Han, Y., Lin, V., Wu, F., & Hser, Y.-I. (2016). Gender comparisons among Asian American and Pacific Islander patients in drug dependency treatment. Substance Use and Misuse, 51(6), 752–762.27070174
Han, Y., Yan, W., Zheng, Y., Khan, M. Z., Yuan, K., & Lu, L. (2019). The rising crisis of illicit fentanyl use, overdose, and potential therapeutic strategies. Translational Psychiatry, 9(1), 1–9.30664621
Hanieh, E., Musa, A.-R., & Jureidini, J. (2013). The AGRO+ model.
Harada, T., Tsutomi, H., Mori, R., & Wilson, D. B. (2018). Cognitive–behavioural treatment for amphetamine–type stimulants (ATS)–use disorders. Cochrane Database of Systematic Reviews. 10.1002/14651858.CD011315.pub2
Hargraves, D., White, C., Frederick, R., Cinibulk, M., Peters, M., Young, A., & Elder, N. (2017). Implementing SBIRT (Screening, Brief Intervention and Referral to Treatment) in primary care: Lessons learned from a multi-practice evaluation portfolio. Public Health Reviews, 38, 31.29450101
Hariri, L., & Patel, J. (2021). Vasodilators. In StatPearls. https://www.ncbi.nlm.nih.gov/books/NBK554423/
Harris, A. M., Iqbal, K., Schillie, S., Britton, J., Kainer, M. A., Tressler, S., & Vellozzi, C. (2016). Increases in acute hepatitis B virus infections – Kentucky, Tennessee, and West Virginia, 2006–2013. Morbidity and Mortality Weekly Report, 65(3), 47–50.26821369
Harrison, J., Grant, J., & Herman, J. L. (2012). A gender not listed here: Genderqueers, gender rebels and otherwise in the National Transgender Discrimination Study. LGBT Policy Journal at the Harvard Kennedy School, 2, 13–24.
Harro, J. (2015). Neuropsychiatric adverse effects of amphetamine and methamphetamine. International Review of Neurobiology, 120, 179–204.26070758
Hart, C. L., Csete, J., & Habibi, D. (2014). Methamphetamine: Fact vs. fiction and lessons from the crack hysteria. https://www.opensocietyfoundations.org/publications/methamphetamine-dangers-exaggerated#publications_download
Hart, C. L., Marvin, C. B., Silver, R., & Smith, E. E. (2012). Is cognitive functioning impaired in methamphetamine users? A critical review. Neuropsychopharmacology, 37(3), 586–608.22089317
Hartnett, K. P., Jackson, K. A., Felsen, C., McDonald, R., Bardossy, A. C., Gokhale, R. H., … Dumyati, G. (2019). Bacterial and fungal infections in persons who inject drugs—Western New York, 2017. Morbidity and Mortality Weekly Report, 68(26), 583–586.31269011
Hartwell, E. E., Moallem, N. R., Courtney, K. E., Glasner-Edwards, S., & Ray, L. A. (2016). Sex differences in the association between internalizing symptoms and craving in methamphetamine users. Journal of Addiction Medicine, 10(6), 395–401.27504928
Hartwell, K., & Brady, K. (2018). Determining appropriate levels of care for treatment of substance use disorders. UpToDate. Retrieved March 19, 2021, from https://www.uptodate.com/contents/determining-appropriate-levels-of-care-for-treatment-of-substance-use-disorders
Hartzler, B., & Garrett, S. (2016). Interest and preferences for contingency management design among addiction treatment clientele. American Journal of Drug and Alcohol Abuse, 42(3), 287–295.
Hasin, D. S., & Grant, B. F. (2015). The National Epidemiologic Survey on Alcohol and Related Conditions (NESARC) Waves 1 and 2: Review and summary of findings. Social Psychiatry and Psychiatric Epidemiology, 50(11), 1609–1640.26210739
Hasin, D., & Kilcoyne, B. (2012). Comorbidity of psychiatric and substance use disorders in the United States: Current issues and findings from the NESARC. Current Opinion in Psychiatry, 25(3), 165–171.22449770
Hasin, D. S., Sarvet, A. L., Meyers, J. L., Saha, T. D., Ruan, W. J., Stohl, M., & Grant, B. F. (2018). Epidemiology of Adult DSM-5 major depressive disorder and its specifiers in the United States. JAMA Psychiatry, 75(4), 336–346.29450462
Havakuk, O., Rezkalla, S. H., & Kloner, R. A. (2017). The cardiovascular effects of cocaine. Journal of the American College of Cardiology, 70(1), 101–113.28662796
Hawk, K., & D'Onofrio, G. (2018). Emergency department screening and interventions for substance use disorders. Addiction Science and Clinical Practice, 13(1), 1–6.29370875
Hayley, A. C., Downey, L. A., Shiferaw, B., & Stough, C. (2016). Amphetamine-type stimulant use and the risk of injury or death as a result of a road-traffic accident: A systematic review of observational studies. European Neuropsychopharmacology, 26(6), 901–922.27006144
Heal, D. J., Smith, S. L., Gosden, J., & Nutt, D. J. (2013). Amphetamine, past and present: A pharmacological and clinical perspective. Journal of Psychopharmacology, 27(6), 479–496.23539642
Healthy People 2030. (n.d.). Social determinants of health. U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. https://health.gov/healthypeople/objectives-and-data/social-determinants-health
Hedegaard, H., Bastian, B. A., Trinidad, J. P., Spencer, M., & Warner, M. (2018). Drugs most frequently involved in drug overdose deaths: United States, 2011–2016. National Vital Statistics Reports, 67(9), 1–14.
Hedges, D. M., Obray, J. D., Yorgason, J. T., Jang, E. Y., Weerasekara, V. K., Uys, J. D., Bellinger, F. P., & Steffensen, S. C. (2018). Methamphetamine induces dopamine release in the nucleus accumbens through a sigma receptor-mediated pathway. Neuropsychopharmacology, 43(6), 1405–1414.29185481
Hellem, T., Shi, X., Latendresse, G., & Renshaw, P. F. (2015). The utility of magnetic resonance spectroscopy for understanding substance use disorders: A systematic review of the literature. Journal of the American Psychiatric Nurses Association, 21(4), 244–275.26282670
Hellem, T. L., Lundberg, K. J., & Renshaw, P. F. (2015). A review of treatment options for co-occurring methamphetamine use disorders and depression. Journal of Addictions Nursing, 26(1), 14–23; quiz E1.25761159
Hendershot, C. S., Witkiewitz, K., George, W. H., & Marlatt, G. A. (2011). Relapse prevention for addictive behaviors. Substance Abuse Treatment, Prevention, and Policy, 6, 17.
Henning, A., Kurtom, M., & Espiridion, E. D. (2019). A case study of acute stimulant-induced psychosis. Cureus, 11(2), e4126.31049275
Hennissen, L., Bakker, M. J., Banaschewski, T., Carucci, S., Coghill, D., Danckaerts, M., … Buitelaar, J. K. (2017). Cardiovascular effects of stimulant and non-stimulant medication for children and adolescents with ADHD: A systematic review and meta-analysis of trials of methylphenidate, amphetamines and atomoxetine. CNS Drugs, 31(3), 199–215.28236285
Herbeck, D. M., Brecht, M. L., Christou, D., & Lovinger, K. (2014). A qualitative study of methamphetamine users' perspectives on barriers and facilitators of drug abstinence. Journal of Psychoactive Drugs, 46(3), 215–225.25052880
Hetea, A., Cosconel, C., Stanescu, A. A. M., & Simionescu, A. A. (2019). Alcohol and psychoactive drugs in pregnancy. Maedica, 14(4), 397–401.32153672
Hibbert, M. P., Porcellato, L. A., Brett, C. E., & Hope, V. D. (2019). Associations with drug use and sexualised drug use among women who have sex with women (WSW) in the UK: Findings from the LGBT Sex and Lifestyles Survey. International Journal of Drug Policy, 74, 292–298.31358403
Hirshfield, S., Schrimshaw, E. W., Stall, R. D., Margolis, A. D., Downing, Jr., M. J., & Chiasson, M. A. (2015). Drug use, sexual risk, and syndemic production among men who have sex with men who engage in group sexual encounters. American Journal of Public Health, 105(9), 1849–1858.25713951
Hodgkins, P., Shaw, M., Coghill, D., & Hechtman, L. (2012). Amfetamine and methylphenidate medications for attention-deficit/hyperactivity disorder: Complementary treatment options. European Child and Adolescent Psychiatry, 21(9), 477–492.22763750
Hoffman, R. S. (2010). Treatment of patients with cocaine-induced arrhythmias: Bringing the bench to the bedside. British Journal of Clinical Pharmacology, 69(5), 448–457.20573080
Hoffman, W. F., Jacobs, M. B., Dennis, L. E., McCready, H. D., Hickok, A. W., Smith, S. B., & Kohno, M. (2020). Psychopathy and corticostriatal connectivity: The link to criminal behavior in methamphetamine dependence. Frontiers in Psychiatry, 11, 90.32180738
Holmskov, M., Storebø, O. J., Moreira-Maia, C. R., Ramstad, E., Magnusson, F. L., Krogh, H. B., … Simonsen, E. (2017). Gastrointestinal adverse events during methylphenidate treatment of children and adolescents with attention deficit hyperactivity disorder: A systematic review with meta-analysis and Trial Sequential Analysis of randomised clinical trials. PLoS One, 12(6), e0178187.28617801
Holmwood, C., & Gowing, L. (2019). Acute presentations related to methamphetamine use clinical guideline for adults (Version No. 2.0, Clinical Guideline No.: CG284). Government of South Australia, SA Health.
Holt, L. J., Schepis, T. S., Looby, A., Marsh, E., Marut, P., & Feinn, R. (2020). How to say “no” most effectively: Evaluating resistance strategies for prescription stimulant diversion to inform preventive interventions. Journal of American College Health, 68(8), 872–882.31241417
Hser, Y.-I., Evans, E., Huang, D., Weiss, R., Saxon, A., Carroll, K. M., … Ling, W. (2016). Long-term outcomes after randomization to buprenorphine/naloxone versus methadone in a multi-site trial. Addiction, 111(4), 695–705.26599131
Hser, Y.-I., & Mooney, L. J. (2021). Integrating telemedicine for medication treatment for opioid use disorder in rural primary care: Beyond the COVID pandemic. Journal of Rural Health, 37(1), 246–248.
Hulsebos, I. F., Pham, C. H., Collier, Z. J., Fang, M., Vrouwe, S. Q., Sugiyama, A., … Gillenwater, J. (2020). Stimulant abuse in burn patients is associated with an increased use of hospital resources. Journal of Burn Care and Research, 41(5), 921–925.32542360
Human Rights Campaign. (n.d.). Transgender and non-binary people FAQ. https://www.hrc.org/resources/transgender-and-non-binary-faq
Hunt, D., Kuck, S., & Truitt, L. (2006). Methamphetamine use: Lessons learned. Abt Associates.
Hunt, G. E., Siegfried, N., Morley, K., Sitharthan, T., & Cleary, M. (2019). Psychosocial interventions for people with both severe mental illness and substance misuse. Schizophrenia Bulletin, 40(1), 18–20.
Huybrechts, K. F., Bröms, G., Christensen, L. B., Einarsdóttir, K., Engeland, A., Furu, K., … Bateman, B. T. (2018). Association between methylphenidate and amphetamine use in pregnancy and risk of congenital malformations: A cohort study from the International Pregnancy Safety Study Consortium. JAMA Psychiatry, 75(2), 167–175.29238795
Indave, B. I., Sordo, L., Bravo, M. J., Sarasa–Renedo, A., Fernández–Balbuena, S., De la Fuente, L., … Barrio, G. (2018). Risk of stroke in prescription and other amphetamine–type stimulants use: A systematic review. Drug and Alcohol Review, 37(1), 56–69.28485090
Indian Health Service. (n.d.). Two-Spirit. https://www.ihs.gov/lgbt/health/twospirit/
Iqbal, K., Klevens, R. M., Kainer, M. A., Baumgartner, J., Gerard, K., Poissant, T., … Teshale, E. (2015). Epidemiology of acute hepatitis B in the United States from population-based surveillance, 2006–2011. Clinical Infectious Diseases, 61(4), 584–592.25904365
Jackson, K. A., Bohm, M. K., Brooks, J. T., Asher, A., Nadle, J., Bamberg, W. M., … See, I. (2018). Invasive methicillin-resistant Staphylococcus aureus infections among persons who inject drugs—Six sites, 2005–2016. Morbidity and Mortality Weekly Report, 67(22), 625–628.29879096
Jaffe, A., Molnar, S., Williams, N., Wong, E., Todd, T., Caputo, C., … Ye, S. (2016). Review and recommendations for drug testing in substance use treatment contexts. Journal of Reward Deficiency Syndrome and Addiction Science, 2(1), 28–45.
Jan, R. K., Kydd, R. R., & Russell, B. R. (2012). Functional and structural brain changes associated with methamphetamine abuse. Brain Sciences, 2(4), 434–482.24961256
Javanbakht, M., Ragsdale, A., Shoptaw, S., & Gorbach, P. M. (2019). Transactional sex among men who have sex with men: Differences by substance use and HIV status. Journal of Urban Health, 96(3), 429–441.30136249
Jeal, N., Macleod, J., Turner, K., & Salisbury, C. (2015). Systematic review of interventions to reduce illicit drug use in female drug-dependent street sex workers. BMJ Open, 5(11), e009238.
Ji, Y., Kujtan, L., & Kershner, D. (2012). Acute endocarditis in intravenous drug users: A case report and literature review. Journal of Community Hospital Internal Medicine Perspectives, 2(1).
Jiménez-Correa, U., Santana-Miranda, R., Barrera-Medina, A., Martínez-Núñez, J. M., Marín-Agudelo, H. A., Poblano, A., … Hernández-Berber, I. (2020). Parasomnias in patients with addictions—A systematic review. CNS Spectrums, 1–8.
Johns Hopkins Medicine. (n.d.-a). Status epilepticus. https://www.hopkinsmedicine.org/health/conditions-and-diseases/status-epilepticus
Johns Hopkins Medicine. (n.d.-b). Thrombotic microangiopathy. https://www.hopkinsmedicine.org/nephrology/tm_sperati
Johnston, L. D., Miech, R. A., O'Malley, P. M., Bachman, J. G., Schulenberg, J. E., & Patrick, M. E. (2020). Monitoring the Future National Survey Results on Drug Use 1975–2019: Overview, key findings on adolescent drug use. University of Michigan, Institute for Social Research.
Jones, A. W. (2019). Forensic drug profile: Cocaethylene. Journal of Analytical Toxicology, 43(3), 155–160.30796807
Jones, C. M., Compton, W. M., & Mustaquim, D. (2020). Patterns and characteristics of methamphetamine use among adults—United States, 2015–2018. Morbidity and Mortality Weekly Report, 69(12), 317–323.32214077
Jones, P., Mutsvunguma, R., & Prahlow, J. A. (2014). Accidental death via intravaginal absorption of methamphetamine. Forensic Science, Medicine, and Pathology, 10(2), 234–238.
Jordan, A., Babuscio, T., Nich, C., & Carroll, K. M. (2021). A feasibility study providing substance use treatment in the Black church. Journal of Substance Abuse Treatment, 124, 108218.33771290
Jordan, A. E., Perlman, D. C., Neurer, J., Smith, D. J., Des Jarlais, D. C., & Hagan, H. (2017). Prevalence of hepatitis C virus infection among HIV+ men who have sex with men: A systematic review and meta-analysis. International Journal of STD and AIDS, 28(2), 145–159.26826159
Kadri, A. N., Wilner, B., Hernandez, A. V., Nakhoul, G., Chahine, J., Griffin, B., … Harb, S. C. (2019). Geographic trends, patient characteristics, and outcomes of infective endocarditis associated with drug abuse in the United States from 2002 to 2016. Journal of the American Heart Association, 8(19), e012969.31530066
Kalvar, A., & Medaglia, J. D. (2018). Evidence of brain modularity. In T. K. Shackelford & V. A. Weekes-Shackelford (Eds.), Encyclopedia of evolutionary psychological science. Springer International Publishing.
Kampman, K. M. (2019). The treatment of cocaine use disorder. Science Advances, 5(10), eaax1532.31663022
Kampman, K., & Jarvis, M. (2015). American Society of Addiction Medicine (ASAM) national practice guideline for the use of medications in the treatment of addiction involving opioid use. Journal of Addiction Medicine, 9(5), 358–367.26406300
Kaplan, G. B., Heinrichs, S. C., & Carey, R. J. (2011). Treatment of addiction and anxiety using extinction approaches: Neural mechanisms and their treatment implications. Pharmacology, Biochemistry, and Behavior, 97(3), 619–625.
Kariisa, M., Scholl, L., Wilson, N., Seth, P., & Hoots, B. (2019). Drug overdose deaths involving cocaine and psychostimulants with abuse potential—United States, 2003–2017. Morbidity and Mortality Weekly Report, 68(17), 388–395.31048676
Karila, L., Weinstein, A., Aubin, H. J., Benyamina, A., Reynaud, M., & Batki, S. L. (2010). Pharmacological approaches to methamphetamine dependence: A focused review. British Journal of Clinical Pharmacology, 69(6), 578–592.20565449
Katzman, M. A., Bilkey, T. S., Chokka, P. R., Fallu, A., & Klassen, L. J. (2017). Adult ADHD and comorbid disorders: Clinical implications of a dimensional approach. BMC Psychiatry, 17(1), 302. 28830387
Kaye, S., Darke, S., & Torok, M. (2013). Attention deficit hyperactivity disorder (ADHD) among illicit psychostimulant users: A hidden disorder? Addiction, 108(5), 923–931.23227816
Keane, T. M., Rubin, A., Lachowicz, M., Brief, D., Enggasser, J. L., Roy, M., … Rosenbloom, D. (2014). Temporal stability of DSM-5 posttraumatic stress disorder criteria in a problem-drinking sample. Psychological Assessment, 26(4), 1138–1145.24932642
Kecojevic, A., Corliss, H. L., & Lankenau, S. E. (2015). Motivations for prescription drug misuse among young men who have sex with men (YMSM) in Philadelphia. International Journal of Drug Policy, 26(8), 764–771.25936445
Kecojevic, A., Jun, H.-J., Reisner, S. L., & Corliss, H. L. (2017). Concurrent polysubstance use in a longitudinal study of US youth: Associations with sexual orientation. Addiction, 112(4), 614–624.27790758
Kelly, T. M., & Daley, D. C. (2013). Integrated treatment of substance use and psychiatric disorders. Social Work in Public Health, 28(3–4), 388–406.23731427
Kerner, B. (2015). Comorbid substance use disorders in schizophrenia: A latent class approach. Psychiatry Research, 225(3), 395–401.25576367
Kerridge, B. T., Chou, S. P., Pickering, R. P., Ruan, W. J., Huang, B., Jung, J., … Hasin, D. S. (2019). Changes in the prevalence and correlates of cocaine use and cocaine use disorder in the United States, 2001–2002 and 2012–2013. Addictive Behaviors, 90, 250–257.30471553
Kesby, J. P., Eyles, D. W., McGrath, J. J., & Scott, J. G. (2018). Dopamine, psychosis and schizophrenia: The widening gap between basic and clinical neuroscience. Translational Psychiatry, 8(1), 1–12.29317594
Kessler, R. C., Petukhova, M., Sampson, N. A., Zaslavsky, A. M., & Wittchen, H. U. (2012). Twelve-month and lifetime prevalence and lifetime morbid risk of anxiety and mood disorders in the United States. International Journal of Methods in Psychiatric Research, 21(3), 169–184.22865617
Keuroghlian, A. S., Reisner, S. L., White, J. M., & Weiss, R. D. (2015). Substance use and treatment of substance use disorders in a community sample of transgender adults. Drug and Alcohol Dependence, 152, 139–146.25953644
Kevil, C. G., Goeders, N. E., Woolard, M. D., Bhuiyan, M. S., Dominic, P., Kolluru, G. K., … Orr, A. W. (2019). Methamphetamine use and cardiovascular disease. Arteriosclerosis, Thrombosis, and Vascular Biology, 39(9), 1739–1746.
Kidd, J. D., Goetz, T. G., Shea, E. A., & Bockting, W. O. (2021). Prevalence and minority-stress correlates of past 12-month prescription drug misuse in a national sample of transgender and gender nonbinary adults: Results from the US Transgender Survey. Drug and Alcohol Dependence, 219, 108474.33360852
Kiluk, B. D., Babuscio, T. A., Nich, C., & Carroll, K. M. (2013). Smokers versus snorters: Do treatment outcomes differ according to route of cocaine administration? Experimental and Clinical Psychopharmacology, 21(6), 490–498.24364538
Kilwein, T. M., Goodman, E. L., Looby, A., & De Young, K. P. (2016). Nonmedical prescription stimulant use for suppressing appetite and controlling body weight is uniquely associated with more severe eating disorder symptomatology. International Journal of Eating Disorders, 49(8), 813–816.
Kim, D. (2021, April 1). Too well-off to seek help?: The model minority myth of Asian Americans [Blog post]. https://adaa.org/learn-from-us/from-the-experts/blog-posts/professional/too-well-seek-help-model-minority-myth-asian
Kim, S. T., & Park, T. (2019). Acute and chronic effects of cocaine on cardiovascular health. International Journal of Molecular Sciences, 20(3), 584.
Kimbrough, A., Smith, L. C., Kallupi, M., Simpson, S., Collazo, A., & George, O. (2019). Characterization of the brain functional architecture of psychostimulant withdrawal using single-cell whole brain imaging. bioRxiv. 10.1101/743799
King, K. A., Vidourek, R. A., & Yockey, R. A. (2019). Social determinants to lifetime methamphetamine use among a national sample of adults. Journal of Substance Use, 24(4), 388–393.
Kirby, K. C., Benishek, L. A., & Tabit, M. B. (2016). Contingency management works, clients like it, and it is cost-effective. American Journal of Drug and Alcohol Abuse, 42(3), 250–253.
Kirby, K. C., Carpenedo, C. M., Dugosh, K. L., Rosenwasser, B. J., Benishek, L. A., Janik, A., … Silverman, K. (2013). Randomized clinical trial examining duration of voucher-based reinforcement therapy for cocaine abstinence. Drug and Alcohol Dependence, 132(3), 639–645.23680075
Kish, S. J., Boileau, I., Callaghan, R. C., & Tong, J. (2017). Brain dopamine neurone ‘damage’: Methamphetamine users vs. Parkinson's disease; A critical assessment of the evidence. European Journal of Neuroscience, 45(1), 58–66.
Kittirattanapaiboon, P., Srikosai, S., & Wittayanookulluk, A. (2017). Methamphetamine use and dependence in vulnerable female populations. Current Opinion in Psychiatry, 30(4), 247–252.28426546
Kiyatkin, E. A. (2019). Respiratory depression and brain hypoxia induced by opioid drugs: Morphine, oxycodone, heroin, and fentanyl. Neuropharmacology, 151, 219–226.30735692
Klassen, L. J., Bilkey, T. S., Katzman, M. A., & Chokka, P. (2012). Comorbid attention deficit/hyperactivity disorder and substance use disorder: Treatment considerations. Current Drug Abuse Reviews, 5(3), 190–198.22571450
Klega, A. E., & Keehbauch, J. T. (2018). Stimulant and designer drug use: Primary care management. American Family Physician, 98(2), 85–92.30215997
Klein, M. O., Battagello, D. S., Cardoso, A. R., Hauser, D. N., Bittencourt, J. C., & Correa, R. G. (2019). Dopamine: Functions, signaling, and association with neurological diseases. Cellular and Molecular Neurobiology, 39(1), 31–59.30446950
Klevens, R. M., Hu, D. J., Jiles, R., & Holmberg, S. D. (2012). Evolving epidemiology of hepatitis C virus in the United States. Clinical Infectious Diseases, 55(Suppl. 1), S3–S9.22715211
Kleykamp, B. A., Guille, C., Barth, K. S., & McClure, E. A. (2020). Substance use disorders and COVID-19: The role of telehealth in treatment and research. Journal of Social Work Practice in the Addictions, 20(3), 248–253.
Kloss, B. T., Broton, C. E., & Rodriguez, E. (2010). Pneumomediastinum from nasal insufflation of cocaine. International Journal of Emergency Medicine, 3, 435–437.21373317
Klostermann, K., Kelley, M. L., Mignone, T., Pusateri, L., & Wills, K. (2011). Behavioral couples therapy for substance abusers: Where do we go from here? Substance Use and Misuse, 46(12), 1502–1509.21707469
Knapp, W. P., Soares, B. G., Farrel, M., & Lima, M. S. (2007). Psychosocial interventions for cocaine and psychostimulant amphetamines related disorders. Cochrane Database of Systematic Reviews. 10.1002/14651858.CD003023.pub2
Knight, K. (2020). Structural factors that affect life contexts of pregnant people with opioid use disorders: The role of structural racism and the need for structural competency. Women's Reproductive Health, 7, 164–171.
Kober, H. H. (2014). Emotion regulation in substance use disorders. In J. J. Gross (Ed.), Handbook of emotion regulation (pp. 428–446). Guilford Press.
Komaromy, M., Mendez-Escobar, E., & Madden, E. (2021). Addressing racial trauma in the treatment of substance use disorders. Pediatrics, 147(Suppl. 2), S268–S270.33386331
Koob, G. F., & Volkow, N. D. (2016). Neurobiology of addiction: A neurocircuitry analysis. Lancet Psychiatry, 3(8), 760–773.27475769
Köpetz, C. E., Lejuez, C. W., Wiers, R. W., & Kruglanski, A. W. (2013). Motivation and self-regulation in addiction: A call for convergence. Perspectives on Psychological Science, 8(1), 3–24.26069472
Kousik, S. M., Napier, T. C., & Carvey, P. M. (2012). The effects of psychostimulant drugs on blood brain barrier function and neuroinflammation. Frontiers in Pharmacology, 3, 121.22754527
Krakowski, A., & Ickowicz, A. (2018). Stimulant withdrawal in a child with autism spectrum disorder and ADHD: A case report. Journal of the Canadian Academy of Child and Adolescent Psychiatry, 27(2), 148–151.29662527
Kral, A. H., Lambdin, B. H., Comfort, M., Powers, C., Cheng, H., Lopez, A. M., … Lorvick, J. (2018). A strengths-based case management intervention to reduce HIV viral load among people who use drugs. AIDS and Behavior, 22(1), 146–153.28916898
Krans, E. E., Bogen, D., Richardson, G., Park, S. Y., Dunn, S. L., & Day, N. (2016). Factors associated with buprenorphine versus methadone use in pregnancy. Substance Abuse, 37(4), 550–557.26914546
Kreek, M. J., Levran, O., Reed, B., Schlussman, S. D., Zhou, Y., & Butelman, E. R. (2012). Opiate addiction and cocaine addiction: Underlying molecular neurobiology and genetics. Journal of Clinical Investigation, 122(10), 3387–3393.
Kruse, C. S., Lee, K., Watson, J. B., Lobo, L. G., Stoppelmoor, A. G., & Oyibo, S. E. (2020). Measures of effectiveness, efficiency, and quality of telemedicine in the management of alcohol abuse, addiction, and rehabilitation: A systematic review. Journal of Medical Internet Research, 22(1), e13252.32012048
Kuczyńska, K., Grzonkowski, P., Kacprzak, Ł., & Zawilska, J. B. (2018). Abuse of fentanyl: An emerging problem to face. Forensic Science International, 289, 207–214.29902699
Kunins, H. V. (2020). Structural racism and the opioid overdose epidemic: The need for antiracist public health practice. Journal of Public Health Management and Practice, 26(3), 201–205.32235203
Kuper, L. E., Nussbaum, R., & Mustanski, B. (2012). Exploring the diversity of gender and sexual orientation identities in an online sample of transgender individuals. Journal of Sex Research, 49(2–3), 244–254.21797716
Kuypers, K., Verkes, R. J., van den Brink, W., van Amsterdam, J., & Ramaekers, J. G. (2020). Intoxicated aggression: Do alcohol and stimulants cause dose-related aggression? A review. European Neuropsychopharmacology, 30, 114–147.29941239
LaBelle, C. T., Han, S. C., Bergeron, A., & Samet, J. H. (2016). Office-based opioid treatment with buprenorphine (OBOT-B): Statewide implementation of the Massachusetts Collaborative Care Model in community health centers. Journal of Substance Abuse Treatment, 60, 6–13.26233698
LaFromboise, T. D., Hoyt, D. R., Oliver, L., & Whitbeck, L. B. (2006). Family, community, and school influences on resilience among American Indian adolescents in the upper Midwest. Journal of Community Psychology, 34(2), 193–209.
Lagisetty, P., Klasa, K., Bush, C., Heisler, M., Chopra, V., & Bohnert, A. (2017). Primary care models for treating opioid use disorders: What actually works? A systematic review. PLoS One, 12(10), e0186315.29040331
Lakhan, S. E., & Kirchgessner, A. (2012). Prescription stimulants in individuals with and without attention deficit hyperactivity disorder: Misuse, cognitive impact, and adverse effects. Brain and Behavior, 2(5), 661–677.23139911
Lameijer, H., Azizi, N., Ligtenberg, J. J. M., & Ter Maaten, J. C. (2014). Ventricular tachycardia after naloxone administration: A drug related complication? Case report and literature review. Drug Safety–Case Reports, 1, 2.27747471
Lander, L., Howsare, J., & Byrne, M. (2013). The impact of substance use disorders on families and children: From theory to practice. Social Work in Public Health, 28(3–4), 194–205.23731414
Lannett Company. (2020). Numbrino: Highlights of prescribing information. https://www.accessdata.fda.gov/drugsatfda_docs/label/2020/209575s000lbl.pdf
Lansky, A., Finlayson, T., Johnson, C., Holtzman, D., Wejnert, C., Mitsch, A., … Crepaz, N. (2014). Estimating the number of persons who inject drugs in the United States by meta-analysis to calculate national rates of HIV and hepatitis C virus infections. PLoS One, 9(5), e97596.24840662
Lappan, S. N., Brown, A. W., & Hendricks, P. S. (2020). Dropout rates of in–person psychosocial substance use disorder treatments: A systematic review and meta–analysis. Addiction, 115(20), 201–217.31454123
Lappin, J. M., Darke, S., & Farrell, M. (2017). Stroke and methamphetamine use in young adults: A review. Journal of Neurology, Neurosurgery, and Psychiatry, 88(12), 1079–1091.
Lappin, J. M., Darke, S., & Farrell, M. (2018). Methamphetamine use and future risk for Parkinson's disease: Evidence and clinical implications. Drug and Alcohol Dependence, 187, 134–140.29665491
Lappin, J. M., & Sara, G. E. (2019). Psychostimulant use and the brain. Addiction, 114(11), 2065–2077.31321819
LaRue, L., Twillman, R. K., Dawson, E., Whitley, P., Frasco, M. A., Huskey, A., & Guevara, M. G. (2019). Rate of fentanyl positivity among urine drug test results positive for cocaine or methamphetamine. JAMA Network Open, 2(4), e192851.31026029
Lawn, W., Aldridge, A., Xia, R., & Winstock, A. R. (2019). Substance-linked sex in heterosexual, homosexual, and bisexual men and women: An online, cross-sectional “global drug survey” report. Journal of Sexual Medicine, 16(5), 721–732.
LeardMann, C. A., McMaster, H. S., Warner, S., Esquivel, A. P., Porter, B., Powell, T. M., … Millennium Cohort Study Team. (2021). Comparison of posttraumatic stress disorder checklist instruments from Diagnostic and Statistical Manual of Mental Disorders, vs Fifth Edition in a large cohort of US Military service members and veterans. JAMA Network Open, 4(4), e218072–e218072.33904913
Lecomte, T., Dumais, A., Dugré, J. R., & Potvin, S. (2018). The prevalence of substance-induced psychotic disorder in methamphetamine misusers: A meta-analysis. Psychiatry Research, 268, 189–192.30041133
Lee, N. K., Jenner, L., Harney, A., & Cameron, J. (2018). Pharmacotherapy for amphetamine dependence: A systematic review. Drug and Alcohol Dependence, 191, 309–337.30173086
Lenz, A. S., Henesy, R., & Callender, K. (2016). Effectiveness of Seeking Safety for co–occurring posttraumatic stress disorder and substance use. Journal of Counseling and Development, 94(1), 51–61.
Lerner, A., & Klein, M. (2019). Dependence, withdrawal and rebound of CNS drugs: An update and regulatory considerations for new drugs development. Brain Communications, 1(1), fcz025.32954266
Levin, F. R., Mariani, J. J., Specker, S., Mooney, M., Mahony, A., Brooks, D. J., … Grabowski, J. (2015). Extended-release mixed amphetamine salts vs placebo for comorbid adult attention-deficit/hyperactivity disorder and cocaine use disorder: A randomized clinical trial. JAMA Psychiatry, 72(6), 593–602.25887096
Lewis, D. A., Park, J. N., Vail, L., Sine, M., Welsh, C., & Sherman, S. G. (2016). Evaluation of the Overdose Education and Naloxone Distribution Program of the Baltimore Student Harm Reduction Coalition. American Journal of Public Health, 106(7), 1243–1246.27077351
Lewis, K., & O'Day, C. S. (2020). Dystonic reactions. In StatPearls. https://www.ncbi.nlm.nih.gov/books/NBK531466/
Li, L., Sujan, A. C., Butwicka, A., Chang, Z., Cortese, S., Quinn, P., … Larsson, H. (2020). Associations of prescribed ADHD medication in pregnancy with pregnancy-related and offspring outcomes: A systematic review. CNS Drugs, 34(7), 731–747.32333292
Li, W., & Pozzo-Miller, L. (2020). Dysfunction of the corticostriatal pathway in autism spectrum disorders. Journal of Neuroscience Research, 98(11), 2130–2147.31758607
Lin, L. A., Fernandez, A. C., & Bonar, E. E. (2020). Telehealth for substance-using populations in the age of coronavirus disease 2019: Recommendations to enhance adoption. JAMA Psychiatry, 77(12), 1209–1210.32609317
Lindson, N., Thompson, T. P., Ferrey, A., Lambert, J. D., & Aveyard, P. (2019). Motivational interviewing for smoking cessation. Cochrane Database of Systematic Reviews. 10.1002/14651858.CD006936.pub4
Linton, S. L., Celentano, D. D., Kirk, G. D., & Mehta, S. H. (2013). The longitudinal association between homelessness, injection drug use, and injection-related risk behavior among persons with a history of injection drug use in Baltimore, MD. Drug and Alcohol Dependence, 132(3), 457–465.23578590
Liu, Y., Williamson, V., Setlow, B., Cottler, L. B., & Knackstedt, L. A. (2018). The importance of considering polysubstance use: Lessons from cocaine research. Drug and Alcohol Dependence, 192, 16–28.30195242
Lokoff, A., & Maynes, J. T. (2019). The incidence, significance, and management of accidental intra-arterial injection: A narrative review. Canadian Journal of Anesthesia, 66(5), 576–592.30877587
Longheu, A., Medas, F., Corrias, F., Farris, S., Tatti, A., Pisano, G., … Calò, P. G. (2016). Surgical management of gynecomastia: Experience of a general surgery center. Il Giornale di Chirurgia, 37(4), 150–154.27938530
López-Núñez, C., Alonso-Pérez, F., Pedrosa, I., & Secades-Villa, R. (2016). Cost-effectiveness of a voucher-based intervention for smoking cessation. American Journal of Drug and Alcohol Abuse, 42(3), 296–305.
Lopez-Patton, M., Kumar, M., Jones, D., Fonseca, M., Kumar, A. M., & Nemeroff, C. B. (2016). Childhood trauma and METH abuse among men who have sex with men: Implications for intervention. Journal of Psychiatric Research, 72, 1–5.26519763
Lorenzetti, V. (2018, August 13–15). Neural pathways in gambling and cocaine use disorders: Commonalities and differences from neuroimaging study [Paper presentation]. Gambling Harm 2018: Taking Action for Change, Geelong, Victoria, Australia.
Loza, O., Curiel, Z. V., Beltran, O., & Ramos, R. (2020). Methamphetamine use and sexual risk behaviors among men who have sex with men in a Mexico-US border city. American Journal on Addictions, 29(2), 111–119.
Lusk, S. L., & Veale, F. R. (2018). Increasing successful vocational rehabilitation outcomes for individuals with substance use disorders. Journal of Applied Rehabilitation Counseling, 49(1), 4–10.
Lutnick, A., Harris, J., Lorvick, J., Cheng, H., Wenger, L. D., Bourgois, P., & Kral, A. H. (2015). Examining the associations between sex trade involvement, rape, and symptomatology of sexual abuse trauma. Journal of Interpersonal Violence, 30(11), 1847–1863.25210029
Lyons, T., Chandra, G., Goldstein, J., & Ostrow, D. G. (2010). Breaking the bond between stimulant use and risky sex: A qualitative study. Substance Abuse, 31(4), 224–230.21038176
Ma, T., Sun, Y., & Ku, Y. (2019). Effects of non-invasive brain stimulation on stimulant craving in users of cocaine, amphetamine, or methamphetamine: A systematic review and meta-analysis. Frontiers in Neuroscience, 13, 1095.31680830
Maagdenberg, T., Savci, S., & Iffy, L. (2006). Cocaine intoxication mimicking preeclampsia postpartum. International Journal of Gynaecology and Obstetrics, 92(1), 73–74.16246345
MacArthur, G. J., van Velzen, E., Palmateer, N., Kimber, J., Pharris, A., Hope, V., … Hutchinson, S. J. (2014). Interventions to prevent HIV and hepatitis C in people who inject drugs: A review of reviews to assess evidence of effectiveness. International Journal on Drug Policy, 25(1), 34–52.
MacLean, R. R., & Sofuoglu, M. (2018). Stimulants and mood disorders. Current Addiction Reports, 5, 323–329.
MacNeil, J., & Pauly, B. (2011). Needle exchange as a safe haven in an unsafe world. Drug and Alcohol Review, 30(1), 26–32.21219494
MacNicol, B. (2017). The biology of addiction. Canadian Journal of Anaesthesia, 64(2), 141–148.
Magidson, J. F., Liu, S. M., Lejuez, C. W., & Blanco, C. (2012). Comparison of the course of substance use disorders among individuals with and without generalized anxiety disorder in a nationally representative sample. Journal of Psychiatric Research, 46(5), 659–666.22444600
Mahoney, J. J., III. (2019). Cognitive dysfunction in individuals with cocaine use disorder: Potential moderating factors and pharmacological treatments. Experimental and Clinical Psychopharmacology, 27(3), 203–214.30556731
Mahoney, M. C., Erwin, D. O., Twarozek, A. M., Saad-Harfouche, F. G., Rodriguez, E. M., Sun, X., … Fox, C. (2018). Leveraging technology to promote smoking cessation in urban and rural primary care medical offices. Preventative Medicine, 114, 102–106.
Maia, A., Martins, F. T., Silva Neto, L. D., Alves, R. B., & De Fátima, Â. (2017). Cocaethylene, the in vivo product of cocaine and ethanol, is a narcotic more potent than its precursors. Acta Crystallographica, Section C, Structural Chemistry, 73(Pt. 10), 780–783.
Maiorana, A., Kegeles, S. M., Brown, S., Williams, R., & Arnold, E. A. (2021). Substance use, intimate partner violence, history of incarceration and vulnerability to HIV among young Black men who have sex with men in a Southern US city. Culture, Health and Sexuality, 23(1), 37–51.
Malcolm, R., Barth, K. S., & Veatch, L. M. (2013). Cocaine addiction. In P. M. Miller (Ed.), Principles of addiction (pp. 669–678). Academic Press.
Maloney, W. J. (2010). The significance of cocaine use to dental practice. New York State Dental Journal, 76(6), 36–39.
Mangado, E. O., & Madoz-Gúrpide, A. (2009). Is the capacity of forming abstract concepts affected by cocaine use? Application of Wisconsin Test in a prospective study. European Psychiatry, 24(S1), 1.
Mariotti, K. C., Rossato, L. G., Fröehlich, P. E., & Limberger, R. P. (2013). Amphetamine-type medicines: A review of pharmacokinetics, pharmacodynamics, and toxicological aspects. Current Clinical Pharmacology, 8(4), 350–357.23342978
Markowitz, J. S., & Patrick, K. S. (2017). The clinical pharmacokinetics of amphetamines utilized in the treatment of attention-deficit/hyperactivity disorder. Journal of Child and Adolescent Psychopharmacology, 27(8), 678–689.28910145
Marlatt, G. A., & Gordon, J. R. (1985). Relapse prevention. Guilford Press.
Marquez, C., Mitchell, S. J., Hare, C. B., John, M., & Klausner, J. D. (2009). Methamphetamine use, sexual activity, patient–provider communication, and medication adherence among HIV-infected patients in care, San Francisco 2004–2006. AIDS Care, 21(5), 575–582.19444665
Marraccini, M. E., Weyandt, L. L., Gudmundsdottir, B. G., Oster, D. R., & McCallum, A. (2017). Attention–deficit hyperactivity disorder: Clinical considerations for women. Journal of Midwifery and Women's Health, 62(6), 684–695.
Marraccini, M. E., Weyandt, L. L., Rossi, J. S., & Gudmundsdottir, B. G. (2016). Neurocognitive enhancement or impairment? A systematic meta-analysis of prescription stimulant effects on processing speed, decision-making, planning, and cognitive perseveration. Experimental and Clinical Psychopharmacology, 24(4), 269–284.27454675
Marschall-Lévesque, S., Castellanos-Ryan, N., Parent, S., Renaud, J., Vitaro, F., Boivin, M., … Séguin, J. R. (2017). Victimization, suicidal ideation, and alcohol use from age 13 to 15 years: Support for the self-medication model. Journal of Adolescent Health, 60(4), 380–387.
Marshall, B. D., & Werb, D. (2010). Health outcomes associated with methamphetamine use among young people: A systematic review. Addiction, 105(6), 991–1002.20659059
Martin, C. E., Scialli, A., & Terplan, M. (2020). Unmet substance use disorder treatment need among reproductive age women. Drug and Alcohol Dependence, 206, 107679.31740208
Mash, D. C. (2016). Excited delirium and sudden death: A syndromal disorder at the extreme end of the neuropsychiatric continuum. Frontiers in Physiology, 7, 435.27790150
Maslow, A. H. (1943). A theory of human motivation. Psychological Review, 50, 370–396.
Masson, C. L., Shopshire, M. S., Sen, S., Hoffman, K., Hengl, N., Bartolome J., … Iguchi, M. (2013). Possible barriers to enrollment in substance abuse treatment among a diverse sample of Asian Americans and Pacific Islanders: Opinions of treatment clients. Journal of Substance Abuse Treatment, 44(3), 309–315.22985677
Mastro, T. D., Akolo, C., & Shoptaw, S. (2020). Managing amphetamine use is critical to achieving HIV control. AIDS, 34(13), 1971–1973.32558661
Matsumoto, R. R., Seminerio, M. J., Turner, R. C., Robson, M. J., Nguyen, L., Miller, D. B., & O'Callaghan, J. P. (2014). Methamphetamine-induced toxicity: An updated review on issues related to hyperthermia. Pharmacology and Therapeutics, 144(1), 28–40.24836729
Matsuzaka, S. (2018). Transgressing gender norms in addiction treatment: Transgender rights to access within gender-segregated facilities. Journal of Ethnicity in Substance Abuse, 17(4), 420–433.28632095
Maxwell, J. C. (2014). A new survey of methamphetamine users in treatment: Who they are, why they like “meth,” and why they need additional services. Substance Use and Misuse, 49(6), 639–644.24093526
Maxwell, S., Gafos, M., Moncrieff, M., Shahmanesh, M., & Stirrup, O. (2020). Pre-exposure prophylaxis use among men who have sex with men who have experienced problematic chemsex. International Journal of STD and AIDS, 31(5), 474–480.32075538
Maxwell, S., Shahmanesh, M., & Gafos, M. (2019). Chemsex behaviours among men who have sex with men: A systematic review of the literature. International Journal of Drug Policy, 63, 74–89.30513473
Mayer, K. H., Agwu, A., & Malebranche, D. (2020). Barriers to the wider use of pre-exposure prophylaxis in the United States: A narrative review. Advances in Therapy, 37(5), 1778–1811.32232664
Mayer, K. H., Jones, D., Oldenburg, C., Jain, S., Gelman, M., Zaslow, S., … Mimiaga, M. J. (2017). Excellent HIV post-exposure prophylaxis regimen completion with single tablet daily elvitegravir/cobicistat/tenofovir disoproxil fumarate/emtricitabine compared with more frequent dosing regimens. Journal of Acquired Immune Deficiency Syndromes, 75(5), 535–539.28696345
Mayo Clinic. (2017a, September 1). Transgender facts. https://www.mayoclinic.org/healthy-lifestyle/adult-health/in-depth/transgender-facts/art-20266812
Mayo Clinic. (2017b, December 22). Aortic dissection. https://www.mayoclinic.org/diseases-conditions/aortic-dissection/symptoms-causes/syc-20369496
Mayo Clinic. (2018, October 19). Prescription drug abuse. https://www.mayoclinic.org/diseases-conditions/prescription-drug-abuse/symptoms-causes/syc-20376813
Mayo Clinic. (2020, January 18). Placental abruption. https://www.mayoclinic.org/diseases-conditions/placental-abruption/symptoms-causes/syc-20376458
McCabe, S. E., & West, B. T. (2013). Medical and nonmedical use of prescription stimulants: Results from a national multicohort study. Journal of the American Academy of Child and Adolescent Psychiatry, 52(12), 1272–1280.24290460
McCall Jones, C., Baldwin, G. T., & Compton, W. M. (2017). Recent increases in cocaine-related overdose deaths and the role of opioids. American Journal of Public Health, 107(3), 430–432.28177817
McCarthy, E., & McClain, E. (2019). Methamphetamine-induced lung injury. European Journal of Case Reports in Internal Medicine, 6(6).
McDonell, M. G., Srebnik, D., Angelo, F., McPherson, S., Lowe, J. M., Sugar, A., … Ries, R. K. (2013). Randomized controlled trial of contingency management for stimulant use in community mental health patients with serious mental illness. American Journal of Psychiatry, 170(1), 94–101.
McGowan, C. E., & Fried, M. W. (2012). Barriers to hepatitis C treatment. Liver International, 32(Suppl. 1), 151–156.22212587
McHugh, R. K. (2015). Treatment of co-occurring anxiety disorders and substance use disorders. Harvard Review of Psychiatry, 23(2), 99–111.25747923
McHugh, R. K., Hearon, B. A., & Otto, M. W. (2010). Cognitive behavioral therapy for substance use disorders. Psychiatric Clinics, 33(3), 511–525.20599130
McHugh, R. K., Hu, M. C., Campbell, A. N., Hilario, E. Y., Weiss, R. D., & Hien, D. A. (2014). Changes in sleep disruption in the treatment of co–occurring posttraumatic stress disorder and substance use disorders. Journal of Traumatic Stress, 27(1), 82–89.24473926
McKay, J. R. (2017). Making the hard work of recovery more attractive for those with substance use disorders. Addiction, 112(5), 751–757.27535787
McKenna, S. A. (2013). “We're supposed to be asleep?” Vigilance, paranoia, and the alert methamphetamine user. Anthropology of Consciousness, 24(2), 172–190.26366049
McKetin, R. (2018). Methamphetamine psychosis: Insights from the past. Addiction, 113(8), 1522–1527.29516555
McKetin, R., Boden, J. M., Foulds, J. A., Najman, J. M., Ali, R., Degenhardt, L., … Weatherburn, D. (2020). The contribution of methamphetamine use to crime: Evidence from Australian longitudinal data. Drug and Alcohol Dependence, 216, 108262.32916517
McKetin, R., Lubman, D. I., Baker, A., Dawe, S., Ross, J., Mattick, R. P., & Degenhardt, L. (2018). The relationship between methamphetamine use and heterosexual behaviour: Evidence from a prospective longitudinal study. Addiction, 113(7), 1276–1285.29397001
McKetin, R., Lubman, D. I., Najman, J. M., Dawe, S., Butterworth, P., & Baker, A. L. (2014). Does methamphetamine use increase violent behaviour? Evidence from a prospective longitudinal study. Addiction, 109(5), 798–806.24400972
Mee-Lee, D., & Shulman, G. D. (2009). The ASAM placement criteria and matching patients to treatment. In R. K. Ries, S. Miller, D. A. Fiellin, & R. Saitz (Eds.), Principles of addiction medicine (4th ed., pp. 387–399). Lippincott Williams & Wilkins.
Mee-Lee, D., Shulman, G. D., Fishman, M. J., Gastfriend, D. R., & Miller, M. M., (Eds.). (2013). The ASAM criteria: Treatment criteria for addictive, substance-related, and co-occurring conditions (3rd ed.). The Change Companies.
Mégarbane, B., & Chevillard, L. (2013). The large spectrum of pulmonary complications following illicit drug use: Features and mechanisms. Chemico-Biological Interactions, 206(3), 444–451.24144776
Meier, S. C., & Labuski, C. M. (2013). The demographics of the transgender population. In A. K. Baumle (Ed.), International handbook of the demography of sexuality (pp. 289–327). Springer Science.
Merriam-Webster. (n.d.-a). End organ. In Merriam-Webster.com dictionary. Retrieved March 19, 2021, from https://www.merriam-webster.com/dictionary/end%20organ
Merriam-Webster. (n.d.-b). Sensorium. In Merriam-Webster.com dictionary. Retrieved March 19, 2021, from https://www.merriam-webster.com/dictionary/sensorium
Mesa, F., Le, T.-A., & Beidel, D. (2015). Social skill-based treatment for social anxiety disorder in adolescents. In K. Ranta, A. M. La Greca, L.-J. Garcia-Lopez, & M. Marttunen (Eds.), Social anxiety and phobia in adolescent: Development, manifestation and intervention strategies (pp. 289–299). Springer International Publishing.
Mete, M., Sakoglu, U., Spence, J. S., Devous, M. D., Sr., Harris, T. S., & Adinoff, B. (2016). Successful classification of cocaine dependence using brain imaging: A generalizable machine learning approach. BMC Bioinformatics, 17(Suppl. 13), 357.27766943
Metzl, J., & Roberts, D. (2014). Structural competency meets structural racism: Race, politics, and the structure of medical knowledge. Virtual Mentor, 16, 674–690.25216304
Meyers, R. J., Roozen, H. G., & Smith, J. E. (2011). The community reinforcement approach: An update of the evidence. Alcohol Research and Health, 33(4), 380–388.23580022
Meyers, R. J., & Smith, J. E. (1995). Clinical guide to alcohol treatment: The community reinforcement approach. Guilford Press.
Miguel, A. Q., Kiluk, B. D., Roos, C. R., Babuscio, T. A., Nich, C., Mari, J. J., & Carroll, K. M. (2019). Change in employment status and cocaine use treatment outcomes: A secondary analysis across six clinical trials. Journal of Substance Abuse Treatment, 106, 89–96.31540616
Miller, W. R. (1985). Motivation for treatment: A review with special emphasis on alcoholism. Psychological Bulletin, 98, 84–107.3898175
Miller, W. R. (1995). Increasing motivation for change. In R. K. Hester & W. R. Miller (Eds.), Handbook of alcoholism treatment approaches: Effective alternatives (2nd ed., pp. 89–104). Allyn & Bacon.
Miller, W. R., & Rollnick, S. (1991). Motivational interviewing: Preparing people to change addictive behavior. Guilford Press.
Mimiaga, M. J., Pantalone, D. W., Biello, K. B., Glynn, T. R., Santostefano, C. M., Olson, J., … Safren, S. A. (2018). A randomized controlled efficacy trial of behavioral activation for concurrent stimulant use and sexual risk for HIV acquisition among MSM: Project IMPACT study protocol. BMC Public Health, 18, 914.30045702
Min, S. Y., Whitecraft, J., Rothbard, A. B., & Salzer, M. S. (2007). Peer support for persons with co-occurring disorders and community tenure: A survival analysis. Psychiatric Rehabilitation Journal, 30, 207–213.17269271
Minnes, S., Min, M. O., Singer, L. T., Edguer, M., Wu, M., & Thi, P. (2012). Cocaine use during pregnancy and health outcome after 10 years. Drug and Alcohol Dependence, 126(1–2), 71–79.22633115
Minozzi, S., Saulle, R., De Crescenzo, F., & Amato, L. (2016). Psychosocial interventions for psychostimulant misuse. Cochrane Database of Systematic Reviews. 10.1002/14651858.CD011866.pub2
Mitchell, O., Wilson, D. B., & MacKenzie, D. L. (2012). The effectiveness of incarceration–based drug treatment on criminal behavior: A systematic review. Campbell Systematic Reviews, 8(1), i–76.
Moeller, K. E., Kissack, J. C., Atayee, R. S., & Lee, K. C. (2017). Clinical interpretation of urine drug tests: What clinicians need to know about urine drug screens. Mayo Clinic Proceedings, 92(5), 774–796.28325505
Moeller, S. J., & Paulus, M. P. (2018). Toward biomarkers of the addicted human brain: Using neuroimaging to predict relapse and sustained abstinence in substance use disorder. Progress in Neuro-Psychopharmacology and Biological Psychiatry, 80(Pt. B), 143–154.28322982
Molina, B. S. G., & Swanson, J. M. (2020). Why are long-term benefits of stimulant medication so difficult to detect? ADHD Report, 28(1), 1–7.
Moody, R. L., Starks, T. J., Grov, C., & Parsons, J. T. (2018). Internalized homophobia and drug use in a national cohort of gay and bisexual men: Examining depression, sexual anxiety, and gay community attachment as mediating factors. Archives of Sexual Behavior, 47(4), 1133–1144.28608294
Morais, A., Pita, I. R., Fontes-Ribeiro, C. A., & Pereira, F. C. (2018). The neurobiological mechanisms of physical exercise in methamphetamine addiction. CNS Neuroscience and Therapeutics, 24(2), 85–97.29266758
Moran, L. V., Ongur, D., Hsu, J., Castro, V. M., Perlis, R. H., & Schneeweiss, S. (2019). Psychosis with methylphenidate or amphetamine in patients with ADHD. New England Journal of Medicine, 380(12), 1128–1138.
Moreno-Rius, J., & Miquel, M. (2017). The cerebellum in drug craving. Drug and Alcohol Dependence, 173, 151–158.28259088
Morgenstern, J., Hogue, A., Dauber, S., Dasaro, C., & McKay, J. R. (2009). Does coordinated care management improve employment for substance-using welfare recipients? Journal of Studies on Alcohol and Drugs, 70(6), 955–963.19895774
Morris, L., Stander, J., Ebrahim, W., Eksteen, S., Meaden, O. A., Ras, A., & Wessels, A. (2018). Effect of exercise versus cognitive behavioural therapy or no intervention on anxiety, depression, fitness, and quality of life in adults with previous methamphetamine dependency: A systematic review. Addiction Science and Clinical Practice, 13(1), 4.29338767
Moss, M. J., Hendrickson, R. G., & Toxicology Investigators Consortium (ToxIC). (2019). Serotonin toxicity: Associated agents and clinical characteristics. Journal of Clinical Psychopharmacology, 39(6), 628–633.31688388
Mueller, M. D., & Wyman, J. R. (1997). Study sheds new light on the state of drug abuse treatment nationwide. NIDA Notes, 12(5), 1–7.
Müller, C. P., & Homberg, J. R. (2015). The role of serotonin in drug use and addiction. Behavioural Brain Research, 277, 146–192.24769172
Munro, B. A., Weyandt, L. L., Marraccini, M. E., & Oster, D. R. (2017). The relationship between nonmedical use of prescription stimulants, executive functioning and academic outcomes. Addictive Behaviors, 65, 250–257.27567397
Murch, D. (2015). Crack in Los Angeles: Crisis, militarization, and Black response to the late twentieth-century war on drugs. Journal of American History, 102(1), 162–173.
Murphy, S. M., Campbell, A. N. C., Ghitza, U. E., Kyle, T. L., Bailey, G. L., Nunes, E. V., & Polsky, D. (2016). Cost-effectiveness of an internet-delivered treatment for substance abuse: Data from a multisite randomized controlled trial. Drug and Alcohol Dependence, 161, 119–126.26880594
Nakamura, N., Mausbach, B. T., Ulibarri, M. D., Semple, S. J., & Patterson, T. L. (2011). Methamphetamine use, attitudes about condoms, and sexual risk behavior among HIV-positive men who have sex with men. Archives of Sexual Behavior, 40(2), 267–272.19856091
Nash, A. J. (2020). The twelve steps and adolescent recovery: A concise review. Substance Abuse: Research and Treatment, 14, 1178221820904397.32071541
Nassar, P., & Ouanounou, A. (2020). Cocaine and methamphetamine: Pharmacology and dental implications. Canadian Journal of Dental Hygiene, 54(2), 75–82.33240367
National Academies of Sciences, Engineering, and Medicine (2016). Ending discrimination against people with mental and substance use disorders: The evidence for stigma change (p. 23442). National Academies Press.
National Center for Biotechnology Information (2021). PubChem compound summary for CID 446220, cocaine. Retrieved March 22, 2021, from https://pubchem.ncbi.nlm.nih.gov/compound/Cocaine
National Center for Health Statistics (2020). About multiple cause of death, 1999–2019. CDC WONDER. Centers for Disease Control and Prevention. Retrieved March 25, 2021, through https://wonder.cdc.gov/mcd-icd10.html
National Institute on Drug Abuse (2014). Stimulant ADHD medications: Methylphenidate and amphetamines DrugFacts. National Institutes of Health.
National Institute on Drug Abuse (2015). Therapeutic communities (NIH Publication Number 15-4877). National Institutes of Health.
National Institute on Drug Abuse (2016a). Cocaine research report. National Institutes of Health.
National Institute on Drug Abuse. (2016b, May). What are the effects of maternal cocaine use? https://www.drugabuse.gov/publications/research-reports/cocaine/what-are-effects-maternal-cocaine-use
National Institute on Drug Abuse. (2016c, May). Why are cocaine users at risk for contracting HIV/AIDS and hepatitis? https://www.drugabuse.gov/publications/research-reports/cocaine/are-cocaine-abusers-risk-contracting-hivaids-hepatitis-b-c
National Institute on Drug Abuse. (2018a, January). The Matrix model (stimulants). https://www.drugabuse.gov/publications/principles-drug-addiction-treatment-research-based-guide-third-edition/evidence-based-approaches-to-drug-addiction-treatment/behavioral-therapies/matrix
National Institute on Drug Abuse. (2018b, June). Prescription stimulants DrugFacts. https://www.drugabuse.gov/publications/drugfacts/prescription-stimulants
National Institute on Drug Abuse. (2018c, July). The science of drug use and addiction: The basics. https://www.drugabuse.gov/publications/media-guide/science-drug-use-addiction-basics
National Institute on Drug Abuse (2019a). Methamphetamine research report. National Institutes of Health.
National Institute on Drug Abuse. (2019b, October). How is methamphetamine different from other stimulants, such as cocaine? https://www.drugabuse.gov/publications/research-reports/methamphetamine/how-methamphetamine-different-other-stimulants-such-cocaine
National Institute on Drug Abuse. (2019c, October). How is methamphetamine misused? https://www.drugabuse.gov/publications/research-reports/methamphetamine/how-methamphetamine-misused
National Institute on Drug Abuse. (2019d, October). What is the scope of methamphetamine misuse in the United States? https://www.drugabuse.gov/publications/research-reports/methamphetamine/what-scope-methamphetamine-misuse-in-united-states
National Institute on Drug Abuse. (2019e, October). What treatments are effective for people who misuse methamphetamine? https://www.drugabuse.gov/publications/research-reports/methamphetamine/what-treatments-are-effective-people-who-misuse-methamphetamine
National Institute on Drug Abuse. (2019f, December 18). Monitoring the Future 2019 Survey results: Overall findings. https://www.drugabuse.gov/drug-topics/trends-statistics/infographics/monitoring-future-2019-survey-results-overall-findings
National Institute on Drug Abuse (2020a). Drugs, brains, and behavior: The science of addiction (NIH Publication No. 20-DA-5605). National Institutes of Health.
National Institute on Drug Abuse (2020b). Misuse of prescription drugs research report. National Institutes of Health.
National Institute on Drug Abuse. (2020c, June). Criminal justice DrugFacts. National Institutes of Health. https://www.drugabuse.gov/publications/drugfacts/criminal-justice
National Institute on Drug Abuse. (2021a, January 29). Overdose death rates. https://www.drugabuse.gov/drug-topics/trends-statistics/overdose-death-rates
National Institute on Drug Abuse. (2021b, March). Cocaine DrugFacts. https://www.drugabuse.gov/publications/drugfacts/cocaine
Neeki, M. M., Dong, F., Liang, L., Toy, K., Carrico, B., Jabourian, N., … Wong, D. (2018). Evaluation of the effect of methamphetamine on traumatic injury complications and outcomes. Addiction Science and Clinical Practice, 13(1), 11.29592800
Nelson, N. P., Weng, M. K., Hofmeister, M. G., Moore, K. L., Doshani, M., Kamili, S., … Harris, A. M. (2020). Prevention of hepatitis A virus infection in the United States: Recommendations of the Advisory Committee on Immunization Practices, 2020. MMWR Recommendations and Reports, 69(RR-5), 1–38.
Nelson, P. K., Mathers, B. M., Cowie, B., Hagan, H., Des Jarlais, D., Horyniak, D., & Degenhardt, L. (2011). Global epidemiology of hepatitis B and hepatitis C in people who inject drugs: Results of systematic reviews. Lancet, 378(9791), 571–583.21802134
Nerlander, L. M. C., Hoots, B. E., Bradley, H., Broz, D., Thorson, A., & Paz-Bailey, G. (2018). HIV infection among MSM who inject methamphetamine in 8 US cities. Drug and Alcohol Dependence, 190, 216–223.30055426
Newcomb, M. E., Ryan, D. T., Greene, G. J., Garofalo, R., & Mustanski, B. (2014.) Prevalence and patterns of smoking, alcohol use, and illicit drug use in young men who have sex with men. Drug and Alcohol Dependence, 141, 65–71.24907774
Newton, T. F., De La Garza, R., Kalechstein, A. D., & Nestor, L. (2005). Cocaine and methamphetamine produce different patterns of subjective and cardiovascular effects. Pharmacology, Biochemistry, and Behavior, 82(1), 90–97.
Nguyen, T. Q., Weir, B. W., Des Jarlais, D. C., Pinkerton, S. D., & Holtgrave, D. R. (2014). Syringe exchange in the United States: A national level economic evaluation of hypothetical increases in investment. AIDS and Behavior, 18(11), 2144–2155. 10.1007/s10461-014-0789-9 24824043
Nickell, J. R., Siripurapu, K. B., Vartak, A., Crooks, P. A., & Dwoskin, L. P. (2014). The vesicular monoamine transporter-2: An important pharmacological target for the discovery of novel therapeutics to treat methamphetamine abuse. Advances in Pharmacology, 69, 71–106.24484975
NIDAnews [@NIDAnews]. (2014, September 11). “[Addiction] is like driving a car without brakes.” – NIDA Director Dr. Nora Volkow at #TEDMED [Image attached] [Tweet]. Twitter. https://twitter.com/nidanews/status/510086913160515584?lang=en
Niello, M., Gradisch, R., Loland, C. J., Stockner, T., & Sitte, H. H. (2020). Allosteric modulation of neurotransmitter transporters as a therapeutic strategy. Trends in Pharmacological Sciences, 41(7), 446–463.32471654
Nishino, S. (2009). Rebound hypersomnolence, stimulant abuse, and DAT-mediated dopamine release. Sleep, 32(11), 1407–1409.19928377
Nolan, S. O., Zachry, J. E., Johnson, A. R., Brady, L. J., Siciliano, C. A., & Calipari, E. S. (2020). Direct dopamine terminal regulation by local striatal microcircuitry. Journal of Neurochemistry, 155(5), 475–493.32356315
Norman, L., & Ford, J. (2018). Undergraduate prescription stimulant misuse: The impact of academic strain. Substance Use and Misuse, 53(9), 1482–1491.29313737
Novartis Pharmaceuticals (2019). Ritalin and Ritalin-SR: Highlights of prescribing information. https://www.accessdata.fda.gov/drugsatfda_docs/label/2019/010187s091,018029s059lbl.pdf
Novick, T., Liu, Y., Alvanzo, A., Zonderman, A. B., Evans, M. K., & Crews, D. C. (2016). Lifetime cocaine and opiate use and chronic kidney disease. American Journal of Nephrology, 44(6), 447–453.27788520
Nowotny, K. M. (2015). Race/ethnic disparities in the utilization of treatment for drug dependent inmates in U.S. state correctional facilities. Addictive Behaviors, 40, 148–153.25270722
Nutt, D. J., Lingford-Hughes, A., Erritzoe, D., & Stokes, P. R. (2015). The dopamine theory of addiction: 40 years of highs and lows. Nature Reviews Neuroscience, 16(5), 305–312.25873042
Nuttbrock, L., Bockting, W., Rosenblum, A., Hwahng, S., Mason, M., Macri, M., & Becker, J. (2014). Gender abuse, depressive symptoms, and substance use among transgender women: A 3-year prospective study. American Journal of Public Health, 104(11), 2199–2206.25211716
Nyamathi, A., Hudson, A., Greengold, B., & Leake, B. (2012). Characteristics of homeless youth who use cocaine and methamphetamine. American Journal on Addictions, 21(3), 243–249.
Nyamathi, A., Reback, C. J., Shoptaw, S., Salem, B. E., Zhang, S., & Yadav, K. (2017). Impact of tailored interventions to reduce drug use and sexual risk behaviors among homeless gay and bisexual men. American Journal of Men's Health, 11(2), 208–220.
O'Brien, P., Crable, E., Fullerton, C., Hughley, L., & Truven Health Analytics. (2019). Final project report: Best practices and barriers to engaging people with substance use disorders in treatment. https://aspe.hhs.gov/report/best-practices-and-barriers-engaging-people-substance-use-disorders-treatment
O'Connor, A., Harris, E., Hamilton, D., Fisher, C., & Sachmann, M. (2021). The experiences of pregnant women attending a specialist service and using methamphetamine. Women and Birth, 34(2), 170–179.32061546
O'Connor, E., Thomas, R., Senger, C. A., Perdue, L., Robalino, S., & Patnode, C. (2020). Interventions to prevent illicit and nonmedical drug use in children, adolescents, and young adults: Updated evidence report and systematic review for the US Preventive Services Task Force. JAMA, 323(20), 2067–2079.32453373
O'Donnell, J., Gladden, R. M., Mattson, C. L., Hunter, C. T., & Davis, N. L. (2020). Vital signs: Characteristics of drug overdose deaths involving opioids and stimulants—24 states and the District Columbia, January–June 2019. Morbidity and Mortality Weekly Report, 69(35), 1189–1197.32881854
Oei, J. L., Kingsbury, A., Dhawan, A., Burns, L., Feller, J. M., Clews, S., … Abdel-Latif, M. E. (2012). Amphetamines, the pregnant woman, and her children: A review. Journal of Perinatology, 32(10), 737–747.22652562
O'Farrell, T. J., & Clements, K. (2012). Review of outcome research on marital and family therapy in treatment for alcoholism. Journal of Marital and Family Therapy, 38(1), 122–144.22283384
Office of Infectious Disease and HIV/AIDS Policy. (n.d.-a). Hepatitis B basic information. U.S. Department of Health and Human Services. https://www.hhs.gov/hepatitis/learn-about-viral-hepatitis/hepatitis-b-basics/index.html
Office of Infectious Disease and HIV/AIDS Policy. (n.d.-b). Hepatitis C basic information. U.S. Department of Health and Human Services. https://www.hhs.gov/hepatitis/learn-about-viral-hepatitis/hepatitis-c-basics/index.html#hcv-prevention
Office of the Surgeon General (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
Office of the Surgeon General. (2018, April 5). U.S. Surgeon General's advisory on naloxone and opioid overdose. https://www.hhs.gov/surgeongeneral/priorities/opioids-and-addiction/naloxone-advisory/index.html
O'Halloran, C., Rice, B., White, E., Desai, M., Dunn, D. T., McCormack, S., … Gafos, M. (2019). Chemsex is not a barrier to self-reported daily PrEP adherence among PROUD study participants. International Journal on Drug Policy, 74, 246–254.
Ojikutu, B. O., Bogart, L. M., Higgins-Biddle, M., Dale, S. K., Allen, W., Dominique, T., & Mayer, K. H. (2018). Facilitators and barriers to pre-exposure prophylaxis (PrEP) use among Black individuals in the United States: Results from the National Survey on HIV in the Black Community (NSHBC). AIDS and Behavior, 22(11), 3576–3587.29468493
Otten, R., Mun, C. J., Shaw, D. S., Wilson, M. N., & Dishion, T. J. (2019). A developmental cascade model for early adolescent-onset substance use: The role of early childhood stress. Addiction, 114(2), 326–334.30280443
Overdose Response Strategy, New England High Intensity Drug Trafficking Area, & Boston Medical Center Office Based Addiction Treatment Training and Technical Assistance (2020). Methamphetamine: Public safety response. Boston Medical Center Office Based Addiction Treatment Training and Technical Assistance.
Pace, C. A., & Uebelacker, L. A. (2018). Addressing unhealthy substance use in primary care. Medical Clinics of North America, 102(4), 567–586.
Page, K., Morris, M. D., Hahn, J. A., Maher, L., & Prins, M. (2013). Injection drug use and hepatitis C virus infection in young adult injectors: Using evidence to inform comprehensive prevention. Clinical Infectious Diseases, 57(Suppl. 2), S32–S38.23884063
Palamar, J. J., Davies, S., Ompad, D. C., Cleland, C. M., & Weitzman, M. (2015). Powder cocaine and crack use in the United States: An examination of risk for arrest and socioeconomic disparities in use. Drug and Alcohol Dependence, 149, 108–116.25702933
Pan, Y., Metsch, L. R., Wang, W., Philbin, M., Kyle, T. L., Gooden, L. K., & Feaster, D. J. (2020). The relationship between housing status and substance use and sexual risk behaviors among people currently seeking or receiving services in substance use disorder treatment programs. Journal of Primary Prevention, 41(4), 363–382.
Paquette, C. E., Syvertsen, J. L., & Pollini, R. A. (2018). Stigma at every turn: Health services experiences among people who inject drugs. International Journal of Drug Policy, 57, 104–110.29715589
Paratz, E. D., Cunningham, N. J., & MacIsaac, A. I. (2016). The cardiac complications of methamphetamines. Heart, Lung and Circulation, 25(4), 325–332.
Parsons, J. T., John, S. A., Millar, B. M., & Starks, T. J. (2018). Testing the efficacy of combined motivational interviewing and cognitive behavioral skills training to reduce methamphetamine use and improve HIV medication adherence among HIV-positive gay and bisexual men. AIDS and Behavior, 22(8), 2674–2686.29536284
Parvaz, M. A., Alia-Klein, N., Woicik, P. A., Volkow, N. D., & Goldstein, R. Z. (2011). Neuroimaging for drug addiction and related behaviors. Reviews in the Neurosciences, 22(6), 609–624.22117165
Patel, P., Borkowf, C. B., Brooks, J. T., Lasry, A., Lansky, A., & Mermin, J. (2014). Estimating per-act HIV transmission risk: A systematic review. AIDS (London, England), 28(10), 1509–1519.
Paterno, M. T., Fiddian-Green, A., & Gubrium, A. (2018). Moms supporting moms: Digital storytelling with peer mentors in recovery from substance use. Health Promotion Practice, 19(6), 823–832.29298520
Paulus, M. P., & Stewart, J. L. (2020). Neurobiology, clinical presentation, and treatment of methamphetamine use disorder. JAMA Psychiatry, 77(9), 959–966.32267484
PDR Network. (n.d.). Methylphenidate hydrochloride – drug summary. In PDR: Prescribers' digital reference. Retrieved March 8, 2021, from https://www.pdr.net/drug-summary/Methylphenidate-Hydrochloride-ER-methylphenidate-hydrochloride-24298
Pedrelli, P., Nyer, M., Yeung, A., Zulauf, C., & Wilens, T. (2015). College students: Mental health problems and treatment considerations. Academic Psychiatry, 39(5), 503–511.25142250
Pendergraft, W. F., III, Herlitz, L. C., Thornley-Brown, D., Rosner, M., & Niles, J. L. (2014). Nephrotoxic effects of common and emerging drugs of abuse. Clinical Journal of the American Society of Nephrology, 9(11), 1996–2005.25035273
Perry, C. J., & Lawrence, A. J. (2017). Addiction, cognitive decline and therapy: Seeking ways to escape a vicious cycle. Genes, Brain and Behavior, 16(1), 205–218.
Perry, C. J., Zbukvic, I., Kim, J. H., & Lawrence, A. J. (2014). Role of cues and contexts on drug-seeking behaviour. British Journal of Pharmacology, 171(20), 4636–4672.24749941
Pescosolido, B. A., & Martin, J. K. (2015). The stigma complex. Annual Review of Sociology, 41(1), 87–116.
Petit, A., Karila, L., Chalmin, F., & Lejoyeux, M. (2012). Methamphetamine addiction: A review of the literature. Journal of Addiction Research and Therapy, S1, 006. https://www.omicsonline.org/methamphetamine-addiction-a-review-of-the-literature-2155-6105.S1-006.php?aid=3893
Petry, N. M. (2011). Contingency management: What it is and why psychiatrists should want to use it. Psychiatrist, 35(5), 161–163.22558006
Petry, N. M., Alessi, S. M., Barry, D., & Carroll, K. M. (2015). Standard magnitude prize reinforcers can be as efficacious as larger magnitude reinforcers in cocaine-dependent methadone patients. Journal of Consulting and Clinical Psychology, 83(3), 464–472.25198284
Pew Charitable Trusts (2018). More imprisonment does not reduce state drug problems. https://www.pewtrusts.org/en/research-and-analysis/issue-briefs/2018/03/more-imprisonment-does-not-reduce-state-drug-problems
Pew Charitable Trusts (2020). Care coordination strategies for patients can improve substance use disorder outcomes [Issue brief]. https://www.pewtrusts.org/en/research-and-analysis/issue-briefs/2020/04/care-coordination-strategies-for-patients-can-improve-substance-use-disorder-outcomes
Pew Research Center. (2020, May 6). Black imprisonment rate in the U.S. has fallen by a third since 2006. https://www.pewresearch.org/fact-tank/2020/05/06/share-of-black-white-hispanic-americans-in-prison-2018-vs-2006/
Pham, T., Milanaik, R., Kaplan, A., Papaioannou, H., & Adesman, A. (2017). Household diversion of prescription stimulants: Medication misuse by parents of children with attention-deficit/hyperactivity disorder. Journal of Child and Adolescent Psychopharmacology, 27(8), 741–746.28686059
Philbin, M. M., Greene, E. R., Martins, S. S., LaBossier, N. J., & Mauro, P. M. (2020). Medical, nonmedical, and illegal stimulant use by sexual identity and gender. American Journal of Preventive Medicine, 59(5), 686–696.32981768
Philip, S. S., Yu, X., Donnell, D., Vittinghoff, E., & Buchbinder, S. (2010). Serosorting is associated with a decreased risk of HIV seroconversion in the EXPLORE study cohort. PLoS One, 5(9), e12662.20844744
Phillips, K. T. (2016). Barriers to practicing risk reduction strategies among people who inject drugs. Addiction Research and Theory, 24(1), 62–68.27499724
Pilgrim, J. L., Woodford, N., & Drummer, O. H. (2013). Cocaine in sudden and unexpected death: A review of 49 post-mortem cases. Forensic Science International, 227(1–3), 52–59.22981213
Pinedo, M., Zemore, S., & Rogers, S. (2018). Understanding barriers to specialty substance abuse treatment among Latinos. Journal of Substance Abuse Treatment, 94, 1–8.30243409
Piper, B. J., Ogden, C. L., Simoyan, O. M., Chung, D. Y., Caggiano, J. F., Nichols, S.D., & McCall, K. L. (2018). Trends in use of prescription stimulants in the United States and territories, 2006 to 2016. PLoS One, 13(11), e0206100.30485268
Plant, C. P., & Holland, J. M. (2018). Family behavior therapy for alcohol and drug problems in later-life. Clinical Gerontologist, 41(5), 508–515.28960173
Platt, L., Minozzi, S., Reed, J., Vickerman, P., Hagan, H., French, C., … Hickman, M. (2017). Needle syringe programmes and opioid substitution therapy for preventing hepatitis C transmission in people who inject drugs. Cochrane Database of Systematic Reviews. 10.1002/14651858.CD012021.pub2
Polcin, D. L., Bond, J., Korcha, R., Nayak, M. B., Galloway, G. P., & Evans, K. (2014). Randomized trial of intensive motivational interviewing for methamphetamine dependence. Journal of Addictive Diseases, 33(3), 253–265.25115166
Polcin, D. L., Korcha, R., Bond, J., & Galloway, G. (2010). What did we learn from our study on sober living houses and where do we go from here? Journal of Psychoactive Drugs, 42(4), 425–433.21305907
Porcu, A., & Castelli, M. P. (2017). Cannabis and the use of amphetamine-like substances. In Handbook of cannabis and related pathologies (pp. e101–e110). Academic Press.
Potenza, M. N., Balodis, I. M., Derevensky, J., Grant, J. E., Petry, N. M., Verdejo-Garcia, A., & Yip, S. W. (2019). Gambling disorder. Nature Reviews Disease Primers, 5(1), 51.
Pradeep, T., & Standeven, L. R. (2019, January 3). Amphetamine. Johns Hopkins Psychiatry Guide. https://www.hopkinsguides.com/hopkins/view/Johns_Hopkins_Psychiatry_Guide/787274/all/Amphetamine
Preston, K. L., Schroeder, J. R., Kowalczyk, W. J., Phillips, K. A., Jobes, M. L., Dwyer, M., … Epstein, D. H. (2018). End-of-day reports of daily hassles and stress in men and women with opioid-use disorder: Relationship to momentary reports of opioid and cocaine use and stress. Drug and Alcohol Dependence, 193, 21–28.30336389
Priester, M. A., Browne, T., Iachini, A., Clone, S., DeHart, D., & Seay, K. D. (2016). Treatment access barriers and disparities among individuals with co-occurring mental health and substance use disorders: An integrative literature review. Journal of Substance Abuse Treatment, 61, 47–59.26531892
Prochaska, J. O., DiClemente, C. C., & Norcross, J. C. (1992). In search of how people change: Applications to addictive behaviors. American Psychologist, 47(9), 1102–1114.
Proctor, S. L., Hoffmann, N. G., & Raggio, A. (2019). Prevalence of substance use disorders and psychiatric conditions among county jail inmates: Changes and stability over time. Criminal Justice and Behavior, 46(1), 24–41.
Qiao, S., Zhou, G., & Li, X. (2018). Disclosure of same-sex behaviors to health-care providers and uptake of HIV testing for men who have sex with men: A systematic review. American Journal of Men's Health, 12(5), 1197–1214.
Quednow, B. B., & Vonmoos, M. (2017). Cognitive dysfunctions in chronic cocaine users. In V. R. Preedy (Ed.), The neuroscience of cocaine: Mechanisms and treatment (pp. 395–405). Academic Press.
Quinn, P. D., Chang, Z., Hur, K., Gibbons, R. D., Lahey, B. B., Rickert, M. E., … D'Onofrio, B. M. (2017). ADHD medication and substance-related problems. American Journal of Psychiatry, 174(9), 877–885.
Rabiner, D. L. (2013). Stimulant prescription cautions: Addressing misuse, diversion and malingering. Current Psychiatry Reports, 15(7), 375.23712725
Radfar, S. R., & Rawson, R. A. (2014). Current research on methamphetamine: Epidemiology, medical and psychiatric effects, treatment, and harm reduction efforts. Addiction and Health, 6(3–4), 146–154.25984282
Raiker, N., Aouthmany, M., & Ezra, N. (2016). Dermatologic signs and symptoms of substance abuse. Journal of Clinical and Experimental Dermatology Research, 7(2), 337.
Ramesh, D., Keyser-Marcus, L. A., Ma, L., Schmitz, J. M., Lane, S. D., Marwitz, J. H., … Moeller, F. G. (2015). Prevalence of traumatic brain injury in cocaine-dependent research volunteers. American Journal on Addictions, 24(4), 341–347.
Ramirez, R. L., III, Perez, V. D. J., & Zamanian, R. T. (2018a). Methamphetamine and the risk of pulmonary arterial hypertension. Current Opinion in Pulmonary Medicine, 24(5), 416–424.30036313
Ramirez, R. L., III, Perez, V. D. J., & Zamanian, R. T. (2018b). Stimulants and pulmonary arterial hypertension: An update. Advances in Pulmonary Hypertension, 17(2), 49–54.31656550
Ramsey, A. T., Satterfield, J. M., Gerke, D. R., & Proctor, E. K. (2019). Technology-based alcohol interventions in primary care: Systematic review. Journal of Medical Internet Research, 21(4), e10859.30958270
Rash, C. J., Alessi, S. M., & Petry, N. M. (2017). Substance abuse treatment patients in housing programs respond to contingency management interventions. Journal of Substance Abuse Treatment, 72, 97–102.27492676
Rash, C. J., Burki, M., Montezuma-Rusca, J. M., & Petry, N. M. (2016). A retrospective and prospective analysis of trading sex for drugs or money in women substance abuse treatment patients. Drug and Alcohol Dependence, 162, 182–189.27020748
Ratcliffe, M., Burd, C., Holder, K., & Fields, A. (2016). Defining rural at the U.S. Census Bureau (ACSGEO-1). U.S. Census Bureau.
Rawson, R. A. (2010). Treatments for methamphetamine dependence: Contingency management and the Matrix model. In R. Pates & D. Riley (Eds.), Interventions for amphetamine misuse (pp. 83–100). Wiley-Blackwell.
Rawson, R. A. (2013). Current research on the epidemiology, medical and psychiatric effects, and treatment of methamphetamine use. Journal of Food and Drug Analysis, 21(4), S77–S81.25214749
Rawson, R. (2020). Stimulant use by patients on medication for opioid use disorder: Do we have any answers? [PowerPoint slides]. https://uclaisap.org/ntpreach/docs/RR-Meth-and-MOUD_05-01-20.pdf
Rawson, R. A., Chudzynski, J., Gonzales, R., Mooney, L., Dickerson, D., Ang, A., … Cooper, C. B. (2015). The impact of exercise on depression and anxiety symptoms among abstinent methamphetamine-dependent individuals in a residential treatment setting. Journal of Substance Abuse Treatment, 57, 36–40.25934458
Rawson, R. A., Chudzynski, J., Mooney, L., Gonzales, R., Ang, A., Dickerson, D., … Cooper, C. B. (2015). Impact of an exercise intervention on methamphetamine use outcomes post-residential treatment care. Drug and Alcohol Dependence, 156, 21–28.26371404
Rawson, R. A., Gonzales, R., & Brethen, P. (2002). Treatment of methamphetamine use disorders: An update. Journal of Substance Abuse Treatment, 23(2), 145–150.12220612
Rawson, R. A., Huber, A., Brethen, P., Shoptaw, S., & Ling, W. (1996). Methamphetamine and cocaine: Comparison of reported effects and response to treatment [Paper presentation]. CPDD Satellite Conference on Methamphetamine, San Juan, Puerto Rico, United States.
Rawson, R. A., Ling, W., & Mooney, L. J. (2015). Clinical management: Methamphetamine. In M. Galanter, H. D. Kleber, & K. T. Brady (Eds.), Textbook of substance abuse treatment (5th ed., chapter 14). American Psychiatric Association Publishing.
Rawson, R. A., Obert, J. L., McCann, M. J., & Ling, W. (1991). The Matrix model of outpatient treatment for alcohol use and dependency. The Matrix Center.
Rawson, R. A., Obert, J. L., McCann, M. J., & Ling, W. (1993). Neurobehavioral treatment for cocaine dependency: A preliminary evaluation. In F. M. Tims & C. G. Leukefeld (Eds.), Cocaine treatment: Research and clinical perspectives (pp. 92–115). NIDA Research Monograph Series, Number 135, DHHS Publication No. (ADM) 93-3639. National Institute on Drug Abuse.
Rawson, R. A., Schmidt, K., & Mooney, L. J. (2021). Treatment of stimulant-related disorders. In K. T. Brady, F. R. Levin, M. Galanter, & H. D. Kleber (Eds.), The American Psychiatric Association Publishing textbook of substance use disorder treatment (6th ed., pp. 161–178). American Psychiatric Association Publishing.
Ray, L. A., Bujarski, S., Courtney, K. E., Moallem, N. R., Lunny, K., Roche, D., … Miotto, K. (2015). The effects of naltrexone on subjective response to methamphetamine in a clinical sample: A double-blind, placebo-controlled laboratory study. Neuropsychopharmacology, 40(10), 2347–2356.25801501
Reddy, P., Ng, T., Oh, E. E., Moady, G., & Elkayam, U. (2020). Clinical characteristics and management of methamphetamine-associated cardiomyopathy: State-of-the-art review. Journal of the American Heart Association, 9(11), e016704.32468897
Regier, P. S., & Redish, A. D. (2015). Contingency management and deliberative decision-making processes. Frontiers in Psychiatry, 6, 76.26082725
Reif, S., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., … Delphin-Rittmon, M. E. (2014). Peer recovery support for individuals with substance use disorders: Assessing the evidence. Psychiatric Services, 65(7), 853–861.24838535
Restrepo, C. S., Carrillo, J. A., Martínez, S., Ojeda, P., Rivera, A. L., & Hatta, A. (2007). Pulmonary complications from cocaine and cocaine-based substances: Imaging manifestations. RadioGraphics, 27(4), 941–956.17620460
Rhoades, H., Winetrobe, H., & Rice, E. (2014). Prescription drug misuse among homeless youth. Drug and Alcohol Dependence, 138, 229–233.24613220
Richard, J., Potenza, M. N., Ivoska, W., & Derevensky, J. (2019). The stimulating nature of gambling behaviors: Relationships between stimulant use and gambling among adolescents. Journal of Gambling Studies, 35(1), 47–62.29860582
Richards, J. R., Garber, D., Laurin, E. G., Albertson, T. E., Derlet, R. W., Amsterdam, E. A., … Lange, R. A. (2016). Treatment of cocaine cardiovascular toxicity: A systematic review. Clinical Toxicology, 54(5), 345–364.26919414
Richards, J. R., Hamidi, S., Grant, C. D., Wang, C. G., Tabish, N., Turnipseed, S. D., & Derlet, R. W. (2017). Methamphetamine Use and emergency department utilization: 20 years later. Journal of Addiction, 2017, 4050932.28913001
Richards, J. R., Hawkins, J. A., Acevedo, E. W., & Laurin, E. G. (2019). The care of patients using methamphetamine in the emergency department: Perception of nurses, residents, and faculty. Substance Abuse, 40(1), 95–101.29595368
Richards, J. R., & Laurin, E. G. (2020). Methamphetamine toxicity. In StatPearls. Retrieved March 19, 2021, from https://www.ncbi.nlm.nih.gov/books/NBK430895/
Richards, J. R., & Le, J. K. (2020). Cocaine toxicity. In StatPearls. Retrieved March 19, 2021, from https://www.ncbi.nlm.nih.gov/books/NBK430976/
Richards, J. R., Mefford, J. M., Patel, J. J., Parikh, A. K., Eder, A. Z., & Elder, J. W. (2020). The association between cocaine use detected on drug screening and rhabdomyolysis. Toxicology Communications, 4(1), 18–24.
Richards, J. R., Wang, C. G., Fontenette, R. W., Stuart, R. P., McMahon, K. F., & Turnipseed, S. D. (2020). Rhabdomyolysis, methamphetamine, amphetamine and MDMA use: Associated factors and risks. Journal of Dual Diagnosis, 16(4), 429–437.32644906
Rieckmann, T., Moore, L. A., Croy, C. D., Novins, D. K., & Aarons, G. (2016). A national study of American Indian and Alaska Native substance abuse treatment: Provider and program characteristics. Journal of Substance Abuse Treatment, 68, 46–56.27431046
Riley, E. D., Evans, J. L., Hahn, J. A., Briceno, A., Davidson, P. J., Lum, P. J., & Page, K. (2016). A longitudinal study of multiple drug use and overdose among young people who inject drugs. American Journal of Public Health, 106(5), 915–917.26985620
Ritchwood, T. D., DeCoster, J., Metzger, I. W., Bolland, J. M., & Danielson, C. K. (2016). Does it really matter which drug you choose? An examination of the influence of type of drug on type of risky sexual behavior. Addictive Behaviors, 60, 97–102.27104799
Ritchwood, T. D., Ford, H., DeCoster, J., Sutton, M., & Lochman, J. E. (2015). Risky sexual behavior and substance use among adolescents: A meta-analysis. Children and Youth Services Review, 52, 74–88.25825550
Rivera, A. V., DeCuir, J., Crawford, N. D., Amesty, S., & Lewis, C. F. (2014). Internalized stigma and sterile syringe use among people who inject drugs in New York City, 2010–2012. Drug and Alcohol Dependence, 144, 259–264.25307745
Robbins, J. L., Wenger, L., Lorvick, J., Shiboski, C., & Kral, A. H. (2010). Health and oral health care needs and health care-seeking behavior among homeless injection drug users in San Francisco. Journal of Urban Health, 87(6), 920–930.20945108
Robertson, C. L., Ishibashi, K., Chudzynski, J., Mooney, L. J., Rawson, R. A., Dolezal, B. A., … London, E. D. (2016). Effect of exercise training on striatal dopamine D2/D3 receptors in methamphetamine users during behavioral treatment. Neuropsychopharmacology, 41(6), 1629–1636.26503310
Robertson, E. B., Sims, B. E., & Reider, E. E. (2016). Risk and protective factors. In E. Wargo (Ed.), Principles of substance abuse prevention for early childhood: A research-based guide (pp. 21–32). National Institutes of Health, National Institute on Drug Abuse.
Roche, D. J. O., Worley, M. J., Courtney, K. E., Bujarski, S., London, E. D., Shoptaw, S., & Ray, L. A. (2017). Naltrexone moderates the relationship between cue-induced craving and subjective response to methamphetamine in individuals with methamphetamine use disorder. Psychopharmacology, 234(13), 1997–2007.28357460
Rolland, B., Karila, L., Geoffroy, P. A., & Cottencin, O. (2011). Shared vulnerability between seizures and psychosis in cocaine addiction? Epilepsy and Behavior, 22(3), 596–598.21924684
Ronsley, C., Nolan, S., Knight, R., Hayashi, K., Klimas, J., Walley, A., … Fairbairn, N. (2020). Treatment of stimulant use disorder: A systematic review of reviews. PLoS One, 15(6), e0234809.32555667
Ropelewski, L. R., Mancha, B. E., Hulbert, A., Rudolph, A. E., & Martins, S. S. (2011). Correlates of risky injection practices among past-year injection drug users among the US general population. Drug and Alcohol Dependence, 116(1–3), 64–71.21227602
Rosino, M., & Hughey, M. (2018). The war on drugs, racial meanings, and structural racism: A holistic and reproductive approach. American Journal of Economics and Sociology, 77, 849–892.
Rowe, C., Santos, G. M., McFarland, W., & Wilson, E. C. (2015). Prevalence and correlates of substance use among trans female youth ages 16–24 years in the San Francisco Bay Area. Drug and Alcohol Dependence, 147, 160–166.25548025
Ruglass, L. M., Hien, D. A., Hu, M. C., & Campbell, A. N. (2014). Associations between post-traumatic stress symptoms, stimulant use, and treatment outcomes: A secondary analysis of NIDA's Women and Trauma Study. American Journal on Addictions, 23(1), 90–95.
Ruglass, L. M., Shevorykin, A., Brezing, C., Hu, M.-C., & Hien, D. A. (2017). Demographic and clinical characteristics of treatment seeking women with full and subthreshold PTSD and concurrent cannabis and cocaine use disorders. Journal of Substance Abuse Treatment, 80, 45–51.28755772
Rutter, L. A., & Brown, T. A. (2017). Psychometric properties of the Generalized Anxiety Disorder Scale-7 (GAD-7) in outpatients with anxiety and mood disorders. Journal of Psychopathology and Behavioral Assessment, 39(1), 140–146.28260835
Ryan, S. A. (2019). Cocaine use in adolescents and young adults. Pediatric Clinics of North America, 66(6), 1135–1147.31679603
Sahker, E., Ali, S. R., & Arndt, S. (2019). Employment recovery capital in the treatment of substance use disorders: Six-month follow-up observations. Drug and Alcohol Dependence, 205, 107624.31645013
Sahker, E., Yeung, C. W., Garrison, Y. L., Park, S., & Arndt, S. (2017). Asian American and Pacific Islander substance use treatment admission trends. Drug and Alcohol Dependence, 171, 1–8.27988403
Saitz, R., Bair-Merritt, M. H., & Levy, S. J. (2021). Screening for young adults for illicit drug use: A good idea although evidence is lacking. Pediatrics, 147(Suppl. 2), S259–S261.33386328
Saitz, R., Cheng, D. M., Allensworth-Davies, D., Winter, M. R., & Smith, P. C. (2014). The ability of single screening questions for unhealthy alcohol and other drug use to identify substance dependence in primary care. Journal of Studies on Alcohol and Drugs, 75(1), 153–157.24411807
Salamanca, S. A., Sorrentino, E. E., Nosanchuk, J. D., & Martinez, L. R. (2015). Impact of methamphetamine on infection and immunity. Frontiers in Neuroscience, 8, 445.25628526
Salas-Wright, C. P., Lee, S., Vaughn, M. G., Jang, Y., & Sanglang, C. C. (2015). Acculturative heterogeneity among Asian/Pacific Islanders in the United States: Associations with DSM mental and substance use disorders. American Journal of Orthopsychiatry, 85(4), 362–370.
Saldana, C. S., Vyas, D. A., & Wurcel, A. G. (2020). Soft tissue, bone, and joint infections in people who inject drugs. Infectious Disease Clinics of North America, 34(3), 495–509.32782098
Salloum, I. M., & Brown, E. S. (2017). Management of comorbid bipolar disorder and substance use disorders. American Journal of Drug and Alcohol Abuse, 43(4), 366–376.
Salmanzadeh, H., Ahmadi-Soleimani, S. M., Pachenari, N., Azadi, M., Halliwell, R. F., Rubino, T., & Azizi, H. (2020). Adolescent drug exposure: A review of evidence for the development of persistent changes in brain function. Brain Research Bulletin, 156, 105–117.31926303
Salo, R., Flower, K., Kielstein, A., Leamon, M. H., Nordahl, T. E., & Galloway, G. P. (2011). Psychiatric comorbidity in methamphetamine dependence. Psychiatry Research, 186(2–3), 356–361.21055832
Saloner, B., Bandara, S. N., McGinty, E. E., & Barry, C. L. (2016). Justice-involved adults with substance use disorders: Coverage increased but rates of treatment did not in 2014. Health Affairs (Millwood), 35(6), 1058–1066.
Samuels, E. A., Baird, J., Yang, E. S., & Mello, M. J. (2019). Adoption and utilization of an emergency department naloxone distribution and peer recovery coach consultation program. Academic Emergency Medicine, 26(2), 160–173.30074673
Sanchez, K., Chartier, K. G., Greer, T. L. Walker, R., Carmody, T., Rethorst, C. D., … Trivedi, M. H. (2015). Comorbidities and race/ethnicity among adults with stimulant use disorders in residential treatment. Journal of Ethnicity in Substance Abuse, 14(1), 79–95.25580933
Sanchez, K., Greer, T. L., Walker, R., Carmody, T., Rethorst, C. D., & Trivedi, M. H. (2017). Racial and ethnic differences in treatment outcomes among adults with stimulant use disorders after a dosed exercise intervention. Journal of Ethnicity in Substance Abuse, 16(4), 495–510.28524806
Sánchez-Hervás, E., & Llorente del Pozo, J. M. (2012). Recaídas en la adicción a cocaína: Una revisión [Relapse in cocaine addiction: A review]. Adicciones, 24(3), 269–279.22868982
Sanders, M. (2011). Strategies for engaging difficult-to-reach, multiproblem clients with substance use disorders. Alcoholism Treatment Quarterly, 29(1), 91–98.
Sanders, M. (2015). Counseling African Americans with substance use disorders. [Handout showing PowerPoint slides]. https://www.naadac.org/assets/2416/2015-06-04_counseling_african_americans_with_suds_webinarslides.pdf
Sanner, L. M., & Greene, M. S. (2020). Social determinants of health and their impact on mental health and substance misuse. Center for Health Policy at the Indiana University School of Public Health.
Santoro, P., Rodríguez, R., Morales, P., Morano, A., & Morán, M. (2020). One “chemsex” or many? Types of chemsex sessions among gay and other men who have sex with men in Madrid, Spain: Findings from a qualitative study. International Journal of Drug Policy, 82, 102790.32516688
Saunders, E. C., Lambert-Harris, C., McGovern, M. P., Meier, A., & Xie, H. (2015). The prevalence of posttraumatic stress disorder symptoms among addiction treatment patients with cocaine use disorders. Journal of Psychoactive Drugs, 47(1), 42–50.25715071
Sayegh, C. S., Huey, S. J., Jr., Zara, E. J., & Jhaveri, K. (2017). Follow-up treatment effects of contingency management and motivational interviewing on substance use: A meta-analysis. Psychology of Addictive Behaviors, 31(4), 403–414.28437121
Scheim, A. I., Bauer, G. R., & Shokoohi, M. (2017). Drug use among transgender people in Ontario, Canada: Disparities and associations with social exclusion. Addictive Behaviors, 72, 151–158.28411424
Schierenberg, A., van Amsterdam, J., van den Brink, W., & Goudriaan, A. E. (2012). Efficacy of contingency management for cocaine dependence treatment: A review of the evidence. Current Drug Abuse Reviews, 5(4), 320–331.23244344
Schillie, S., Vellozzi, C., Reingold, A., Harris, A., Haber, P., Ward, J. W., & Nelson, N. P. (2018). Prevention of hepatitis B virus infection in the United States: Recommendations of the Advisory Committee on Immunization Practices. MMWR Recommendations and Reports, 67(RR-1), 1–31.
Schneider, J. A., Cornwell, B., Ostrow, D., Michaels, S., Schumm, P., Laumann, E. O., & Friedman, S. (2013). Network mixing and network influences most linked to HIV infection and risk behavior in the HIV epidemic among black men who have sex with men. American Journal of Public Health, 103(1), e28–e36.
Schottenfeld, R. S., Chawarski, M. C., Cubells, J. F., George, T. P., Lappalainen, J., & Kosten, T. R. (2014). Randomized clinical trial of disulfiram for cocaine dependence or abuse during buprenorphine treatment. Drug and Alcohol Dependence, 136, 36–42.24462581
Schottenfeld, R. S., Moore, B., & Pantalon, M. V. (2011). Contingency management with community reinforcement approach or twelve-step facilitation drug counseling for cocaine dependent pregnant women or women with young children. Drug and Alcohol Dependence, 118(1), 48–55.21454024
Schumm, J. A., & Gore, W. L. (2016). Simultaneous treatment of co-occurring posttraumatic stress disorder and substance use disorder. Current Treatment Options in Psychiatry, 3(1), 28–36.
Scoglio, A. A., Gorman, J. A., Park, D., Jooma, S., & Kraus, S. W. (2020). Trauma-informed drug screens for veterans with co-occurring disorders: A case series. Journal of Dual Diagnosis, 16(3), 347–356.32286200
Searight, R. (2018). Counseling patients in primary care: Evidence-based strategies. American Family Physician, 98, 719–728.30525356
See, I., Gokhale, R. H., Geller, A., Lovegrove, M., Schranz, A., Fleischauer, A., … Fiore, A. (2020). National public health burden estimates of endocarditis and skin and soft-tissue infections related to injection drug use: A review. Journal of Infectious Diseases, 222(Suppl. 5), S429–S436.
Sembower, M. A., Ertischek, M. D., Buchholtz, C., Dasgupta, N., & Schnoll, S. H. (2013). Surveillance of diversion and nonmedical use of extended-release prescription amphetamine and oral methylphenidate in the United States. Journal of Addictive Diseases, 32(1), 26–38.23480245
Semple, S. J., Strathdee, S. A., Zians, J., McQuaid, J. R., & Patterson, T. L. (2011). Drug assertiveness and sexual risk-taking behavior in a sample of HIV-positive, methamphetamine-using men who have sex with men. Journal of Substance Abuse Treatment, 41(3), 265–272.21550758
Sevelius, J. M., Patouhas, E., Keatley, J. G., & Johnson, M. O. (2014). Barriers and facilitators to engagement and retention in care among transgender women living with human immunodeficiency virus. Annals of Behavioral Medicine, 47(1), 5–16.24317955
Severtson, S. G., Kreider, S. E. D., Olsen, H., Ellis, M. S., Cicero, T. J., & Dart, R. C. (2019). RADARS System Quarterly Technical Report: The prevalence of methamphetamine use is increasing among individuals entering medication-assisted treatment programs for opioid use disorders (2019–Q3). RADARS System.
Sewell, J., Cambiano, V., Miltz, A., Speakman, A., Lampe, F. C., Phillips, A., … Rodger, A. (2018). Changes in recreational drug use, drug use associated with chemsex, and HIV-related behaviours, among HIV-negative men who have sex with men in London and Brighton, 2013–2016. Sexually Transmitted Infections, 94(7), 494–501.29700052
Sewell, J., Miltz, A., Lampe, F. C., Cambiano, V., Speakman, A., Phillips, A. N., … Rodger, A. J. (2017). Poly drug use, chemsex drug use, and associations with sexual risk behaviour in HIV-negative men who have sex with men attending sexual health clinics. International Journal of Drug Policy, 43, 33–43.28189979
Shahrokh, N. C., Hales, R. E., Phillips, K. A., & Yudofsky, S. C. (2011). The language of mental health: A glossary of psychiatric terms. American Psychiatric Publishing.
Sharma, A., & Stan, M. N. (2019). Thyrotoxicosis: Diagnosis and management. Mayo Clinic Proceedings, 94(6), 1048–1064.30922695
Sharma, T., Kumar, M., Rizkallah, A., Cappelluti, E., & Padmanabhan, P. (2019). Cocaine-induced thrombosis: Review of predisposing factors, potential mechanisms, and clinical consequences with a striking case report. Cureus, 11(5), e4700.31355062
Shearer, R. D., Howell, B. A., Bart, G., & Winkelman, T. N. A. (2020). Substance use patterns and health profiles among US adults who use opioids, methamphetamine, or both, 2015–2018. Drug and Alcohol Dependence, 214, 108162.32652380
Shekarchizadeh, H., Khami, M. R., Mohebbi, S. Z., Ekhtiari, H., & Virtanen, J. I. (2013). Oral health of drug abusers: A review of health effects and care. Iranian Journal of Public Health, 42(9), 929–940.26060654
Shen, W. W., Zhang, Y. S., Li, L. H., Liu, Y., Huang, X. N., Chen, L. H., & Zhou, W. (2014). Long-term use of methamphetamine disrupts the menstrual cycles and hypothalamic-pituitary-ovarian axis. Journal of Addiction Medicine, 8(3), 183–188.24695019
Sherman, C. (2017, March 9). Impacts of drugs on neurotransmission. National Institute on Drug Abuse. https://www.drugabuse.gov/news-events/nida-notes/2017/03/impacts-drugs-neurotransmission
Shetty, V., Harrell, L., Clague, J., Murphy, D. A., Dye, B. A., & Belin, T. R. (2016). Methamphetamine users have increased dental disease: A propensity score analysis. Journal of Dental Research, 95(7), 814–821.26994107
Shetty, V., Harrell, L., Murphy, D. A., Vitero, S., Gutierrez, A., Belin, T. R., … Spolsky, V. W. (2015). Dental disease patterns in methamphetamine users: Findings in a large urban sample. Journal of the American Dental Association (1939), 146(12), 875–885.26610832
Shetty, V., Mooney, L. J., Zigler, C. M., Belin, T. R., Murphy, D., & Rawson, R. (2010). The relationship between methamphetamine use and increased dental disease. Journal of the American Dental Association (1939), 141(3), 307–318.20194387
Shin, E. J., Dang, D. K., Tran, T. V., Tran, H. Q., Jeong, J. H., Nah, S. Y., … Kim, H. C. (2017). Current understanding of methamphetamine-associated dopaminergic neurodegeneration and psychotoxic behaviors. Archives of Pharmacal Research, 40(4), 403–428.28243833
Shoptaw, S., Rawson, R. A., McCabb, M. J., & Obert, J. L. (1994). The Matrix model of outpatient stimulant abuse treatment: Evidence of efficacy. Journal of Addictive Diseases, 13(4), 129–141.7734464
Siciliano, C. A., Calipari, E. S., Ferris, M. J., & Jones, S. R. (2015). Adaptations of presynaptic dopamine terminals induced by psychostimulant self-administration. ACS Chemical Neuroscience, 6(1), 27–36.25491345
Silvers, J. A., Squeglia, L. M., Rømer Thomsen, K., Hudson, K. A., & Feldstein Ewing, S. W. (2019). Hunting for what works: Adolescents in addiction treatment. Alcoholism: Clinical and Experimental Research, 43(4), 578–592.
Simon, D. P., & Kreek, M. J. (2016). Cocaine: Usage, misuse, and addiction processes—An overview. In V. Preedy (Ed.), Neuropathology of drug addictions and substance misuse (Vol. 2, pp. 5–13). Elsevier.
Sinha, R. (2013). The clinical neurobiology of drug craving. Current Opinion in Neurobiology, 23(4), 649–654.23764204
Sisson, R., & Azrin, N. H. (1989). The community reinforcement approach. In R. K. Hester & W. R. Miller (Eds.), Handbook of alcoholism treatment approaches: Effective alternatives (Vol. 157, pp. 242–258). Pergamon Press.
Skewes, M. C., & González, V. M. (2013). The biopsychosocial model of addiction. In P. M. Miller (Ed.), Principles of addiction: Comprehensive addiction behaviors and disorders (Vol. 1, pp. 61–70). Elsevier.
Slesnick, N., & Zhang, J. (2016). Family systems therapy for substance-using mothers and their 8- to 16-year-old children. Psychology of Addictive Behaviors, 30(6), 619–629.27454370
Smid, M. C., Metz, T. D., & Gordon, A. J. (2019). Stimulant use in pregnancy: An under-recognized epidemic among pregnant women. Clinical Obstetrics and Gynecology, 62(1), 168–184.30601144
Smith, L. M., Diaz, S., Lagasse, L. L., Wouldes, T., Derauf, C., Newman, E., … Lester, B. M. (2015). Developmental and behavioral consequences of prenatal methamphetamine exposure: A review of the Infant Development, Environment, and Lifestyle (IDEAL) Study. Neurotoxicology and Teratology, 51, 35–44.26212684
Smith, M. A., & Witte, M. A. (2012). The effects of exercise on cocaine self-administration, food-maintained responding, and locomotor activity in female rats: Importance of the temporal relationship between physical activity and initial drug exposure. Experimental and Clinical Psychopharmacology, 20(6), 437–446.22924703
Smith, P. H., Homish, G. G., Leonard, K. E., & Cornelius, J. R. (2012). Intimate partner violence and specific substance use disorders: Findings from the National Epidemiologic Survey on Alcohol and Related Conditions. Psychology of Addictive Behaviors, 26(2), 236–245.21823768
Smith, V., & Tasker, F. (2017). Gay men's chemsex survival stories. Sexual Health, 15(2), 116–122.
Smullin, C., Wagman, J., Mehta, S., & Klausner, J. D. (2021). A narrative review of the epidemiology of congenital syphilis in the United States from 1980 to 2019. Sexually Transmitted Diseases, 48(2), 71–78.32925597
Solingapuram Sai, J., Hurley, R. A., Dodda, M., & Taber, K. H. (2019). Positron emission tomography: Updates on imaging of addiction. Journal of Neuropsychiatry and Clinical Neurosciences, 31(4), A6–A288.
Soontornniyomkij, V., Kesby, J. P., Morgan, E. E., Bischoff-Grethe, A., Minassian, A., Brown, G. G., … Translational Methamphetamine AIDS Research Center (TMARC) Group. (2016). Effects of HIV and methamphetamine on brain and behavior: Evidence from human studies and animal models. Journal of Neuroimmune Pharmacology, 11(3), 495–510.27484318
Spillane, N. S., Weyandt, L., Oster, D., & Treloar, H. (2017). Social contextual risk factors for stimulant use among adolescent American Indians. Drug and Alcohol Dependence, 179, 167–173.28787693
Spiller, H. A., Hays, H. L., & Aleguas, A. (2013). Overdose of drugs for attention-deficit hyperactivity disorder: Clinical presentation, mechanisms of toxicity, and management. CNS Drugs, 27(7), 531–543.23757186
Spronk, D. B., van Wel, J. H. P., Ramaekers, J. G., & Verkes, R. J. (2013). Characterizing the cognitive effects of cocaine: A comprehensive review. Neuroscience and Biobehavioral Reviews, 37(8), 1838–1859.23876288
Staiger, P. K., Richardson, B., Long, C. M., Carr, V., & Marlatt, G. A. (2013). Overlooked and underestimated? Problematic alcohol use in clients recovering from drug dependence. Addiction, 108(7), 1188–1193.23075415
Stanger, C., & Budney, A. J. (2019). Contingency management: Using incentives to improve outcomes for adolescent substance use disorders. Pediatric Clinics of North America, 66(6), 1183–1192.31679606
Stanger, C., & Noel, V. (2014). A social skills and parental training intervention for disruptive boys reduces substance use behaviours in adolescence. Evidence-Based Mental Health, 17(1), 23.24336694
Steingard, R., Taskiran, S., Connor, D. F., Markowitz, J. S., & Stein, M. A. (2019). New formulations of stimulants: An update for clinicians. Journal of Child and Adolescent Psychopharmacology, 29(5), 324–339.31038360
Stevens, O., Moncrieff, M., & Gafos, M. (2020). Chemsex-related drug use and its association with health outcomes in men who have sex with men: A cross-sectional analysis of Antidote clinic service data. Sexually Transmitted Infections, 96(2), 124–130.31171592
Stitzer, M. L., Gukasyan, N., Matheson, T., Sorensen, J. L., Feaster, D. J., Duan, R., … Metsch, L. R. (2020). Enhancing patient navigation with contingent financial incentives for substance use abatement in persons with HIV and substance use. Psychology of Addictive Behaviors, 34(1), 23–30.31436447
Stoddard, S. A., Epstein-Ngo, Q., Walton, M. A., Zimmerman, M. A., Chermack, S. T., Blow, F. C., … Cunningham, R. M. (2015). Substance use and violence among youth: A daily calendar analysis. Substance Use and Misuse, 50(3), 328–339.25493643
Stoicescu, C., Ameilia, R., Irwanto Praptoraharjo, I., & Mahanani, M. (2019). Syndemic and synergistic effects of intimate partner violence, crystal methamphetamine, and depression on HIV sexual risk behaviors among women who inject drugs in Indonesia. Journal of Urban Health, 96(3), 477–496.30874946
Stoops, W. W., & Rush, C. R. (2013). Agonist replacement for stimulant dependence: A review of clinical research. Current Pharmaceutical Design, 19(40), 7026–7035.23574440
Storebø, O. J., Ramstad, E., Krogh, H. B., Nilausen, T. D., Skoog, M., Holmskov, M., … Gluud, C. (2015). Methylphenidate for children and adolescents with attention deficit hyperactivity disorder (ADHD). Cochrane Database of Systematic Reviews. 10.1002/14651858.CD009885.pub2
Strickland, J. C., Havens, J. R., & Stoops, W. W. (2019). A nationally representative analysis of “twin epidemics”: Rising rates of methamphetamine use among persons who use opioids. Drug and Alcohol Dependence, 204, 107592.31586804
Stringfellow, E. J., Kim, T. W., Gordon, A. J., Pollio, D. E., Grucza, R. A., Austin, E. L., … Kertesz, S. G. (2016). Substance use among persons with homeless experience in primary care. Substance Abuse, 37(4), 534–541.26914448
Stroumsa, D. (2014). The state of transgender health care: Policy, law, and medical frameworks. American Journal of Public Health, 104(3), e31–e38.
Stuard, W. L., Gallerson, B. K., & Robertson, D. M. (2017). Alterations in corneal nerves following crack cocaine use mimic diabetes-induced nerve damage. Endocrinology, Diabetes, and Metabolism Case Reports, 2017(1), 16–0131.
Substance Abuse and Mental Health Services Administration. (n.d.). Risk and protective factors. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2009). American Indian and Alaska Native culture card: A guide to build cultural awareness. HHS Publication No. (SMA) 08-4354. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2010). Recovery-oriented systems of care (ROSC) resource guide [Working draft]. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2011). Screening, brief intervention and referral to treatment (SBIRT) in behavioral healthcare. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2012). Using Matrix with women clients: A supplement to the Matrix intensive outpatient treatment for people with stimulant use disorders. HHS Publication No. (SMA) 12-4698. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2013). Behavioral health services for people who are homeless. Treatment Improvement Protocol (TIP) Series 55. HHS Publication No. (SMA) 13-4734. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2015). Hepatitis C screening in the behavioral healthcare setting. Advisory, Vol. 14, Issue 1. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2016). Rural behavioral health: Telehealth challenges and opportunities. In Brief, Vol. 9, Issue 2. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2018a). Behavioral health services for American Indians and Alaska Natives. Treatment Improvement Protocol (TIP) Series 61. HHS Publication No. (SMA) 18-5070EXSUMM. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2018b). SAMHSA opioid overdose prevention toolkit. HHS Publication No. (SMA) 18-4742. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2018c). Tips for teens: The truth about methamphetamine. PEP NO. 18-03. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2020a). 2018 National Survey on Drug Use and Health: Lesbian, gay, and bisexual (LGB) adults [Handout showing PowerPoint slides]. Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/data/sites/default/files/reports/rpt23252/7_LGB_2020_01_14_508.pdf
Substance Abuse and Mental Health Services Administration. (2020b). 2019 National Survey on Drug Use and Health: African Americans [Handout showing PowerPoint slides]. Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/data/sites/default/files/reports/rpt31099/2019NSDUH-AA/AfricanAmerican%202019%20NSDUH.pdf
Substance Abuse and Mental Health Services Administration (2020c). 2019 National Survey on Drug Use and Health: American Indians and Alaska Natives (AI/ANs) [Handout showing PowerPoint slides]. Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/data/sites/default/files/reports/rpt31098/2019NSDUH-AIAN/AIAN%202019%20NSDUH.pdf
Substance Abuse and Mental Health Services Administration (2020d). 2019 National Survey on Drug Use and Health: Asian/Native Hawaiians and Other Pacific Islanders (NHOPI) [Handout showing PowerPoint slides]. Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/data/sites/default/files/reports/rpt31100/2019NSDUH-NHOPI/Asian_NHOPI.pdf
Substance Abuse and Mental Health Services Administration (2020e). 2019 National Survey on Drug Use and Health: Hispanics [Handout showing PowerPoint slides]. Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/data/sites/default/files/reports/rpt31101/2019NSDUH-Hispanic/Hispanic%202019%20NSDUH.pdf
Substance Abuse and Mental Health Services Administration (2020f). 2019 National Survey on Drug Use and Health: Women [Handout showing PowerPoint slides]. Substance Abuse and Mental Health Services Administration. https://www.samhsa.gov/data/sites/default/files/reports/rpt31102/2019NSDUH-Women/Women%202019%20NSDUH.pdf
Substance Abuse and Mental Health Services Administration (2020g). Key substance use and mental health indicators in the United States: Results from the 2019 National Survey on Drug Use and Health. NSDUH Series H-55. HHS Publication No. PEP20-07-01-001. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2020h). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP20-02-01-006. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2020i). The opioid crisis and the Black/African American population: An urgent issue. Publication No. PEP20-05-02-001. Office of Behavioral Health Equity. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2020j). Prevention and treatment of HIV among people living with substance use and/or mental disorders. Publication No. PEP20-06-03-001. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2020k). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2020l). Substance use disorder treatment for people with co-occurring disorders. Treatment Improvement Protocol (TIP) Series 42. SAMHSA Publication No. PEP20-02-01-004. Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2020m). Treatment of stimulant use disorders. SAMHSA Publication No. PEP20-06-01-001. Substance Abuse and Mental Health Services Administration, National Mental Health and Substance Use Policy Laboratory.
Substance Abuse and Mental Health Services Administration. (2020n, August 19). Co-occurring disorders and other health conditions. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions/co-occurring-disorders
Substance Abuse and Mental Health Services Administration. (2020o, September 15). Naltrexone. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions/naltrexone
Substance Abuse and Mental Health Services Administration (2021a). Integrating vocational services into substance use disorder treatment. Advisory.
Substance Abuse and Mental Health Services Administration (2021b). Using technology-based therapeutic tools in behavioral health services. Advisory.
Substance Abuse and Mental Health Services Administration. (2021c, February 5). ASAM criteria. https://www.samhsa.gov/resource/ebp/asam-criteria
Swann, A. C. (2010). The strong relationship between bipolar and substance-use disorder. Annals of the New York Academy of Sciences, 1187(2010), 276–293.20201858
Swanson, J., Baler, R. D., & Volkow, N. D. (2011). Understanding the effects of stimulant medications on cognition in individuals with attention-deficit hyperactivity disorder: A decade of progress. Neuropsychopharmacology, 36(1), 207–226.20881946
Szerman, N., Ferre, F., Basurte-Villamor, I., Vega, P., Mesias, B., Marín-Navarrete, R., & Arango, C. (2020). Gambling dual disorder: A dual disorder and clinical neuroscience perspective. Frontiers in Psychiatry, 11, 589155.33329137
Szydlowski, S. J., & Amato, P. P. (2017). Nutrition in addiction treatment. Journal of Traditional Medicine and Clinical Naturopathy, 6, 218.
Tait, R. J., McKetin, R., Kay-Lambkin, F., Carron-Arthur, B., Bennett, A., Bennett, K., … Griffiths, K. M. (2015). Six-month outcomes of a web-based intervention for users of amphetamine-type stimulants: Randomized controlled trial. Journal of Medical Internet Research, 17(4), e105.25925801
Tavitian-Exley, I., Vickerman, P., Bastos, F. I., & Boily, M.-C. (2015). Influence of different drugs on HIV risk in people who inject: Systematic review and meta-analysis. Addiction, 110(4), 572–584.25582153
Taylor, S. B., Lewis, C. R., & Olive, M. F. (2013). The neurocircuitry of illicit psychostimulant addiction: Acute and chronic effects in humans. Substance Abuse and Rehabilitation, 4, 29–43.24648786
Tech-enabled CM for AUD at scale in Medicaid (2020). (Identification No. NCT04581499). https://clinicaltrials.gov/ct2/show/NCT04581499
Telzer, E. H. (2016). Dopaminergic reward sensitivity can promote adolescent health: A new perspective on the mechanism of ventral striatum activation. Developmental Cognitive Neuroscience, 17, 57–67.26708774
Teran, R. A., Carrico, A. W., Horvath, K. J., Downing, Jr., M. J., Chiasson, M. A., Walters, S. M., & Hirshfield, S. (2020). Stimulant use and study protocol completion: Assessing the ability of men who have sex with men to collect dried blood spots for laboratory measurement of HIV viral load. Archives of Sexual Behavior, 49(1), 195–209.31630286
Terlizzi, E. P., & Villarroel, M. A. (2020). Symptoms of generalized anxiety disorder among adults: United States, 2019 (NCHS Data Brief, No. 378). National Center for Health Statistics.
Tetrault, J. M., McCance-Katz, E. F., Moody, D. E., Fiellin, D. A., Lruie, B. S., DInh, A. T., & Fiellin, L. E. (2015). The impact of recent cocaine use on plasma levels of methadone and buprenorphine in patients with and without HIV-infection. Journal of Substance Abuse Treatment, 51, 70–74.25480096
Thomas, D. M., Pérez, M. A., Francescutti–Verbeem, D. M., Shah, M. M., & Kuhn, D. M. (2010). The role of endogenous serotonin in methamphetamine-induced neurotoxicity to dopamine nerve endings of the striatum. Journal of Neurochemistry, 115(3), 595–605.20722968
Thompson, R. G., Jr., & Auslander, W. F. (2011). Substance use and mental health problems as predictors of HIV sexual risk behaviors among adolescents in foster care. Health and Social Work, 36(1), 33–43.21446607
Timko, C., Booth, B. M., Han, X., Schultz, N. R., Blonigen, D. M., Wong, J. J., & Cucciare, M. A. (2017). Criminogenic needs, substance use, and offending among rural stimulant users. Rural Mental Health, 41(2), 110–122.29051795
Timko, C., Han, X., Woodhead, E., Shelley, A., & Cucciare, M. A. (2018). Polysubstance use by stimulant users: Health outcomes over three years. Journal of Studies on Alcohol and Drugs, 79(5), 799–807.30422794
Timko, C., Schultz, N. R., Britt, J., & Cucciare, M. A. (2016). Transitioning from detoxification to substance use disorder treatment: Facilitators and barriers. Journal of Substance Abuse Treatment, 70, 64–72.27692190
To protect and serve: Joint law enforcement efforts in building safe tribal communities and stopping dangerous drugs from entering Indian Country, U.S. Senate Committee on Indian Affairs. 116th Cong. (2019) (testimony of Charles Addington).
Tolliver, B. K., McRae-Clark, A. L., Saladin, M., Price, K. L., Simpson, A. N., DeSantis, S. M., … Brady, K. T. (2010). Determinants of cue-elicited craving and physiologic reactivity in methamphetamine-dependent subjects in the laboratory. American Journal of Drug and Alcohol Abuse, 36(2), 106–113.
Tong, H. Y., Díaz, C., Collantes, E., Medrano, N., Borobia, A. M., Jara, P., & Ramírez, E. (2015). Liver transplant in a patient under methylphenidate therapy: A case report and review of the literature. Case Reports in Pediatrics, 2015, 437298.25688317
Tonigan, J. S., Venner, K., & Hirchak, K. A. (2020). Urban American Indian adult participation and outcomes in culturally adapted and mainstream Alcoholics Anonymous meetings. Alcohol Treatment Quarterly, 38(1), 50–67.
Torchalla, I., Strehlau, V., Li, K., & Krausz, M. (2011). Substance use and predictors of substance dependence in homeless women. Drug and Alcohol Dependence, 118(2–3), 173–179.21498010
Torregrossa, M. M., & Taylor, J. R. (2013). Learning to forget: Manipulating extinction and reconsolidation processes to treat addiction. Psychopharmacology, 226(4), 659–672.22638814
Torres, T. S., Bastos, L. S., Kamel, L., Bezerra, D. R. B., Fernandes, N. M., Moreira, R. I., … De Boni, R. B. (2020). Do men who have sex with men who report alcohol and illicit drug use before/during sex (chemsex) present moderate/high risk for substance use disorders? Drug and Alcohol Dependence, 209, 107908.32078972
Torres-Acosta, N., O'Keefe, J. H., O'Keefe, C. L., & Lavie, C. J. (2020). Cardiovascular effects of ADHD therapies: JACC Review Topic of the Week. Journal of the American College of Cardiology, 76(7), 858–866.32792083
Tracy, D., Hahn, J. A., Fuller Lewis, C., Evans, J., Briceño, A., Morris, M. D., … Page, K. (2014). Higher risk of incident hepatitis C virus among young women who inject drugs compared with young men in association with sexual relationships: A prospective analysis from the UFO Study cohort. BMJ Open, 4(5), e004988.
Trauma Informed Oregon (2019). Trauma informed urine drug screenings.
Tressler, S. R., Kushner, T., & Bhandari, R. (2020). Factors associated with hepatitis B exposure among people who report using methamphetamine: National Health and Nutrition Examination Survey 2009–2016. Journal of Infectious Diseases, 221(2), 243–250.
Trivedi, M. H., Greer, T. L., Rethorst, C. D., Carmody, T., Grannemann, B. D., Walker, R., … Nunes, E. V. (2017). Randomized controlled trial comparing exercise to health education for stimulant use disorder: Results from the CTN-0037 STimulant Reduction Intervention Using Dosed Exercise (STRIDE) study. Journal of Clinical Psychiatry, 78(8), 1075–1082.
Tsai, H., Lee, J., Hedlin, H., Zamanian, R. T., & de Jesus Perez, V. A. (2019). Methamphetamine use association with pulmonary diseases: A retrospective investigation of hospital discharges in California from 2005 to 2011. ERJ Open Research, 5(4), 00017–2019.31637253
Tsai, J., & Gu, X. (2019). Utilization of addiction treatment among U.S. adults with history of incarceration and substance use disorders. Addiction Science and Clinical Practice, 14, 9.30836991
Tsui, J. I., Mayfield, J., Speaker, E. C., Yakup, S., Ries, R., Funai, H., … Merrill, J. O. (2020). Association between methamphetamine use and retention among patients with opioid use disorders treated with buprenorphine. Journal of Substance Abuse Treatment, 109, 80–85.31810594
Turowski, P., & Kenny, B.-A. (2015). The blood-brain barrier and methamphetamine: Open sesame? Frontiers in Neuroscience, 9, 156.25999807
United Nations Office on Drugs and Crime (2018). World drug report 2018: Drugs and age (Booklet 4).
United Nations Office on Drugs and Crime (2019a). HIV prevention, treatment, care and support for people who use stimulant drugs [Technical guide].
United Nations Office on Drugs and Crime (2019b). Treatment of stimulant use disorders: Current practices and promising perspectives [Discussion paper].
United Nations Population Fund, Global Forum on MSM & HIV, United Nations Development Programme, World Health Organization, U.S. Agency for International Development, World Bank (2015). Implementing comprehensive HIV and STI programmes with men who have sex with men: Practical guidance for collaborative interventions. United Nations Population Fund.
University of Michigan (2020). Monitoring the Future Survey: 2020 data from in-school surveys of 8th-, 10th-, and 12th-grade students [Data set]. http://www.monitoringthefuture.org/data/20data.html#2020data-drugs
Upshur, C. C., Jenkins, D., Weinreb, L., Gelberg, L., & Orvek, E. A. (2018). Homeless women's service use, barriers, and motivation for participating in substance use treatment. American Journal of Drug and Alcohol Abuse, 44(2), 252–262.
U.S. Census Bureau. (n.d.). United States. Retrieved June 22, 2021, from https://data.census.gov/cedsci/profile?q=United%20States&g=0100000US
U.S. Preventive Services Task Force (2020a). Final recommendation statement: Hepatitis C virus infection in adolescents and adults: Screening. https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/hepatitis-c-screening
U.S. Preventive Services Task Force (2020b). Final recommendation statement: Screening for hepatitis B virus infection in adolescents and adults. https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/hepatitis-b-virus-infection-screening
Vanderplasschen, W., Rapp, R. C., De Maeyer, J., & Van Den Noortgate, W. (2019). A meta-analysis of the efficacy of case management for substance use disorders: A recovery perspective. Frontiers in Psychiatry, 10, 186.31057432
Vasan, S., & Olango, G. J. (2020). Amphetamine toxicity. In StatPearls. Retrieved March 19, 2021, from https://www.ncbi.nlm.nih.gov/books/NBK470276/
Vayalapalli, S., Fareed, A., Casarella, J., & Drexler, K. (2011). Housing as a motivation for seeking substance abuse treatment. American Journal on Addictions, 20(2), 182–183.
Verma, V. (2015). Classic studies on the interaction of cocaine and the dopamine transporter. Clinical Psychopharmacology and Neuroscience, 13(3), 227–238.26598579
Visconti, A. J., Sell, J., & Greenblatt, A. D. (2019). Primary care for persons who inject drugs. American Family Physician, 99(2), 109–116.30633481
Visser, S. N., Danielson, M. L., Bitsko, R. H., Holbrook, J. R., Kogan, M. D., Ghandour, R. M., … Blumberg, S. J. (2014). Trends in the parent-report of health care provider-diagnosed and medicated attention-deficit/hyperactivity disorder: United States, 2003–2011. Journal of the American Academy of Child and Adolescent Psychiatry, 53(1), 34–46.e2.24342384
Viswanath, H., Wilkerson, J. M., Breckenridge, E., & Selwyn, B. J. (2017). Life chaos and perceived social support among methamphetamine-using men who have sex with men engaging in transactional sexual encounters. Substance Use and Misuse, 52(1), 100–107.27679931
Volkow, N. D., Baler, R. D., Compton, W. M., & Weiss, S. R. (2014). Adverse health effects of marijuana use. New England Journal of Medicine, 370(23), 2219–2227.
Volkow, N. D., Michaelides, M., & Baler, R. (2019). The neuroscience of drug reward and addiction. Physiological Reviews, 99(4), 2115–2140.31507244
Volkow, N. D., Wang, G. J., Fowler, J. S., Telang, F., Jayne, M., & Wong, C. (2007). Stimulant-induced enhanced sexual desire as a potential contributing factor in HIV transmission. American Journal of Psychiatry, 164(1), 157–160.
Volkow, N. D., Wise, R. A., & Baler, R. (2017). The dopamine motive system: Implications for drug and food addiction. Nature Reviews Neuroscience, 18(12), 741–752.29142296
Vonmoos, M., Hulka, L. M., Preller, K. H., Minder, F., Baumgartner, M. R., & Quednow, B. B. (2014). Cognitive impairment in cocaine users is drug-induced but partially reversible: Evidence from a longitudinal study. Neuropsychopharmacology, 39(9), 2200–2210.24651468
Vosburg, S. K., Haney, M., Rubin, E., & Foltin, R. W. (2010). Using a novel alternative to drug choice in a human laboratory model of a cocaine binge: A game of chance. Drug and Alcohol Dependence, 110(1–2), 144–150.20346597
Vu, N. T., Maher, L., & Zablotska, I. (2015). Amphetamine-type stimulants and HIV infection among men who have sex with men: Implications on HIV research and prevention from a systematic review and meta-analysis. Journal of the International AIDS Society, 18(1), 19273.25609214
Vujanovic, A. A., Bonn-Miller, M. O., & Petry, N. M. (2016). Co-occurring posttraumatic stress and substance use: Emerging research on correlates, mechanisms, and treatments—Introduction to the special issue. Psychology of Addictive Behaviors, 30(7), 713–719.27786510
Walley, A. (2013). Stimulants: Cocaine and methamphetamine [Handout showing PowerPoint slides]. Presentation at the Resident Immersion Training (CRIT) Program in Addiction Medicine at Boston University School of Medicine. https://www.bumc.bu.edu/care/files/2013/06/4.-A.-WALLEY-STIMULANTS-CRIT-FIT-20132.pdf
Walls, N. E., & Bell, S. (2011). Correlates of engaging in survival sex among homeless youth and young adults. Journal of Sex Research, 48(5), 423–436.20799134
Walsh-Buhi, M. L. (2017). “Please don't just hang a feather on a program or put a medicine wheel on your logo and think ‘Oh well, this will work’”: Theoretical perspectives of American Indian and Alaska Native substance abuse prevention programs. Family Community Health, 40(1), 81–87.27870759
Wang, L., Min, J. E., Krebs, E., Evans, E., Huang, D., Liu, L., … Nosyk, B. (2017). Polydrug use and its association with drug treatment outcomes among primary heroin, methamphetamine, and cocaine users. International Journal on Drug Policy, 49, 32–40.
Warden, D. W., Sanchez, K., Greer, T., Carmody, T. Walker, R., dela Cruz, A., … Trivedi, M. H. (2016). Demographic and clinical characteristics of current comorbid psychiatric disorders in a randomized clinical trial for adults with stimulant use disorders. Psychiatry Research, 246, 136–141.27693866
Wassum, K. M., & Izquierdo, A. (2015). The basolateral amygdala in reward learning and addiction. Neuroscience and Biobehavioral Reviews, 57, 271–283.26341938
Waye, K. M., Goyer, J., Dettor, D., Mahoney, L., Samuels, E. A., Yedinak, J. L., & Marshall, B. (2019). Implementing peer recovery services for overdose prevention in Rhode Island: An examination of two outreach-based approaches. Addictive Behaviors, 89, 85–91.30278306
Wearne, T. A., & Cornish, J. L. (2018). A comparison of methamphetamine-induced psychosis and schizophrenia: A review of positive, negative, and cognitive symptomatology. Frontiers in Psychiatry, 9, 491.30364176
Weinstein, Z. M., Kim, H. W., Cheng, D. M., Quinn, E., Hui, D., Labelle, C. T., & Samet, J. H. (2017). Long-term retention in office based opioid treatment with buprenorphine. Journal of Substance Abuse Treatment, 74, 65–70.28132702
Weintraub, E., Greenblatt, A. D., Chang, J., Himelhoch, S., & Welsh, C. (2018). Expanding access to buprenorphine treatment in rural areas with the use of telemedicine. American Journal on Addictions, 27(8), 612–617.
Werb, D., Buxton, J., Shoveller, J., Richardson, C., Rowell, G., & Wood, E. (2013). Interventions to prevent the initiation of injection drug use: A systematic review. Drug and Alcohol Dependence, 133(2), 669–676.24055187
Werner, F. M., & Covenas, R. (2017). Long-term administration of antipsychotic drugs in schizophrenia and influence of substance and drug abuse on the disease outcome. Current Drug Abuse Reviews, 10(1), 19–24.29065847
Westover, A. N., & Halm, E. A. (2012). Do prescription stimulants increase the risk of adverse cardiovascular events?: A systematic review. BMC Cardiovascular Disorders, 12(1), 1–10.22284388
Weyandt, L. L., Marraccini, M. E., Gudmundsdottir, B. G., Zavras, B. M., Turcotte, K. D., Munro, B. A., & Amoroso, A. J. (2013). Misuse of prescription stimulants among college students: A review of the literature and implications for morphological and cognitive effects on brain functioning. Experimental and Clinical Psychopharmacology, 21(5), 385–407.24099359
Weyandt, L. L., Oster, D. R., Marraccini, M. E., Gudmundsdottir, B. G., Munro, B. A., Rathkey, E. S., & McCallum, A. (2016). Prescription stimulant medication misuse: Where are we and where do we go from here? Experimental and Clinical Psychopharmacology, 24(5), 400–414.27690507
Weyandt, L. L., White, T. L., Gudmundsdottir, B. G., Nitenson, A. Z., Rathkey, E. S., De Leon, K. A., & Bjorn, S. A. (2018). Neurocognitive, autonomic, and mood effects of Adderall: A pilot study of healthy college students. Pharmacy, 6(3), 58.
White, W. (2004). History of drug problems and drug policies in America. In R. Coombs (Ed.), Addiction counseling review: Preparing for comprehensive certification exams (pp. 81–104). Lahaska Press.
Whitesell, N. R., Beals, J., Big Crow, C. B., Mitchell, C. M., & Novins, D. K. (2012). Epidemiology and etiology of substance use among American Indians and Alaska Natives: Risk, protection, and implications for prevention. American Journal of Drug and Alcohol Abuse, 38(5), 376–382.
Wiener, S. E., Sutijono, D., Moon, C. H., Subramanian, R. A., Calaycay, J., Rushbrook, J. I., & Zehtabchi, S. (2010). Patients with detectable cocaethylene are more likely to require intensive care unit admission after trauma. American Journal of Emergency Medicine, 28(9), 1051–1055.
Wiers, C. E., Cabrera, E., Skarda, E., Volkow, N. D., & Wang, G. J. (2016). PET imaging for addiction medicine: From neural mechanisms to clinical considerations. Progress in Brain Research, 224, 175–201.26822359
Wiggs, K. K., Chang, Z., Quinn, P. D., Hur, K., Gibbons, R., Dunn, D., … D'Onofrio, B. M. (2018). Attention-deficit/hyperactivity disorder medication and seizures. Neurology, 90(13), e1104–e1110.29476037
Wilens, T. E., Carrellas, N. W., Martelon, M., Yule, A. M., Fried, R., Anselmo, R., & McCabe, S. E. (2017). Neuropsychological functioning in college students who misuse prescription stimulants. American Journal on Addictions, 26(4), 379–387.
Wilens, T. E., Martelon, M., Joshi, G., Bateman, C., Fried, R., Petty, C., & Biederman, J. (2011). Does ADHD predict substance-use disorders? A 10-year follow-up study of young adults with ADHD. Journal of the American Academy of Child and Adolescent Psychiatry, 50(6), 543–553.21621138
Wilens, T., Zulauf, C., Martelon, M., Morrison, N. R., Simon, A., Carrellas, N. W., … Anselmo, R. (2016). Nonmedical stimulant use in college students: Association with attention-deficit/hyperactivity disorder and other disorders. Journal of Clinical Psychiatry, 77(7), 940–947.
Wilkerson, A. K., Sahlem, G. L., Bentzley, B. S., Lord, J., Smith, J. P., Simmons, R. O., … Book, S. W. (2019). Insomnia severity during early abstinence is related to substance use treatment completion in adults enrolled in an intensive outpatient program. Journal of Substance Abuse Treatment, 104, 97–103.31370990
Wilkerson, J. M., Noor, S. W., Rhoton, J. M., Li, D., & Rosser, B. R. S. (2018). Differentially classified methamphetamine-using men who have sex with men: A latent class analysis. Drug and Alcohol Dependence, 192, 129–136.30248559
Wimberly, A. S., Hyatt, J. M., & McKay, J. R. (2018). Effect of continuing care for people with cocaine dependence on criminal justice sentences. Behavioral Sciences and the Law, 36(1), 116–129.29460440
Winkelman, T. N. A., Admon, L. K., Jennings, L., Shippee, N. D., Richardson, C. R., & Bart, G. (2018). Evaluation of amphetamine-related hospitalizations and associated clinical outcomes and costs in the United States. JAMA Network Open, 1(6), e183758.30646256
Winn, L. A. P., Paquette, K. L., Donegan, L. R. W., Wilkey, C. M., & Ferreira, K. N. (2019). Enhancing adolescent SBIRT with a peer-delivered intervention: An implementation study. Journal of Substance Abuse Treatment, 103, 14–22.31229188
Wise, R. A. (2008). Dopamine and reward: The anhedonia hypothesis 30 years on. Neurotoxicity Research, 14(2–3), 169–183.19073424
Wise, R. A., & Koob, G. F. (2014). The development and maintenance of drug addiction. Neuropsychopharmacology, 39(2), 254–262.24121188
Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction (pp. 21–42). Elsevier.
Wood, S., Sage, J. R., Shuman, T., & Anagnostaras, S. G. (2014). Psychostimulants and cognition: A continuum of behavioral and cognitive activation. Pharmacological Reviews, 66(1), 193–221.24344115
Woolum, J. A., Travis, M., Running Cranem, C., Bailey, A. M., Baum, R. A., & Akpunonu, P. (2019). Use of lidocaine for treatment of pulseless ventricular tachycardia after massive cocaine overdose. Toxicology Communications, 3(1), 19–22.
Workowski, K. A., & Bolan, G. A. (2015). Sexually transmitted diseases treatment guidelines, 2015. MMWR Recommendations and Reports, 64(RR-3), 1–137.
World Health Organization & United Nations Office on Drugs and Crime (2020). International standards for the treatment of drug use disorders: Revised edition incorporating results of field testing. https://www.who.int/publications/i/item/international-standards-for-the-treatment-of-drug-use-disorders
Worley, J. (2014). Identification and management of prescription drug abuse in pregnancy. Journal of Perinatal and Neonatal Nursing, 28(3), 196–203.25062521
Wright, T. E., Schuetter, R., Tellei, J., & Sauvage, L. (2015). Methamphetamines and pregnancy outcomes. Journal of Addiction Medicine, 9(2), 111–117.25599434
Wu, L. T., Pan, J. J., Blazer, D. G., Tai, B., Stitzer, M. L., & Woody, G. E. (2010). Using a latent variable approach to inform gender and racial/ethnic differences in cocaine dependence: A National Drug Abuse Treatment Clinical Trials Network Study. Journal of Substance Abuse Treatment, 38(Suppl. 1), S70–S79.20307798
Wunderli, M. D., Vonmoos, M., Niedecker, S. M., Hulka, L. M., Preller, K. H., Baumgartner, M. R., … Quednow, B. B. (2016). Cognitive and emotional impairments in adults with attention-deficit/hyperactivity disorder and cocaine use. Drug and Alcohol Dependence, 163, 92–99.27085500
Yang, X., Wang, Y., Li, Q., Zhong, Y., Chen, L., Du, Y., … Yan, J. (2018). The main molecular mechanisms underlying methamphetamine-induced neurotoxicity and implications for pharmacological treatment. Frontiers in Molecular Neuroscience, 11, 186.29915529
Yanofski, J. (2011). The dopamine dilemma—Part II: Could stimulants cause tolerance, dependence, and paradoxical decompensation? Innovations in Clinical Neuroscience, 8(1), 47–53.21311708
Yasaei, R., & Saadabadi, A. (2021). Methamphetamine. In StatPearls. Retrieved June 1, 2021, from https://www.ncbi.nlm.nih.gov/books/NBK535356/
Yazdanian, M., Armoon, B., Noroozi, A., Mohammadi, R., Bayat, A. H., Ahounbar, E., … Hemmat, M. (2020). Dental caries and periodontal disease among people who use drugs: A systematic review and meta-analysis. BMC Oral Health, 20(1), 44.32041585
Ye, L., Peng, J. S., Wang, X., Wang, Y. J., Luo, G. X., & Ho, W. Z. (2008). Methamphetamine enhances hepatitis C virus replication in human hepatocytes. Journal of Viral Hepatitis, 15(4), 261–270.18307590
Yee, T., Perantie, D. C., Dhanani, N., & Brown, E. S. (2004). Drug dreams in outpatients with bipolar disorder and cocaine dependence. Journal of Nervous and Mental Disease, 192(3), 238–242.
Yeung, J. T., Williams, J., & Bowling, W. M. (2013). Effect of cocaine use on outcomes in traumatic brain injury. Journal of Emergencies, Trauma, and Shock, 6(3), 189–194.
Yoshioka-Maxwell, A., Rice, E., Rhoades, H., & Winetrobe, H. (2015). Methamphetamine use among homeless former foster youth: The mediating role of social networks. Journal of Alcoholism and Drug Dependence, 3(2), 197.26146647
Young, D., & Scoville, W. B. (1938). Paranoid psychosis in narcolepsy and the possible danger of enzedrine treatment. Medical Clinics of North America, 22, 637–646.
Young, L. B., Grant, K. M., & Tyler, K. A. (2015). Community-level barriers to recovery for substance-dependent rural residents. Journal of Social Work Practice in the Addictions, 15(3), 307–326.
Younger, D. S. (2019). Central nervous system vasculitis due to substance abuse. Neurologic Clinics, 37(2), 425–440.30952417
Yu, G., Wall, M. M., Chiasson, M. A., & Hirshfield, S. (2015). Complex drug use patterns and associated HIV transmission risk behaviors in an Internet sample of U.S. men who have sex with men. Archives of Sexual Behavior, 44(2), 421–428.25104104
Zapolski, T. C. B., Baldwin, P. D., & Lejuez, C. W. (2016). Examining risk for frequent cocaine use: Focus on an African American treatment population. Substance Use and Misuse, 51(7), 882–891.27100459
Zhang, S. X., Shoptaw, S., Reback, C. J., Yadav, K., & Nyamathi, A. M. (2018). Cost-effective way to reduce stimulant-abuse among gay/bisexual men and transgender women: A randomized clinical trial with a cost comparison. Public Health, 154, 151–160.29245022
Zhou, C., Crawford, A., Serhal, E., Kurdyak, P., & Sockalingam, S. (2016). The impact of Project ECHO on participant and patient outcomes: A systematic review. Academic Medicine, 91(10), 1439–1461.27489018
Zhu, Y., Evans, E. A., Mooney, L. J., Saxon, A. J., Kelleghan, A., Yoo, C., & Hser, Y.-I. (2018). Correlates of long-term opioid abstinence after randomization to methadone versus buprenorphine/naloxone in a multi-site trial. Journal of Neuroimmune Pharmacology, 13, 488–497.30094695
Zimmerman, J. L. (2012). Cocaine intoxication. Critical Care Clinics, 28(4), 517–526.22998988
Zorick, T., Nestor, L., Miotto, K., Sugar, C., Hellemann, G., Scanlon, G., … London, E. D. (2010). Withdrawal symptoms in abstinent methamphetamine-dependent subjects. Addiction, 105(10), 1809–1818.20840201
Zwick, J., Appleseth, H., & Arndt, S. (2020). Stigma: How it affects the substance use disorder patient. Substance Abuse Treatment, Prevention, and Policy, 15(1), 50.