# Consensus Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

## Chair

Harvey A. Siegal, Ph.D.
Professor and Director
Substance Abuse Intervention Programs School of Medicine
Wright State University Dayton, Ohio

## Workgroup Leaders

James A. Hall, Ph.D.
Associate Professor
School of Social Work
University of Iowa
Iowa City, Iowa

Howard Isenberg, M.A.
Division Director
Outpatient Treatment Services
Northeast Treatment Centers
Wilmington, Delaware

Mary Nakashian
Vice President and Director of Program Demonstration
National Center on Addiction and Substance Abuse at Columbia University (CASA)
New York, New York

Richard C. Rapp, M.S.W.
Co-Investigator, Assistant Professor Substance
Abuse Intervention Programs School of Medicine
Wright State University Dayton, Ohio

M. Susan Ridgely, M.S.W., J.D.
Associate Professor
Department of Mental Health Law and Policy
Florida Mental Health Institute
University of South Florida Tampa, Florida

Patrick Sullivan, Ph.D.
Division Director Division of Mental Health
Family and Social Services Administration
Indianapolis, Indiana

## Panelists

Kathleen Andolina, R.N., M.S., C.S.
Consultant
Center for Case Management Natick, Massachusetts

Barbara A. Blakeney, M.S., R.N., C.S., A.N.P.
Principal Public Health Nurse
Long Island Shelter
Homeless Services and Addiction Services Public Health Commission
Boston, Massachusetts

Elizabeth Garcia, M.S.W.
Director
Managed Care
Pinal Gila Behavioral Health Association Apache Junction, Arizona

Margaret E. Hanna, M.Ed.
Executive Director
Bucks County Drug and Alcohol Commission
New Britain, Pennsylvania

Albert Hasson, M.S.W.
Administrative Director
Matrix Institute on Addictions
Pizarro Treatment Center
Los Angeles, California

Judith Levy, Ph.D.
Associate Professor
School of Public Health
University of Illinois
Chicago, Illinois

Duane C. McBride, Ph.D.
Director of Research
Behavioral Science Department
Andrews University
Berin Springs, Michigan

Sylvia M. Ryan, M.A., B.A.
Program Director
Rocky Boy Health Board
Rocky Boy Chemical Dependency Program
Box Elder, Montana

Anne C. Sowell, A.C.S.W., L.I.S.W.
Coordinator of Community Projects
Miracle Village
MetroHealth Medical Center
Cleveland, Ohio