# Editorial Advisory Board

Note: The information given indicates each participant's affiliation during the time the board was convened and may no longer reflect the individual's current affiliation.

Karen Allen, Ph.D., R.N., C.A.R.N.
President
National Nurses Society on Addictions
Associate Professor
Department of Psychiatry, Community Health, and Adult Primary Care
University of Maryland, Baltimore
Baltimore, Maryland

Richard L. Brown, M.D., M.P.H.
Associate Professor
Department of Family Medicine
University of Wisconsin School of Medicine
Madison, Wisconsin

Dorynne Czechowicz, M.D.
Associate Director
Medical/Professional Affairs Treatment Research Branch
Division of Clinical and Services Research
National Institute on Drug Abuse Rockville, Maryland

Linda S. Foley, M.A. Former
Director
Project for Addiction Counselor Training
National Association of State Alcohol and Drug Counselors Director
Treatment Improvement Exchange Health Systems Research, Inc.
Washington, D.C.

Wayde A. Glover, MIS, NCAC II Director
Commonwealth Addictions Consultants and Trainers
Richmond, Virginia

Pedro J. Greer, M.D.
Assistant Dean for Homeless Education
University of Miami School of Medicine
Miami, Florida

Thomas W. Hester, M.D.
Former State Director Substance Abuse Services Division of Mental Health
Mental Retardation and Substance Abuse
Georgia Department of Human Resources
Atlanta, Georgia

Gil Hill
Director
Office of Substance Abuse American Psychological Association
Washington, D.C.

Douglas B. Kamerow, M.D., M.P.H.
Director
Center for Practice and Technology Assessment
Agency for Health Care Policy and Research
Rockville, Maryland

Stephen W. Long
Director
Office of Policy Analysis
National Institute on Alcohol Abuse and Alcoholism
Rockville, Maryland

Richard A. Rawson, Ph.D.
Executive Director
Matrix Center
Los Angeles, California

Ellen A. Renz, Ph.D.
Former Vice President of Clinical Systems
MEDCO Behavioral Care Corporation
Kamuela, Hawaii

Richard K. Ries, M.D.
Director and Associate Professor
Outpatient Mental Health Services and Dual Disorder Programs
Harborview Medical Center
Seattle, Washington

Sidney H. Schnoll, M.D., Ph.D.
Chairman
Division of Substance Abuse Medicine
Medical College of Virginia
Richmond, Virginia