# Appendix E Field Reviewers

Note: The information given indicates each participant's affiliation during the time the review was conducted and may no longer reflect the individual's current affiliation.

Darlene Allen, M.S.
Director
Child Welfare Services Children's Friend and Services
Providence, Rhode Island

Andrea G. Barthwell, M.D.
President
Encounter Medical Group, P.C. Oak Park, Illinois

Janice S. Bennett, M.S., C.S.A.C.
Project Director
Addiction Technology Transfer Center of Hawaii
Honolulu, Hawaii

Saroja A. Boaz
Executive Director
Intake Assessment and Referral Center
Flint, Michigan

Kim Bowman
Director
Government Services
Center Chester County Department of Drug and and Alcohol Services
West Chester, Pennsylvania

Patricia Bradford, L.I.S.W., L.M.F.T., C.T.S.
P.A. Bradford and Associates
Columbia, South Carolina

Mary Candace Burger, Ph.D.
Assistant Professor
Division of Geriatric Psychiatry Department of Psychiatry Vanderbilt Medical School
Nashville, Tennessee

Donna L. Caldwell, Ph.D.
Senior Research Associate
National Perinatal Information Center Providence
Rhode Island

Donna H. Caum, M.S.S.W.
Treatment Program Consultant
Bureau of Alcohol and Drug Abuse Services Tennessee
Department of Health
Nashville, Tennessee

Patrick R. Connelly
Substance Abuse Program Consultant
Division of Mental Health, Development Disabilities and Substance Abuse Services
North Carolina Department of Health and Human Services
Raleigh, North Carolina

Gary Cox, Ph.D.
Research Associate Professor
ADAI University of Washington
Seattle, Washington

Martin C. Doot, M.D.
Chief Division of Addiction Medicine
Addiction Medicine/ Family Practice Lutheran General Hospital Advocate
Park Ridge, Illinois

Larry W. Dupree, Ph.D.
Professor
Department of Aging and Mental Health
Florida Mental Health Institute
University of South Florida
Tampa, Florida

Mary E. Evans, R.N, Ph.D.
Director of Research
College of Nursing (MDC 22)
University of South Florida
Tampa, Florida

Gary L. Fisher, Ph.D.
Addiction Technology Transfer
Center College of Education
University of Nevada at Reno Reno, Nevada

Steven L. Gallon, Ph.D.
Program Director
Office of Alcohol and Drug Abuse Programs
Northwest Frontier Addiction Technology Transfer Center
Salem, Oregon

Theodore M. Godlaski, M.Div., I.C.D.C.
Director of Community
Treatment Project Center for Alcohol and Drug Research
University of Kentucky
Lexington, Kentucky

Susan H. Godley, Ph.D.
Senior Research Consultant
Lighthouse Institute Chestnut Health Systems
Bloomington, Illinois

Darryl M. Grafton, M.Div., C.C.D.C.
Clinical Supervisor
Southeast Baltimore Center for Treatment
Bayview Medical Center
Johns Hopkins University
Baltimore, MD

Marge L. Hazen
Systems and Funding Development Specialist
Bureau of Substance Abuse Services
Department of Health and Social Services State of Wisconsin
Madison, Wisconsin

Maya Hennessey, C.R.A.D.C.
Women's Specialist
Office of Special Programs Illinois
Department of Alcoholism and Substance Abuse
Chicago, Illinois

Robert Holden, M.A.
Program Director
Partners in Drug Abuse Rehabilitation Counseling
Washington, D.C.

Deborah Horan
Manager
Special Issues American College of Obstetrics and Gynecology
Washington, D.C.

Mary Beth Johnson, M.S.W.
University of Missouri at Kansas City
Kansas City, Missouri

Patti Juliana
Director of Clinical Services
Division of Substance Abuse
Albert Einstein College of Medicine
Bronx, New York

Linda Kaplan
Executive Director
National Association of Alcoholism and Drug Abuse Counselors
Arlington, Virginia

Karen Kelly-Woodall, M.S., M.A.C., N.C.A.C. II
Cork Institute Morehouse School of Medicine
Atlanta, Georgia

Michael W. Kirby, Jr., Ph.D.
Chief Executive Officer
Arapahoe House, Inc.
Thornton, Colorado

Mark L. Kraus, M.D.
Westside Medical Group
Waterbury, Connecticut

Jeffrey N. Kushner
Drug Court Administrator
22nd Judicial District Municipal Court of Saint Louis
Saint Louis, Missouri

Carl G. Leukefeld, D.S.W.
Director
Center on Drug and Alcohol Research
University of Kentucky
Lexington, Kentucky

Sheera Lipshitz
Director
Assertive Treatment Team Brandywine Counseling, Inc.
Wilmington, Delaware

Bruce Lorenz, N.C.A.C. II
Director Thresholds, Inc.
Dover, Delaware

Greg J. Madden, Ph.D.
Research Associate
Human Behavioral Pharmacology Laboratory
University of Vermont
Burlington, Vermont

Jennifer Mankey, B.S.W., M.P.A.
Project Director
Denver Juvenile Justice Treatment Network
Denver, Colorado

Patrice Muchowski, Sc.D.
Vice President
Clinical Services Adcare Hospital of Worcester
Worcester, Massachusetts

Marlene O'Connell, R.N.
Manager Behavioral Health Services
Benefits Healthcare
Great Falls, Montana

Gennaro Ottomanelli, Ph.D.
Director
Division of Drug Dependence Kings County Addictive Disease Hospital
Brooklyn, New York

Elizabeth A. Peyton
Executive Director
National TASC Silver Spring, Maryland

Ronald Pike, M.D.
AdCare Hospital of Worcester
Worcester, Massachusetts

Deborah Powers
IDU/AIDS Treatment Specialist
State Methadone Authority State
Department of Health and Family Services
Madison, Wisconsin

Lynda A. Price, Ph.D., I.C.A.D.C.
Treatment Coordinator National Drug Commission
Global House Hamilton, Bermuda

Anthony Quintiliani, Ph.D.
Clinical Director
Chief Psychologist Drug and Alcohol
Division Howard Center for Human Services South Burlington
Vermont

Patricia Reihl
Coordinator
Spring House Paramus, New Jersey

Margaret M. Salinger, M.S.N., R.N., C.A.R.N.
National Nurses Society on Addiction c/o Department of Veterans Affairs Medical Center
Coatesville, Pennsylvania

Anna M. Scheyett, M.S.W.
Program Coordinator
Behavioral Health Care Resource Program
School of Social Work
University of North Carolina at Chapel Hill
Chapel Hill, North Carolina

Stephen Schoen, Ph.D.
Director
Alcohol and Drug Awareness Program
Department of State Medical Services
Washington, D.C.

Rene W. Seidel
Director
HIV Services Tarzana Treatment Center
Tarzana, California

Michael R. Sosin, M.S.W., Ph.D.
Professor
School of Social Service Administration
University of Chicago
Chicago, Illinois

Flo A. Stein, M.P.A.
Acting Section Chief
Division of Mental Health
Developmental Disabilities and Substance Abuse Services
Alcohol and Drug Services
Raleigh, North Carolina

Richard T. Suchinsky, M.D.
Associate Chief Addictive Disorders Mental Health and Behavioral Sciences Services
Department of Veterans Affairs
Washington, D.C.

Suzan Swanton
Clinical Supervisor
Glenwood Life Counseling Center
Baltimore, Maryland

Donald L. Tomlin
Specialist Nashville Area
Indian Health Service Substance Abuse Indian Health Service
Cherokee, North Carolina

Robert Walker, M.S.W., L.C.S.W., B.C.D.
Director
Bluegrass East Comprehensive Care Center
Lexington, Kentucky

Deborah Watson, Ph.D.
Program Operations Manager
Cleveland CARES Target Cities Alcohol and Drug Addiction Services Board
Cleveland, Ohio

Robert Whitney, M.D.
Medical Consultant
Office of Alcoholism and Substance Abuse Research
Institute on Addiction
Buffalo, New York

Annette H. Wieser
Regional Director
Program Administration Texas Commission on Alcohol and Drug Abuse
Austin, Texas

Janet S. Woodburn
President
Bridgeway Counseling Services, Inc.
Saint Charles, Missouri