# Appendix D Resource Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Robert E. Anderson
Director
Quality Assurance Programs
National Association of State Alcohol and Drug Abuse Directors, Inc.
Washington, D.C.

Lynn Aronson
Housing Resource Manager
Homeless Programs Branch
Center for Mental Health Services
Division of State and Community Systems Development
Rockville, Maryland

James Brennan
Senior Staff Associate
National Association of Social Workers
Washington, D.C.

Peter J. Cohen, M.D., J.D.
Special Expert
Medications Development Division
National Institute on Drug Abuse
Rockville, Maryland

Linda S. Foley, M.A.
Member TIPS Editorial Advisory Board Director
Treatment Improvement Exchange Health Systems Research, Inc.
Washington, D.C.

Helen Howerton, M.A.
Director
Child and Family Development
Office of Planning, Research, and Evaluation Administration for Children and Families
Washington, D.C.

Mary Nakashian
Vice President and Director of Program Demonstration
National Center on Addiction and Substance Abuse Columbia University
New York, NY

Elizabeth Rahdert, Ph.D.
Research Psychologist Treatment
Research Branch
Division of Clinical and Services Research National Institute on Drug Abuse
Rockville, Maryland

Larry Rickards, Ph.D.
Director
Intergovernmental Initiatives Homeless Programs Branch
Center for Mental Health Services
Rockville, Maryland

Barbara Roberts, Ph.D.
Senior Policy Analyst
Executive Office
White House Office of National Drug Control Policy
Washington, D.C.

Santo Ruiz
Project Officer
Community Support Program
Division of State and Community Systems Development
Center for Mental Health Services
Rockville, Maryland

Richard T. Suchinsky, M.D.
Associate Chief
Addictive Disorders
Mental Health and Behavioral Sciences Services
Department of Veterans Affairs
Washington, D.C.