# Appendix A Bibliography

Alemi, F.; Stephens, R.C.; and Butts, J. Case management: A telecommunications practice model. In: Ashery, R.S., ed. Progress and Issues in Case Management. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 261–273.
Alter, C., and Hage, J. Organizing Working Together. Newbury Park, CA: Sage, 1993.
Alterman, A.I.; Bedrick, J.; Howden, D.; and Maany, I. Reducing waiting time for substance abuse treatment does not reduce attrition. Journal of Substance Abuse 6(3):325–332, 1994.7703709
American Hospital Association. Case management: An aid to quality and continuity of care. In: Rose, S.R., ed. Case Management and Social Work. New York: Longman, 1992. pp. 149–159.
American Society of Addiction Medicine. Patient Placement Criteria for the Treatment of Substance-Related Disorders. 2^nd^ edition. Chevy Chase, MD: American Society of Addiction Medicine, 1997
Anthony, W.A., and Farkas, M. A client outcome planning model for assessing psychiatric rehabilitation interventions. Schizophrenic Bulletin 8(1):13–38, 1982.
Ashery, R.S. Case management for substance abusers: More issues than answers. Journal of Case Management 3(4):179–183, 1994.7735091
Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992.
Ashery, R.S.; Carlson, R.G.; Falck, R.S.; and Siegal, H.A. Injection drug users, crack-cocaine users, and human service utilization: An exploratory study. Social Work 40(1):75–82, 1995.7863375
Ballew, J.R., and Mink, G. Case Management in Social Work: Developing the Professional Skills Needed for Work With Multiproblem Clients. Springfield, IL: Charles C. Thomas, 1996.
Bander, K.W.; Goldman, D.S.; Schwartz, M.A.; Rabinowitz, E.; and English, J.T. Survey of attitudes among three specialties in a teaching hospital toward alcoholics. Journal of Medical Education 62(1):17–24, 1987.3795240
Beckman, L., and Amaro, H. Personal and social difficulties faced by women and men entering alcoholism treatment. Journal of Studies on Alcohol 47:135–145, 1986.3713175
Bellack, A.S.; Mueser, K.T.; Gingerich, S.; and Agresta, J. Social Skills Training for Schizophrenia: A Step-by-Step Guide. New York: Guilford Press, 1997.
Bokos, P.; Mejta, C.; Monks, R.; and Mickenberg, J. Case management program: A case management model for intravenous drug users. In: Inciardi, J.A., ed. Innovative Approaches to the Treatment of Drug Abuse: Program Models and Strategies. Westport, CT: Greenwood, 1993. pp. 87–96.
Bond, G.R.; McGrew, J.H.; and Fekete, D.M. Assertive outreach for frequent users of psychiatric hospitals: A meta-analysis. Journal of Mental Health Administration 22: 4–16, 1995.10141270
Bonham, G.S.; Hague, D.E.; Abel, M.H.; Cummings, P.; and Deutsch, R.S. Louisville's Project Connect for the homeless alcohol and drug abuser. In: Stahler, G.J., and Stimmel, B., eds. Alcoholism and Drug Abuse Among Homeless Men and Women. New York: Haworth Press, 1990. pp. 57–78.
Braucht, N.G.; Reichardt, C.S.; Geissler, L.J.; Bormann, C.A.; Kwiatkowski, C.F.; and Kirby, M.W. Effective services for homeless substance abusers. In: Stahler, G.J., and Stimmel, B., eds. The Effectiveness of Social Interventions for Homeless Substance Abusers. New York: Haworth Medical Press, 1995. pp. 87–109.
Brekke, J. The model-guided method of monitoring program implementation. Evaluation Review 11(3):281–299, 1987.
Brindis, C.; Pfeffer, R.; and Wolf, A. A case management program for chemically dependent clients with multiple needs. Journal of Case Management 4(1):22–28, 1995.7795539
Brindis, C.D., and Theidon, K.S. The role of case management in substance abuse treatment services for women and children. Journal of Psychoactive Drugs 29(1): 79–88, 1997.9110268
Broskowski, A., and Eaddy, M. Community mental health in a managed care environment. Administration and Policy in Mental Health 27:335–352, 1994.
Brown, J.D. Preprofessional socialization and identity transformation: The case of the professional ex-. Journal of Contemporary Ethnography 20(2):157–178, 1991.
Brown, S.A.; Vik, P.W.; and Creamer, V.A. Characteristics of relapse following adolescent substance abuse treatment. Addictive Behaviors 14:291–300, 1989.2787585
Bureau of Justice. Treatment Alternatives to Street Crime. 2^nd^ ed. Administration Program Brief. Washington, DC: U.S. Department of Justice, April 1992.
Bureau of Justice Assistance. Guidelines for Implementing and Operating TASC Programs. Washington, DC: U.S. Department of Justice, 1988.
Case Management Standards Work Group. NASW Standards for Social Work Case Management. Washington, DC: National Association of Social Workers Press, 1992.
Center for Substance Abuse Treatment. Pregnant, Substance-Using Women. Treatment Improvement Protocol (TIP) Series, Number 2. HHS Pub. No. (SMA) 93-1998. Washington, DC: U.S. Government Printing Office, 1993a.
Center for Substance Abuse Treatment. Guidelines for the Treatment of Alcohol and Other Drug Abusing Adolescents. Treatment Improvement Protocol (TIP) Series, Number 4. HHS Pub. No. (SMA) 93-2010. Washington, DC: U.S. Government Printing Office, 1993b.
Center for Substance Abuse Treatment. Screening and Assessment for Alcohol and Other Drug Abuse Among Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series, Number 7. HHS Pub. No. (SMA) 94-2076. Washington, DC: U.S. Government Printing Office, 1994a.
Center for Substance Abuse Treatment. Assessment and Treatment of Patients with Coexisting Mental Illness and Alcohol and Other Drug Abuse. Treatment Improvement Protocol (TIP) Series, Number 9. HHS Pub. No. (SMA) 94-2078. Washington, DC: U.S. Government Printing Office, 1994b.
Center for Substance Abuse Treatment. Combining Substance Abuse Treatment With Intermediate Sanctions for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series, Number 12. HHS Pub. No. (SMA) 94-3004. Washington, DC: U.S. Government Printing Office, 1994c.
Center for Substance Abuse Treatment. The Role and Current Status of Patient Placement Criteria in the Treatment of Substance Use Disorders. Treatment Improvement Protocol (TIP) Series, Number 13. HHS Pub. No. (SMA) 95-3021. Washington, DC: U.S. Government Printing Office, 1995a.
Center for Substance Abuse Treatment. Planning for Alcohol and Other Drug Abuse Treatment for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series, Number 17. HHS Pub. No. (SMA) 95-3039. Washington, DC: U.S. Government Printing Office, 1995b.
Center for Substance Abuse Treatment. Combining Alcohol and Other Drug Abuse Treatment With Diversion for Juveniles in the Justice System. Treatment Improvement Protocol (TIP) Series, Number 21. HHS Pub. No. (SMA) 95-3051. Washington, DC: U.S. Government Printing Office, 1995c.
Center for Substance Abuse Treatment. Purchasing Managed Care Services for Alcohol and Other Drug Treatment: Essential Elements and Policy Issues. Technical Assistance Publication (TAP) Series, Number 16. HHS Pub. No. (SMA) 95-3040. Washington, DC: U.S. Government Printing Office, 1995d.
Center for Substance Abuse Treatment. Treatment Drug Courts: Integrating Substance Abuse Treatment With Legal Case Processing. Treatment Improvement Protocol (TIP) Series, Number 23. DHS Pub. No. (SMA) 96-3113. Washington, DC: U.S. Government Printing Office, 1996a.
Center for Substance Abuse Treatment. Addiction Counseling Competencies: The Knowledge, Skills, and Attitudes of Professional Practice. Technical Assistance Protocol (TAP) Series, Number 21. HHS Pub. No. (SMA) 98-3171. Washington, DC: U.S. Government Printing Office, 1998.
Chamberlain, R. and Rapp, C.A. A decade of case management: A methodological review of outcome research. Community Mental Health Journal 27:171–188, 1991.2055004
Conrad, K.J.; Hultman, C.I.; and Lyons, J.S. Treatment of the chemically dependent homeless: A synthesis. Alcoholism Treatment Quarterly 10(3–4):235–246, 1993.
Cook, F. TASC: Case management models linking criminal justice and treatment. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 368–382.
Cook, F. “Client Management: Fundamental Issues.” Presentation to Criminal Justice Treatment Network Grantee Meeting, Center for Substance Abuse Treatment, Washington, DC: April 28, 1997.
Cook, K. Exchange and power in networks of interorganizational relations. The Sociological Quarterly 18(1):62–82, 1977.
Cox, G.B.; Meijer, L.; Carr, D.I.; and Freng, S.A. Systems Alliance and Support (SAS): A program of intensive case management for chronic public inebriates: Seattle. In: Conrad, K.J.; Hultman, C.I.; and Lyons, J.S., eds. Treatment of the Chemically Dependent Homeless: Theory and Implementation in Fourteen American Projects. New York: Haworth Press, 1993. pp. 125–138.
Cross, T.; Bazron, B.; Dennis, K.; and Isaacs, M. Towards a Culturally Competent System of Care: A Monograph on Effective Services for Minority Children Who Are Severely Emotionally Disturbed. Washington, DC: Georgetown University Child Development Center, 1989.
Crystal, S. Chronic and Situational Dependency: Long Term Residents in a Shelter for Men. New York: Human Resources Administration, 1982.
DeLeon, G. Legal pressure in therapeutic communities. Journal of Drug Issues 18:625–640, 1988.
DiMaggio, P. Structural analysis of organizational fields: A block model approach. Research in Organizational Behavior 8:335–370, 1986.
Drake, R.E.; Bebout, R.R.; and Roach, J.P. A research evaluation of social network case management for homeless persons with dual disorders. In: Harris, M., and Bergman, H.C., eds. Case Management for Mentally Ill Patients: Theory and Practice. Vol. 1., Chronic Mental Illness. Langhorne, PA: Harwood Academic Publishers, 1993. pp. 83–98.
Drake, R. and Noordsey, D. Case management for people with coexisting severe mental disorder and substance abuse disorder. Psychiatric Annals 24(8): 427–431, 1994.
Falck, R.; Carlson, R.G.; Price, S.K.; and Turner, J.A. Case management to enhance HIV risk reduction among users of injection drugs and crack cocaine. Journal of Case Management 3(4):162–166, 1994.7735088
Falck, R.; Siegal, H.A.; and Carlson, R.G. Case management to enhance AIDS risk reduction for injection drug users and crack users: Theoretical and practical considerations. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 167–180.
Fletcher, B.W.; Inciardi, J.A.; and Horton, A.M., eds. Drug Abuse Treatment: The Implementation of Innovative Approaches to Drug Abuse Treatment. Westport, CT: Greenwood Press, 1994.
Freeman, Michael A., MD. General Editor. How to Respond to Managed Behavioral Health Care—A Workbook Guide to Your Organization's Success. Tiburon, CA: CentraLink Publications, 1995.
Gilbert, F.S. The effect of type of aftercare follow-up on treatment outcome among alcoholics. Journal of Studies on Alcohol 49(2):149–159, 1988.2834605
Gillespie, D.F., and Murty, S.A. Cracks in a postdisaster service delivery network. American Journal of Community Psychology 22(5):639–660, 1994.
Gilson, S.F.; Chilcoat, H.D.; and Stapleton, J.M. Illicit drug use by persons with disabilities: Insights from the National Household Survey on Drug Abuse. American Journal of Public Health 86(11):1613–1615, 1996.8916529
Godley, S.H.; Godley, M.D.; Pratt, A.; and Wallace, J.L. Case management services for adolescent substance abusers: A program description. Journal of Substance Abuse Treatment 11:309–317, 1994.7966501
Graham, K., and Birchmore-Timney, C. Case management in addictions treatment. Journal of Substance Abuse Treatment 7:181–188, 1990.2172567
Harris, M., and Bergman, H. Case management with the chronically mentally ill: a clinical perspective. American Journal of Orthopsychiatry 57(2): 296–302, April 1987.
Harvey, P.D.; Davidson, M.; Mueser, K.T.; Parella, M.; White, L.; and Powchik, P. The social-adaptive functioning evaluation (safe): A rating scale for geriatric psychiatric patients. Schizophrenia Bulletin 23:131–145, 1997.9050119
Hasson, A.L.; Grella, C.E.; Rawson, R.; and Anglin, M.D. Case management within a methadone maintenance program. A research demonstration project for HIV risk reduction. Journal of Case Management 3(4):167–172, 1994.7735089
Hepburn, M. Social problems. Baillieres Clinical Obstet. Gynaecol. 4(1): 149–168, 1990.
Hoffman, N.G.; Halikas, J.A.; Mee-Lee, D.; and Weedman, R.D. Patient Placement Criteria for the Treatment of Psychoactive Substance Use Disorders. Chevy Chase, MD: American Society of Addiction Medicine, 1991.
Hubbard, R.L.; Collins, J.J.; Rachel, J.V.; and Cavanaugh, E.R. The criminal justice client in drug abuse treatment. In: Leukenfeld, C.J., and Tims, F.M., eds. Compulsory Treatment of Drug Abuse: Research and Clinical Practice. Rockville, MD: National Institute on Drug Abuse, 1988. pp. 57–80.
Inciardi, J.A.; Martin, S.S.; and Scarpitti, F.R. Appropriateness of assertive case management for drug-involved prison releases. Journal of Case Management 3(4):145–149, 1994.7735085
Inciardi, J.A., and McBride, D. Treatment Alternatives to Street Crime: History, Experience, and Issues. U.S. Department of Health and Human Services, Public Health Services. HHS Pub. No. (ADM) 91-1749. Washington, DC: U.S. Government Printing Office, 1991.
Inciardi, J.A.; Tims, F.M.; and Fletcher, B.W., eds. Innovative Approaches in the Treatment of Drug Abuse: Program Models and Strategies. Westport, CN: Greenwood Press, 1993.
Institute of Medicine. Broadening the Base of Treatment for Alcohol Problems. Washington, DC: National Academy Press, 1990.
Institute of Medicine. Treating Drug Problems. Vol. 1. Washington, DC: National Academy Press, 1990.
Intagliata, J. Improving the quality of community care for the chronically mentally disabled: The role of case management. Schizophrenia Bulletin 8(4):655–674, 1982.7178854
Intagliata, J. Operationalizing a case management system: A multilevel approach. National Conference on Social Welfare: Case Management: State of the Art. Washington, DC: U.S. Department of Health and Human Services, 1981.
Joint Commission on Accreditation of Healthcare Organizations. Principles of Accreditation of Community Mental Health Service Programs. Oakbrook Terrace, IL: Joint Commission on Accreditation of Hospitals, 1979.
Joint Commission on Accreditation of Healthcare Organizations. Accreditation Manual for Mental Health, Chemical Dependency, and Mental Retardation/Developmental Disabilities Services. Vol. 1, Standards. Oakbrook Terrace, IL: Joint Commission on Accreditation of Healthcare Organizations, 1995.
Kanter, J.S. Case management of the young adult chronic patient: A clinical perspective. In: Kanter, J.S., ed. Clinical Issues in Treating the Chronic Mentally Ill: New Directions for Mental Health Services. No. 27. San Francisco: Jossey-Bass, 1985. pp. 77–92.
Kanter, J. Case management with long-term patients: A comprehensive approach. In: Soreff, S., ed. Handbook for the Treatment of the Seriously Mentally Ill. Seattle: Hogrefe and Huber, 1996. pp. 171–189.
Kanter, J. Clinical issues in the case management relationship. In: Harris, M., and Bachrach, L., eds. Clinical Case Management New Directions for Mental Health Services. No 40. San Francisco: Jossey-Bass, Winter 1988.
Kennedy, B.P., and Minami, M. The Beech Hill Hospital/Outward Bound adolescent chemical dependency treatment program. Journal of Substance Abuse Treatment 10:395–406, 1993.8411298
Khantzian, E., and Treece, C. Psychiatric diagnosis of narcotic addicts: Recent findings. Archives of General Psychiatry 42:1067–1071, 1985.4051684
Kosten, T.R., and Kleber, H.D. Differential diagnosis of psychiatric comorbidity in substance abusers. Journal of Substance Abuse Treatment 5:201–206, 1988.3216436
Lehman, A.F.; Herron, J.D.; Schwartz, R.P.; and Myers, C.P. Rehabilitation for adults with severe mental illness and substance use disorders: A clinical trial. Journal of Nervous and Mental Disease 181(2): 86–90, February, 1993.
Levy, J.A.; Gallmeier, C.P.; Weddington, W.W.; and Wiebel, W.W. Delivering case management using a community-based service model of drug intervention. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 145–166.
Levy, J.A.; Strenski, T.; and Amick, D.J. Community-based case management for active injecting drug users. In: Albrecht, G.L., ed. Advances in Medical Sociology. Vol. 6, Case and Care Management. Greenwich, CT: JAI Press, 1995. pp. 183–206.
Lidz, V.; Bux, D.A.; Platt, J.J.; and Iguchi, M.Y. Transitional case management: A service model for AIDS outreach projects. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 112–144.
Lightfoot, L.; Rosenbaum, P.; Ogurzsoff, S.; Laverty, G.; Kusiar, S.; Barry, K.; and Reynolds, W. Final Report of the Kingston Treatment Programme Development Research Project. Ottawa: Department of Health, Health Promotion Directorate, 1982.
Luborsky, L.; McLellan, A.T.; Woody, G.E.; O'Brien, C.P.; and Auerbauch, A. Therapist success and its determinants. Archives of General Psychiatry 42: 602–611, 1985.4004503
Manoleas, P., ed. The Cross Cultural Practice of Clinical Case Management in Mental Health. New York: Haworth Press, 1997.
Markoff, L.S., and Cawley, P.A. Retaining your clients and your sanity: Using a relational model of multi-systems case management. Journal of Chemical Dependency Treatment 6(12): 45–65, 1996.
Martin, S.S.; Isenberg, H.; and Inciardi, J.A. Assertive community treatment: Integrating intensive drug treatment with aggressive case management for hard-to-reach populations. In: Inciardi, J.A.; Tims, F.M.; and Fletcher, B.W., eds. Innovative Approaches in the Treatment of Drug Abuse: Program Models and Strategies. Westport, CN: Greenwood Press, 1993. pp. 97–108.
Martin, S., and Scarpitti, F. An intensive case management approach for paroled IV drug users. Journal of Drug Issues 23(1):81–96, 1993.
McCarthy, E.P.; Feldman, Z.T.; and Lewis, B.F. Development and implementation of an interorganizational case management model for substance users. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 331–349.
McGrew, J.H., and Bond, G.R. Critical ingredients of assertive community treatment: Judgments of the experts. Journal of Mental Health Administration 22:113–125, 1995.10142125
McKirnan, D.J., and Peterson, P.L. Alcohol and drug use among homosexual men and women: Epidemiology and population characteristics. Addictive Behaviors 14(5):545–553, 1989.2589133
McLellan, A.T.; Arndt, I.; Metzger, D.S.; Woody, G.E.; and O'Brien, C.P. The effects of psychosocial services in substance abuse treatment. Journal of the American Medical Association 269:1953–1959; 1993.8385230
McLellan, A.T.; Luborsky, L.; O'Brien, C.P.; Woody, G.E.; and Druley, K.A. Is treatment for substance abuse effective? Journal of the American Medical Association 247:1423–1428, 1982.7057531
Mechanic, D.; Schlesinger, M.; and McAlpine, D.D. Management of mental health and substance abuse services: State of the art early results. Milbank Quarterly 73:19–55, 1995.
Mejta, C.L.; Bokos, P.J.; Mickenberg, J.H.; Maslar, E.M.; Hasson, A.L.; Gil, V.; O'Keefe, Z.; Martin, S.S.; Isenberg, H.; Inciardi, J.A.; Lockwood, D.; Rapp, R.C.; Siegal, H.A.; Fisher, J.H.; and Wagner, J.H. Approaches to case management with substance abusing populations. In Lewis, J., ed. Addictions: Concepts and Strategies for Treatment. Gaithersburg, MD: Aspen, 1994.
Miles, M., and Huberman, A. Qualitative Data Analysis. Newbury Park, CA: Sage, 1997.
Miller, W.R. and Rollnick, S. Motivational Interviewing: Preparing People to Change Addictive Behavior. New York: Guilford Press, 1991.
Mirin, S.M.; Weiss, R.D.; and Michael, J. Psychopathology in substance abusers: Diagnosis and treatment. American Journal of Drug and Alcohol Abuse 14(2):139–157, 1988.
Modrcin, M.; Rapp, C.; and Chamberlain, R. Case Management With Physically Disabled Individuals: Curriculum and Training Program. Lawrence, KS: University of Kansas School of Social Welfare, 1985.
Mondanaro, J.E.; Wedenoja, M.; Densen-Gerber, J.; Elahi, J.; Mason, M.; and Redmond, A.C. Sexuality and fear of intimacy as barriers to recovery for drug dependent women. In: Beschner, G.M.; Reed, B.D.; and Mondanaro, J., eds. Treatment Services for Drug Dependent Women, Vol. 2. NIDA Treatment Monograph Series. Washington, DC: National Institute on Drug Abuse, 1982.
Monti, P.M.; Abrams, D.B.; Kadden, R.M.; and Cooney, N.L. Treating Alcohol Dependence. New York: Guilford Press, 1989.
Moore, D., and Polsgrove, L. Disabilities, developmental handicaps, and substance misuse: A review. International Journal of the Addictions 26(1): 65–90, 1991.
Moore, S.T. A social work practice model of case management: The case management grid. Social Work 35(5):444–448, 1990.2237522
Moos, R.H.; Finney, J.W.; and Cronkite, R.C. Alcoholism Treatment: Context, Process, and Outcome. New York: Oxford University Press, 1990. pp. 220–248.
Morlock, L.; Taube, C.; and Ross, A. Alternatives for Case Management of the CMI in Baltimore City: Implications for Cost and Impact. Unpublished report. Baltimore, MD: The Johns Hopkins University, Center on Organization and Financing of Care for the Severely Mentally Ill, 1988.
Morrissey, J.P.; Ridgely, M.S.; Goldman, H.H.; and Bartko, W.T. Assessments of community mental health support systems: A key informant approach. Community Mental Health Journal 30(6): 565–579, 1994.7835042
Mumm, A.M.; Olsen, L.; and Allen, D. “Families Affected by Substance Abuse: Implications for Generalist Practice.” Submitted for publication, 1997.
National Association of Alcoholism and Drug Abuse Counselors. Certification Commission Oral Exam Guidelines. Arlington, VA: National Association of Alcoholism and Drug Abuse Counselors, 1986.
National Association of Social Workers. Case management's cost, benefits eyed. National Association of Social Workers News. Washington, DC: NASW Press, 1992. p. 12.
National Certification Reciprocity Consortium/Alcohol and Other Drug Abuse. Standards for Certification. Atkinson, NH: National Certification Reciprocity Consortium/Alcohol and Other Drug Abuse, 1993.
National Institute on Alcohol Abuse and Alcoholism. Homelessness, Alcohol and Other Drugs. HHS Pub. No. (ADM) 89-1614. Rockville, MD: National Institute on Alcohol Abuse and Alcoholism, 1989.
Ogborne, A.C., and Rush, B.R. The coordination of treatment services for problem drinkers: Problems and prospects. British Journal of Addiction 78:131–138, 1983.6575804
Ohio Credentialing Board for Chemical Dependency Professionals. Standards and Procedures of the Ohio Certification Program. Columbus, OH: Ohio Credentialing Board for Chemical Dependency Professionals, 1995.
Olfson, M. Assertive community treatment: An evaluation of experimental evidence. Hospital and Community Psychiatry 41:534–641, 1990.
Oppenheimer, E.; Sheehan, M.; and Taylor, C. Letting the client speak: Drug misusers and the process of help seeking. British Journal of Addiction 83:635–647, 1988.3401610
Orwin, R.G.; Sonnefeld, L.J.; Garrison-Mogren, R.; and Smith, N.G. Pitfalls in evaluating the effectiveness of case management programs for homeless persons. Evaluation Review 18(2):153–207, 1994.
Ouellet, L.; Kelly, M.; Coward, A.; and Wiebel, W.W. Developing community resources for a stigmatized population. In: Albrecht, G.L., ed. Advances in Medical Sociology. Vol. 6, Case and Care Management. Greenwich, CT: JAI Press, 1995. pp. 207–230.
Perl, H.I. and Jacobs, M.L. Case management models for homeless persons with alcohol and other drug problems: An overview of the NIAAA research demonstration program. In: Ashery, R.S., ed. Progress and Issues in Case Management, NIDA Research Monograph Series. Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 208–222.
Platt, J.J.; Buhringer, G.; Kaplan, C.D.; Brown, B.B.; and Taube, D.O. The prospects and limitations of compulsory treatment for drug addiction. Journal of Drug Issues 18: 505–525, 1988.11650856
Prochaska, J.O., and DiClemente, C.C. Self-change and therapy change of smoking behavior: A comparison of processes of change in cessation and maintenance. Addictive Behaviors 7(2):133–142, 1982.7102444
Raiff, N.R., and Shore, B.K. Advanced Case Management: New Strategies for the Nineties. Newbury Park, CA: Sage, 1993.
Rapp, C.A., and Chamberlain, R. Case management services for the chronically mentally ill. Social Work 30(5): 417–422, 1985.10273981
Rapp, R.C. The strengths perspective and persons with substance abuse problems. In: Saleebey, D., ed. The Strengths Perspective in Social Work Practice, 2^nd^ ed. New York: Longman Press, 1997.
Rapp, R.C.; Kelliher, C.W.; Fisher, J.H.; and Hall, F.J. Strengths-based case management: A role in addressing denial in substance abuse treatment. Journal of Case Management 3(4):139–144, 1994.7735084
Rapp, R.C.; Siegal, H.A.; and Fisher, J.H. A strengths-based model of case management/advocacy: Adapting a mental health model to practice work with persons who have substance abuse problems. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 79–91.
Rapp, R.C.; Siegal, H.A.; Li, L.; and Saha, P. Predicting post-primary treatment services and drug use outcome: A multivariate analysis. American Journal of Drug and Alcohol Abuse, in press.
Regier, D.A.; Farmer, M.E.; Rae, D.S.; Locke, B.Z.; Keith, S.J.; Judd, L.L.; and Goodwin, F.K. Comorbidity of mental disorders with alcohol and other drug abuse: Results from the epidemiologic catchment area (ECA) study. Journal of the American Medical Association 264(19):2511–2518, 1990.2232018
Rehabilitation Research and Training Center on Drugs and Disability. Substance Abuse, Disability and Vocational Rehabilitation. Dayton, OH: Rehabilitation Research and Training Center on Drugs and Disability, 1996.
Richmond, M. What Is Social Casework? New York: Russell Sage Foundation, 1922.
Ridgely, M.S., and Willenbring, M.L. Application of case management to drug abuse treatment: Overview of models and research issues. In: Ashery, R., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 12–33.
Rife, J.C.; First, R.J.; Greenlee, R.W.; Miller, L.D.; and Feichter, M.A. Case management with homeless mentally ill people. Health and Social Work 16(1):58–67, 1991.2001851
Roberts-DeGennaro, M. Generalist model of case management practice. Journal of Case Management 2(3):106–111, 1993.8130748
Robinson, R., and Bergman, G. Choices in Case Management: A Review of Current Knowledge and Practice for Mental Health Programs. Washington, DC: Policy Resources, Inc., 1989.
Rogers, G. Educating case managers for culturally competent practice. Journal of Case Management 4(2):60–65, 1995.7627100
Ross, H. Proceedings of the Conference on the Evaluation of Case Management Programs. Los Angeles: Volunteers for Services to Older Persons, 1980.
Ross, H.E.; Glasser, F.B.; Germanson, T. The prevalence of psychiatric disorders in patients with alcohol and other drug problems. Archives of General Psychiatry 45:1023–1031, 1988.3263100
Ross, M.W., and Darke, S. Mad, bad, and dangerous to know: Dimensions and measurements of attitudes toward injecting drug users. Drug and Alcohol Dependence 30(1):71–74, 1992.1317289
Rothman, J. Guidelines for Case Management. Itasca, IL: F.E. Peacock Publishers, 1992.
Rothman, J. Practice With Highly Vulnerable Clients. Englewood Cliffs, NJ: Prentice Hall, 1994.
Rubin, A. Is case management effective for people with serious mental illness? A research review. Health and Social Work 17:138–150, 1992.1618427
Rush, B., and Ekdahl, A. Recent trends in the development of alcohol and drug treatment services in Ontario. Journal of Studies on Alcohol 51(6): 514–522, 1990.2176704
Saleebey, D., ed. The Strengths Perspective in Social Work Practice, 2^nd^ ed. New York: Longman Press, 1997.
Schlenger, W.E.; Kroutil, L.A.; and Roland, E. J. Case management as a mechanism for linking drug abuse treatment and primary care: Preliminary evidence from the ADAMHA/HRSA linkage demonstration. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92-1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 316–330.
Schwartz, B.; Dilley, J.; and Sorensen, J.L. Case management of substance abusers with HIV disease. In: Siegal, H., and Rapp, R.C., eds. Case Management and Substance Abuse Treatment: Practice and Experience. New York: Springer, 1996. pp. 123–140.
Shernoff, M., and Springer, E. Substance abuse and AIDS: Report from the front lines (The impact on professionals). Journal of Chemical Dependency Treatment 5(1):35–48, 1992.
Shilony, E.; Lacey, D.; O'Hagan, P.; and Curto, M. All in one neighborhood: A community-based rehabilitation treatment program for homeless adults with mental illness and alcohol/substance abuse disorders. Psychosocial Rehabilitation Journal 16(4):103–116, April, 1993.
Shwartz, M.; Baker, G.; Mulvey, K.P. and Plough, A. Improving publicly funded substance abuse treatment: The value of case management. American Journal of Public Health 87(10):1659–1664, 1997.9357349
Siegal, H.A.; Fisher, J.A.; Rapp, R.C.; Kelliher, C.W.; Wagner, J.H.; O'Brien, W.F.; and Cole, P.A. Enhancing substance abuse treatment with case management: Its impact on employment. Journal of Substance Abuse Treatment 13(2):93–98, 1996.8880666
Siegal, H.A.; Rapp, R.C.; Kelliher, C.W.; Fisher, J.H.; Wagner, J.H.; and Cole, P.A. The strengths perspective of case management: A promising inpatient substance abuse treatment enhancement. Journal of Psychoactive Drugs 27(1):67–72, 1995.7602442
Siegal, H.A.; Rapp, R.C.; Li, L.; Saha, P.; and Kirk, K. The role of case management in retaining clients in substance abuse treatment: An exploratory analysis. Journal of Drug Issues 27(4):821–831, 1997.
Skinner, W.F. The prevalence and demographic predictors of illicit and licit drug use among lesbians and gay men. American Journal of Public Health 84(8):1307–1310, 1994.8059891
Soloman, P. The efficacy of case management services for severely mentally disabled clients. Community Mental Health Journal 28:163–180, 1992.1319304
Soloman, P., and Draine, J. Consumer case management and attitudes concerning family relations among persons with mental illness. Psychiatric Quarterly 66(3):249–261, 1995.
Sonsel, G.E.; Paradise, F.; and Stroup, S. Case management practice in an AIDS service organization. Social Casework: The Journal of Contemporary Social Work 69(6):388–392, 1988.
Sosin, M.R.; Bruni, M.; and Mairead, R. Paths and impacts in the progressive independence model: A homelessness and substance abuse intervention in Chicago. In: Stahler, G.J., and Stimmel, B., eds. The Effectiveness of Social Interventions for Homeless Substance Abusers. New York: Haworth Medical Press, 1995. pp. 1–20.
Sosin, M.R.; Yamaguchi, J.; Bruni, M.; Grossman, S.; Leonelli, B.; and Reidy, M. Treating Homelessness and Substance Abuse in Community Context: A Case Management and Supported Housing Demonstration. Chicago, IL: The University of Chicago, 1994.
Stahler, G.J.; Shipley, T.F.; Bartlet, D.; DuCette, J.P.; and Shandler, I.W. Evaluating alternative treatments for homeless substance abusing men: Outcomes and predictors of success. In: Stahler, G.J., and Stimmel, B., eds. The Effectiveness of Social Interventions for Homeless Substance Abusers. New York: Haworth Medical Press, 1995. pp. 151–167.
Stark, M.J., and Kane, B.J. General and specific psychotherapy role induction with substance abusing clients. International Journal of the Addictions 20(8):1135–1141, 1985.
Steadman, H.J. Boundary spanners: A key component for the effective interactions of the justice and mental health systems. Law and Human Behavior 16(1):75–87, 1992.
Stein, L., and Test, M. Alternatives to mental hospital treatment. I. Conceptual model, treatment program, and clinical evaluation. Archives of General Psychiatry 37:392–397, 1980.7362425
Sullivan, W. Technical assistance consultation: A new model for social work practice [Diss.] Dissertation Abstracts International 50:4106, 1990.
Sullivan, W.P. Case Management in Alcohol and Drug Treatment: Conceptual Issues and Practical Applications. Springfield, MO: Center for Social Research, Southwest Missouri State University, 1991.
Sullivan, W.P.; Wolk, J.L.; and Hartmann, D.J. Case management in alcohol and drug treatment: Improving client outcomes. Families in Society: The Journal of Contemporary Human Service 73:195–201, 1992.
Tausig, M. Detecting “cracks” in mental health service systems: Application of network analytic techniques. American Journal of Community Psychology 15:337–351, 1987.3605001
Teague, G.B.; Schwab, B.; and Drake, R.E. Evaluation of Services for Young Adults With Severe Mental Illness and Substance Use Disorders. Alexandria, VA: National Association of State Mental Health Program Directors, 1990.
Test, M.A. Effective community treatment of the chronically mentally ill: What is necessary? Journal of Social Issues 37(3):71–86, 1981.
Test, M.A. Training in community living. In: Libermann, R.P., ed. Handbook of Psychiatric Rehabilitation. New York: MacMillan, 1992. pp. 153–170.
Toborg, M.A.; Levin, D.R.; Milkman, R.H.; and Center, L.J. Treatment Alternatives to Street Crime: (TASC) Projects: National Evaluation Program, Phase I Summary Report. Washington, DC: National Institute of Law Enforcement and Criminal Justice, 1976.
Turner, J., and TenHoor, W. The NIMH community support program: Pilot approach to a needed social reform. Schizophrenia Bulletin 4(3):319–348, 1978.
U.S. General Accounting Office. Management Practices: U.S. Companies Improve Performance Through Quality Efforts. Pub. No. GAO/NSLAD-91-190. Washington, DC: U.S. Government Printing Office, 1991.
Van de Ven, A.H., and Ferry, D.L. Measuring and Assessing Organizations. New York: Wiley, 1980.
Wallace, J. The new disease model of alcoholism. Western Journal of Medicine 152:502–505, 1990.
Weil, M.; Karls, J.M.; and Associates. Case Management in Human Service Practice. A Systematic Approach to Mobilizing Resources for Clients. San Francisco: Jossey-Bass, 1989.
Westermeyer, J. Cross-cultural studies on alcoholism. In: Goedde, H.W., and Agarwal, D.P., eds. Alcoholism: Biomedical and Genetic Aspects. Elmsford, NY: Pergamon Press, 1989. pp. 305–311.
Wholey, J.; Hatry, H.; and Newcomer, K.M., eds. Handbook of Practical Program Evaluation. San Francisco: Jossey-Bass, 1994.
Wildwind, L. When women resist treatment: Approaches for counselors. Journal of Substance Abuse Treatment 1:47–54, 1984.6535840
Willenbring, M.; Ridgely, M.S.; Stinchfield, R.; and Rose, M. Application of Case Management in Alcohol and Drug Dependence: Matching Techniques and Populations. Rockville, MD: National Institute on Alcohol Abuse and Alcoholism, 1991.
Willenbring, M.L.; Whelan, J.A.; Dahlquist, J.S.; and O'Neal, M.E. Community treatment of the chronic public inebriate. I: Implementation. Alcoholism Treatment Quarterly 7(2):79–97, 1990.
Zweben, A. The efficacy of role induction in preventing early dropout from outpatient treatment of drug dependency. American Journal of Drug and Alcohol Abuse 8(2):171–183, 1981.