# TIP Development Participants

## Consensus Panel

Each Treatment Improvement Protocol (TIP) consensus panel is a group of primarily nonfederal addiction-focused clinical, research, administrative, and recovery support experts with deep knowledge of the TIP's topic. With the Substance Abuse and Mental Health Services Administration's (SAMHSA) Knowledge Application Program (KAP) team, they develop each TIP via a consensus-driven, collaborative process that blends evidence-based, best, and promising practices with the panel's expertise and combined wealth of experience.

Note: The information below indicates each participant's position and affiliation when the panel was convened and may not be current.

### Consensus Panel Chair

Frederic C. Blow, Ph.D.
Director, Addiction Center and Substance Abuse Section
Professor, Department of Psychiatry University of Michigan Ann Arbor, MI
Senior Research Investigator
Center for Clinical Management Research
Department of Veterans Affairs
Ann Arbor, MI

### Consensus Panelists

Kimberly Burton
Director, Older Adult Programs
Chair, Maryland Coalition on Mental Health and Aging
Mental Health Association of Maryland Lutherville, MD

Sarah L. Canham, Ph.D., M.A.
Aging, Alcohol, and Addictions Interest Group Convener
Gerontologists Giving Back Founder and Co-Coordinator
Gerontological Society of America Washington, DC
Senior Lecturer and University Research Associate Gerontology Research Centre
Simon Fraser University
Vancouver, BC, Canada

Alexis Kuerbis, Ph.D., LCSW
Assistant Professor, Silberman School of Social Work
Member, Advisory Committee on LGBT Social Science & Public Policy Center
Member, Health and Mental Health Field of Practice Committee
Member, Clinical Practice with Individuals, Families, and Groups Committee
Hunter College
City University of New York
New York, NY

Sharon A. Matthew, LPC, ACRPS, CCS, CSAT, CMAT
Clinical Director, Addiction Rehab for Older Adults Program
Caron Treatment Centers
Wernersville, PA

David W. Oslin, M.D.
Professor, Geriatric and Addiction Psychiatry
Treatment Research Center
Perelman School of Medicine
University of Pennsylvania
Philadelphia, PA
Chief of Behavioral Health
Philadelphia VA Medical Center
Philadelphia, PA

Derek D. Satre, Ph.D.
Associate Professor of Psychiatry, In Residence – Step 4
School of Medicine
Medical Staff Psychologist
Langley Porter Hospital and Clinics
University of California, San Francisco
San Francisco, CA

## Stakeholders Meeting Participants

Stakeholders represent a cross-section of key audiences with a deep interest in a TIP's subject matter. Stakeholders review and comment on the draft outline and supporting materials for the TIP to ensure that its focus is clear, its stated purpose meets an urgent need in the field, and it will not duplicate existing resources produced by the federal government or other entities.

Note: The information below indicates each participant's position and affiliation when the meeting was convened and may not be current.

### Chair

Frederic C. Blow, Ph.D.
Director, Addiction Center and Substance Abuse Section
Professor, Department of Psychiatry University of Michigan Ann Arbor, MI
Senior Research Investigator
Center for Clinical Management Research
Department of Veterans Affairs
Ann Arbor, MI

### Stakeholders Meeting

Candi Byrne
Alternate Contracting Officer's Representative Center for Substance Abuse Treatment (CSAT)
SAMHSA
Rockville, MD

Melinda Campopiano von Klimo, M.D.
Senior Medical Adviser
CSAT
SAMHSA
Rockville, MD

Anita Everett, M.D.
Chief Medical Officer
Office of Planning, Policy and Innovation (OPPI)
SAMHSA
Rockville, MD

Deborah Goodman
Publications Manager
Office of Communications
SAMHSA
Rockville, MD

Kimberly Johnson, Ph.D.
Director
CSAT
SAMHSA
Rockville, MD

Melinda Lantz, M.D.
Member, Board of Directors
American Association of Geriatric Psychiatry
McLean, VA

Eunice Park-Lee, Ph.D.
Survey Statistician
Center for Behavioral Health Statistics and Quality
SAMHSA
Rockville, MD

Ron Pritchard, B.S.
Veterans Affairs Subcommittee Chairperson
NAADAC, the Association for Addiction Professionals
Alexandria, VA

Patricia Santora, Ph.D.
Public Health Advisor
Division of Service Improvement
CSAT
SAMHSA
Rockville, MD

Jennie Simpson, Ph.D.
Special Assistant to the Administrator
OPPI
SAMHSA
Rockville, MD

Jennifer Solomon, M.A.
TIP Product Champion
Public Health Analyst
Center for Substance Abuse Prevention
SAMHSA
Rockville, MD

Ivette Torres, M.Ed., M.S.
Associate Director for Consumer Affairs
Office of the Director
CSAT
SAMHSA
Rockville, MD

Sherrill Wayland, M.S.W.
National Projects Manager
National Resource Center on LGBT Aging
Services & Advocacy for GLBT Elders (SAGE)
New York, NY

Eric Weakly
Chief, State Grants Western Branch
Division of State and Community Systems Development
Center for Mental Health Services
SAMHSA
Rockville, MD

Marissa Whitehouse, M.Ed.
Senior Program Specialist
Center for Healthy Aging
National Council on Aging
Arlington, VA

## Field Reviewers

Field reviewers represent each TIP's intended target audiences. They work in addiction, mental health, primary care, and adjacent fields. Their direct frontline experience related to the TIP's topic allows them to provide valuable input on a TIP's relevance, utility, accuracy, and accessibility.

Note: The information below indicates each participant's position and affiliation when the review was requested and may not be current.

Constance Coogle, Ph.D., M.S.
Associate Director for Research and Administrator for Alzheimer's and Related Diseases Research
Award Fund, Virginia Center on Aging
Director of Evaluation, Virginia Geriatric Education Center
Associate Professor, Department of Gerontology
Associate Research Professor, Department of Psychology
Virginia Commonwealth University
Richmond, VA

Brandi Cotton, Ph.D., M.S.N., APRN
Assistant Professor, College of Nursing
University of Rhode Island
Kingston, RI

Larry Dupree, Ph.D., M.S., M.A.
Chair Emeritus
Department of Aging and Mental Health, Louis de la Parte Florida Mental Health Institute
University of South Florida
Tampa, FL

John Dyben, D.H.S., M.S., M.A.
Chief Clinical Officer
Origins Behavioral Healthcare
West Palm Beach, FL

Stephen Ferrante, Ph.D., M.S.W.
Adjunct Professor
Barry University School of Social Work
Miami Shores, FL

Michael Fingerhood, M.D., FACP
Associate Professor, Department of Medicine
Johns Hopkins University School of Medicine
Associate Professor, Department of Mental Health
Johns Hopkins University Bloomberg School of Public Health
Attending Physician and Director, Division of Chemical Dependence
Johns Hopkins Bayview Medical Center
Baltimore, MD

Benjamin Han, M.D., M.P.H.
Assistant Professor, Department of Medicine, Division of Geriatric Medicine
Assistant Professor, Department of Population Health
New York University School of Medicine
Primary Care Physician, Geriatric Medicine
Bellevue Hospital Center
New York, NY

Robert Hazlett, Ph.D., M.S.
Consultant/Trainer
National Screening, Brief Intervention, and Referral to Treatment Addiction Technology Transfer Center
Pittsburgh, PA

Chris Herman, M.S.W., LICSW
Senior Practice Associate for Aging
National Association of Social Workers
Washington, DC

Brenda Iliff, M.A., LADC, CAC, CMAT
Executive Director
Hazelden Betty Ford Foundation
Naples, FL

Susan Lehmann, M.D.
Associate Professor, Department of Psychiatry and Behavioral Sciences
Director, Psychiatry Clerkship and Geriatric Psychiatry Outpatient Clinic
Clinical Director, Division of Geriatric Psychiatry and Neuropsychiatry
Johns Hopkins University School of Medicine
Director, Geriatric Psychiatry Day Hospital
Johns Hopkins Hospital
Baltimore, MD

Nicole MacFarland, Ph.D., M.S.W., LCSW-R, CASAC
Executive Director
Senior Hope Counseling, Inc.
Albany, NY

Alison Moore, M.D., M.P.H., FACP, AGSF
Chief of Geriatric Medicine and Gerontology, Professor of Medicine, and Adjunct Professor of Psychiatry, University of California-San Diego La Jolla, CA
Co-Director, Center for Health Improvement for Minority Elders Mentorship Core, Resource Centers for Minority Aging Research, University of California-Los Angeles/Charles R. Drew University of Medicine and Science
Los Angeles, CA

Cynthia Munshell, Ph.D., M.A.
Partner and Managing Member, Director of Psychotherapy Services
PsychoGeriatric Services
Silver Spring, MD
Collegiate Professor of Psychology
University of Maryland University College
Adelphi, MD

Joseph Pickard, Ph.D., LCSW
Associate Professor and Gerontology
Concentration Coordinator
University of Missouri-St. Louis School of Social Work
St. Louis, MO

Lawrence Schonfeld, Ph.D., M.A.
Professor Emeritus, Department of Mental Health Law and Policy, College of Behavioral and Community Sciences, Louis de la Parte Florida
Mental Health Institute
University of South Florida
Tampa, FL

Harvey Sterns, Ph.D., M.A.
Director, Institute for Life-Span Development and Gerontology
Professor of Psychology
University of Akron
Akron, OH
Research Professor of Gerontology, Family and Community Medicine
Northeast Ohio Medical University
Rootstown, OH

Ming Wang, M.D., FASAM
Addiction Medicine Specialist and Medical Director, Caron Older Adult Treatment Program
Caron Treatment Centers
Wernersville, PA
Clinical Assistant Professor of Psychiatry
Penn State College of Medicine
Hershey, PA

Kimberly Williams, M.S.W.
President and CEO
Vibrant Emotional Health
Executive Committee Chair
National Coalition on Mental Health and Aging
Adjunct Lecturer
Columbia University School of Social Work
New York, NY

Faika Zanjani, M.S.W., LICSW
Associate Professor, Department of Gerontology, College of Health Professionals
Associate Director of Academic Programs and Research Training, Institute for Inclusion, Inquiry, and Innovation
Virginia Commonwealth University
Richmond, VA