# Executive Summary

Treatment Improvement Protocol (TIP) 26 provides a wide range of guidance in the latest evidence-based screening and assessment approaches, interventions, and services for substance misuse, including substance use disorders (SUDs), in older adults. It is intended for behavioral health service providers, healthcare professionals, and older adults, as well as those people who are significant in their lives.

## Introduction

Older adults are a special group because they are particularly vulnerable to the negative effects of substances and therefore substance misuse. Further, providers, professionals, and family and caregivers tend to overlook substance misuse in older people, meaning they are less likely than younger adults to be correctly diagnosed and offered treatments, services, or referrals. This oversight makes SUDs particularly dangerous for this population in terms of possible effects on mortality and comorbid conditions (including physical, cognitive, and mental disorders). This TIP is designed to help providers and others better understand how to identify, manage, and prevent substance misuse in older adults. This publication describes the unique ways in which SUD signs and symptoms manifest in older adults; drug and alcohol use disorder (AUD) screening tools, assessments, and treatments specifically tailored for older clients' needs; the interaction between SUDs and dementia and other cognitive disorders; and strategies to help providers improve their older clients' social functioning and overall wellness—both of which are critical to successful recovery.

A consensus panel developed the TIP's content based on a review of the most up-to-date literature and on their extensive experience in the field of geriatric alcohol and drug addiction treatment. Other professionals also generously contributed their time and commitment to this publication.

This publication is an update of the original TIP. The content addresses many of the same key topics and messages, as well as new ones. Revisions reflect the most recent scientific knowledge, clinical advances, and guidance pertaining to preventing and treating substance misuse among older adults.

## Overall Key Messages

Substance misuse in older adults is often overlooked and undertreated. In part, this is because of false beliefs among providers, professionals, and the general public that older adults do not develop or need treatment for drug and alcohol use disorders. Providers and professionals can benefit from an improved awareness about substance misuse in older clients, including how to approach screening, assessment, and treatment. Similarly, family members/caregivers can benefit from information and resources to help them recognize, prevent, and respond to substance misuse in their older loved ones.

Empirical evidence supports the use of SUD treatment for older adults—especially when tailored to their age-related needs. The notion that older adults are not interested in or do not respond well to treatment for substance misuse is simply untrue. In fact, when interventions are adapted to the physical, cognitive, and psychosocial needs of older clients, they are likely to be effective. It is critical that providers and professionals learn about available interventions and local resources so they can treat, serve, or otherwise refer older clients appropriately.

Like treatments and services, screening and assessment techniques can and should be adapted to older adults. Many instruments have been developed specifically to detect possible SUDs and common comorbid mental and physical conditions (e.g., depression, anxiety, pain) in this population. Age-appropriate screening tools and interventions are available for older adults struggling with alcohol use, illicit drug use, or nonmedical prescription medication use. Comprehensive assessments should explore other areas relevant to older adults and substance misuse, such as their trauma history and risk of current elder abuse, fall risk, cognitive decline, and ability to perform activities of daily living and other functions.

Nearly all of us will experience changes in our thinking as we age, but substance misuse can potentially worsen normal age-related changes in cognition. Further, older people already experiencing cognitive conditions, including dementia or mild cognitive impairment (MCI), may have difficulty using substances like alcohol and prescription medications safely and according to recommended guidelines.

Alcohol is the most widely used substance among older adults with substance misuse. It is vital that older adults and their family and caregivers receive information about moderate versus high-risk drinking, harmful effects of alcohol misuse, and available treatments for AUD.

Providers, professionals, and family and caregivers should be especially watchful for signs and symptoms of nonmedical prescription drug use, including that of opioids and benzodiazepines. Most older adults take at least one prescription medication, and many take more than one. This increases their risk for potentially dangerous drug-drug interactions and drug-alcohol interactions.

Older adults often experience reductions in their social network and social functioning as a part of normal aging, but among older individuals with substance misuse, this can be especially problematic. Social support is a critical piece of achieving and sustaining long-term recovery from substance misuse for all people, including older adults. Providers and professionals should be mindful of this and work closely with older clients to help them enhance the size and diversity of their social network, increase their social functioning, and engage in meaningful, recovery-oriented social activities (e.g., mutual-aid support programs, peer recovery support).

Recovery is just one part of wellness. To help older clients achieve true health and well-being, be sure to help them address any areas in which functioning may be lacking. This includes their physical functioning, mental health, emotional well-being, intellectual activities, spirituality, work or volunteer activities, and social life. All of these aspects of wellness play a role in recovery and in overall health.

Many older adults consume alcohol, but how does one know whether an older adult's alcohol use is a problem? Part of your role is to provide a wide range of education and resources to help older adults and their family or caregivers better understand the risk factors for, signs and symptoms of, and treatments and services available for alcohol misuse.

This TIP is divided into nine chapters designed to thoroughly cover all relevant aspects of the ways in which SUDs affect older adults and how providers, professionals, and family members and caregivers can offer treatment, services, support, and resources to help older adults prevent or overcome substance misuse.

## Content Overview

The TIP is divided into chapters to make the material more accessible according to the reader's interests. Below is a summary of each TIP chapter's main messages and key content areas.

### Chapter 1: Older Adults and Substance Misuse: Understanding the Issue

This chapter lays the foundation for understanding the scope and importance of substance misuse as a problem among older aged populations. It is for a variety of audiences (e.g., providers, professionals, administrators, informal and formal caregivers, family).

This chapter emphasizes the fact that substance misuse is indeed a serious—and increasing— problem among older adults. SUDs tend to be underrecognized by providers, professionals, and family and caregivers in part because of false beliefs that drug and alcohol addiction is only a “young person's disease” and that older clients are not interested and willing to engage in treatment or services. These myths contribute to low rates of diagnosis, treatment, and service provision among older persons and interfere with their chances for recovery. Most providers and professionals do not have specialized training in geriatric substance misuse, and most family members and caregivers do not know how to recognize and respond to these problems in older adults. This chapter helps fill these knowledge gaps by laying out the facts and statistics, many from large-scale surveys and empirical research, that underscore how problematic drug and alcohol addiction truly is for older adults.

In Chapter 1, you will learn that:

• Even though rates of drug and alcohol addiction are higher among adolescents and younger adults, SUDs can and do occur in older persons. Substance misuse is not something that only occurs in younger people. These ageist beliefs are a large reason why we see low rates of diagnosis and treatment/services in the older adult population.
• Substance misuse among older individuals is very dangerous and can increase their risk of death and other physical harms. Older persons are vulnerable to negative drug and alcohol interactions with prescription medications, adverse reactions from illicit drugs and prescription medications, and the harmful effects of alcohol.
• Not only are rates of illicit drug use among older adults growing, rates of co-occurring mental disorders are also high. As the number of older individuals in the U.S. population increases, the need for treatment providers and programs that understand and can respond to the needs of older adults with SUDs also will likely rise over time.
• Older adults with SUDs are more likely to misuse alcohol than any other substance. This is concerning because older individuals' bodies do not metabolize alcohol as efficiently as those of younger people, increasing their risk of cognitive and physical problems, like confusion and falls.
• Most older adults take at least one medication, and many take more than one. This makes substance use and misuse even more dangerous because of potentially deadly or otherwise harmful interactions between prescription medications and drugs and alcohol. Like their younger counterparts, some older adults do engage in nonmedical prescription medication use, including nonmedical use of opioids and benzodiazepines.
• Providers and professionals may struggle to identify SUDs in older clients because symptoms can be hard to recognize and do not necessarily mirror diagnostic criteria. For example, changes in thinking attributable to alcohol misuse may appear similar to normal age-related changes in cognition.
• Although the idea that older adults are unwilling to seek treatment or services for substance misuse is false, certain barriers can make this population less likely to seek treatment. These barriers include negative attitudes among providers, professionals, or family/caregivers; denial on the part of the older adult; lack of knowledge about substance misuse among family and caregivers; and lack of provider awareness about available and effective treatment and services.
• Multiple treatment approaches for SUDs exist that are effective for older adults. These include screening, brief intervention, and referral to treatment; brief structured treatment; patient education; relapse prevention techniques; formal SUD treatment programs; and pharmacotherapy (e.g., methadone, buprenorphine, naloxone).

### Chapter 2: Principles of Care for Older Adults

This chapter describes guiding principles for evidence-based, effective, and safe treatments and services for older adults with substance misuse. This chapter will most benefit providers.

Older adults are a diverse and unique population, and their SUD treatment and service needs typically differ somewhat from those of younger adults. Providers should understand developmental differences but also generational differences (e.g., baby boomers versus earlier cohorts) among their older clients. Age-sensitive and age-specific interventions can help increase older adults' chances of achieving and sustaining long-term recovery. The treatment/service environment itself also should be adapted to this population, for example, through organization-wide training and encouragement of staff attitudes responsive to older clients' needs. Consider each older client's cultural background, gender, and age of onset of an SUD, all of which can influence treatment needs and recovery outcomes.

In Chapter 2, you will learn the following:

• To give older clients the best opportunities to access and benefit from substance use treatment and services, you must acknowledge, respect, and respond to differences among populations of older individuals. This includes differences in generation, age of and reason for substance misuse onset, gender, recovery needs and wishes, attitudes about substance use/misuse, available support network, and more. In short, providers must remember that no two older clients are alike.
• Organizations should create a treatment/service environment that gives older clients the best chances for successful recovery. This means considering how the physical environment, as well as staff skills, services, abilities, and policies, can be tailored to overcome any age-related barriers.
• Older adults are diverse in gender, race/ethnicity, and sexual orientation. Bias and discrimination can occur as easily as in any other age group. Take time to learn how such diversity may influence your clients' late-life substance misuse, health disparities, and access to care.
• Early identification, education, and intervention, even if brief and informal, are important because substance misuse in older adults is often unrecognized by older adults themselves, as well as by their family members, friends, and healthcare and social service providers. As a provider, you should learn the signs and symptoms of SUDs in older adults and be prepared to respond appropriately when they appear. This includes performing routine screening and assessment for substance misuse. For older adults uninterested in abstinence, provide health risk reduction services, such as education on the health benefits of reducing alcohol use.
• Person-centered care is the preferred approach for this population and emphasizes older clients' values, needs, and preferences from among a menu of care options.
• Age-sensitive approaches include those that are tailored to older clients' physical needs (e.g., difficulties with mobility, hearing, vision, or a combination of these), cognitive problems (e.g., memory and attention difficulties), learning needs (e.g., using a slower pace, repeating information), and age-related preferences (e.g., desiring age-specific rather than mixed-age group treatment).
• Investing time and money in developing an age-sensitive workforce throughout your organization is important. Staff recruitment, hiring, retention, supervision, and professional development strategies should include a focus on understanding evidence-based approaches that are effective and appropriate for older adults.
• Older adults with substance misuse can benefit greatly from social support and community resources. Keep on hand a listing of resources and referrals, and help older clients access and engage in these services.
• Including caregivers throughout treatment and services (as appropriate) and providing them with education and resources (including access to case managers) can improve older clients' recovery chances. Not only will this help them better understand the nature of SUDs and the recovery process, it can help reduce caregiver burden and stress, which, if unaddressed, can affect their own health as well as that of the older adult with the SUD.

### Chapter 3: Identifying, Screening for, and Assessing Substance Misuse in Older Adults

This chapter addresses how, when, and why to use screening and assessment for substance misuse in older clients. This chapter will most benefit behavioral health service providers, social service providers, and other healthcare professionals and paraprofessionals.

Identification, screening, and assessment are critical steps to linking older adults with substance misuse to needed treatment and services. Older adults' signs and symptoms of SUDs can be difficult to spot, however. By learning the steps to accurate and effective screening and assessment, you increase the chances of older adults receiving timely and appropriate care. This means taking a comprehensive approach that not only focuses on specific drug and alcohol use disorders but also on related conditions that influence (or are influenced by) substance misuse. These conditions include co-occurring mental disorders (e.g., depression, anxiety), certain physical problems (like chronic pain and sleep disorders), cognitive impairment, falls, trauma, and abuse (history and current experiences), and everyday functioning.

In Chapter 3, you will learn the following:

• Screening and assessment for SUDs in older persons can be challenging because the signs and symptoms are not necessarily the same as those in younger adults and do not always mirror diagnostic criteria. To ensure proper and timely identification of problems, you should learn how to recognize and overcome these challenges.
• As a provider, you should regularly screen your older clients for substance misuse, at least annually. Also consider screening if the client displays signs or symptoms that are concerning, if the client or family/caregiver reports substance-related difficulties, or if you otherwise suspect substance misuse may be present.
• Numerous screening instruments are available that have been developed for or tested and approved for use with older persons. These include instruments to help you screen for alcohol misuse, illicit drug use, and nonmedical prescription medication use. Older adult screeners are also available to help you explore related areas, such as depression, posttraumatic stress disorder (PTSD), anxiety, cognition, pain, and daily functioning.
• When communicating screening results, you should praise clients for findings that indicate abstinence, and follow up on findings that indicate substance-related problems. Be sure to also occasionally rescreen older clients even if their findings suggest no problems are present.
• You should follow up on screening that indicates a potential substance-related problem by conducting an assessment. Brief assessments can occur immediately after screening. More thorough, comprehensive assessments are lengthier and may require a separate appointment.
• Comprehensive assessment for SUDs is a multistep process that will help you determine whether substance misuse is truly present and differentiate SUDs from possible co-occurring disorders (CODs), physical conditions common in older populations, and signs of normal aging.
• You should fully explore older clients' psychological, medical, family, vocational or retirement-related, social, sexual, financial, legal, substance use, and substance-related treatment histories. Also ask about older clients' fall risk, abuse potential, skills and abilities, and functional status.
• Not all clients who screen positive will need formal substance use treatment. For older clients with or at risk for mild or moderate substance misuse, a brief intervention may be sufficient (e.g., education, motivational interviewing). For older adults with moderate-to-severe SUDs, formal treatment may be necessary.

### Chapter 4: Treating Alcohol Misuse in Older Adults

This chapter discusses key aspects of alcohol misuse and the screening, assessment, and treatment of/services for binge drinking and AUD. It will most benefit healthcare, behavioral health, and social service providers working with older adults (physicians, nurse practitioners, physician assistants, nurses, social workers, psychologists, psychiatrists, mental health counselors, alcohol and drug counselors, and peer providers).

Alcohol is the most commonly used substance among older individuals with an SUD or substance-related problems. Although widespread screening is an effective method of detecting alcohol-related problems in this population, many providers and professionals fail to screen because of false beliefs (e.g., that older people do not experience AUD or would not be interested in treatment) and lack of knowledge about the importance of widespread screening.

For older clients in need of treatment, services, referrals, or some combination thereof, you should use age-sensitive and age-specific approaches to care that respect and respond to the unique needs of older adults. A wide range of interventions are available to draw from, including pharmacologic and nonpharmacologic options.

In Chapter 4, you will learn about:

• The ways in which older adults are at risk for harm from alcohol misuse, including age-specific health effects as well as negative co-occurring mental and social conditions.
• The need to screen all older adults for alcohol misuse and alcohol-related problems. Screening is especially important in primary care and emergency department settings, where older adults are often seen for co-occurring conditions like chronic pain and falls. Screening is necessary in certain situations, like following major life changes (e.g., retirement [especially if forced or unwanted], loss of a significant other), when starting a new medication, and as part of an annual physical exam.
• Measures developed and approved for use with older populations, such as the Alcohol Use Disorders Identification Test and the Short Michigan Alcoholism Screening Test-Geriatric Version.
• The ways to respond appropriately to older clients who screen positively for alcohol misuse or alcohol-related problems. As a provider, remember that not all diagnostic criteria for AUD apply to older adults in the same way they apply to younger adults. For instance, older adults may report reduced socialization, but this is common with aging and not necessarily a sign that drinking is interfering with social abilities.
• The ways in which prescription medications can interact negatively with alcohol. This is critical information for providers and professionals because most of your older clients will be taking at least one prescription medication. Older adults taking numerous prescriptions or taking certain medications (e.g., benzodiazepines, antidepressants, blood thinners) are especially at risk for potentially harmful alcohol-drug interactions.
• The steps to guiding older clients through the continuum of care for substance misuse, including brief interventions, prevention strategies, outpatient care, inpatient rehabilitation, follow-up services, referrals, and recovery management.
• Adapting treatment and services for age-specific needs of older adults, including clinical approaches (e.g., nonconfrontational and supportive approaches), treatment and service structure (e.g., flexible scheduling, shorter sessions), and content needs (e.g., focus on increasing behavioral change, quality of life, and social connectedness). You also should be aware of pharmacologic and nonpharmacologic interventions and their effectiveness and safety for use with older adults.

### Chapter 5: Treating Drug Use and Prescription Medication Misuse in Older Adults

This chapter discusses age-appropriate interventions and services for older adults with substance misuse (non-alcohol-related), including illicit drug use and nonmedical prescription medication use. This chapter will most benefit healthcare, behavioral health, and social service providers who work with older adults (e.g., physicians, nurse practitioners, physician assistants, nurses, social workers, psychologists, psychiatrists, mental health counselors, alcohol and drug counselors, peer recovery support specialists).

Older adults can and do develop SUDs involving illicit drugs and nonmedical use of prescription medication. Many older adults take multiple medications and may be unaware of potential harms arising from substance misuse (e.g., overdose; dangerous interactions with alcohol and with other medications; increased risk of physical, mental, and cognitive problems). Age-specific, evidence-based treatments and services are available for older clients with these conditions, including SUDs involving opioids, cannabis, stimulants, and benzodiazepines and other sedative-hypnotics.

There is no “wrong door” by which older adults access care for drug addiction, and as a provider, you should ensure education, formal and informal treatment, services, and referrals are available throughout the entire course of care, from prevention through continuing care and recovery management.

In Chapter 5, you will learn that:

• Prescription medication misuse can be unintentional, underscoring the importance of educating your older clients about how to take medication correctly (including avoiding harmful interactions).
• Older adults are at risk for opioid addiction, given the high prevalence of chronic pain in this population. Opioid overdose prevention strategies, detoxification, and medication can be used safely and effectively with this population.
• Illicit substance use (e.g., opioids, cannabis, stimulants) does occur among older adults and can be treated using behavioral and pharmacological methods.
• Routine screening and assessment will help you detect substance misuse early and accurately. Thoroughly explore not just the client's substance misuse (current and past) but also other health behaviors (e.g., exercise, diet), changes in physical and mental functioning, and major life events that may put the person at risk for substance misuse (e.g., retirement, moving, loss of a loved one).
• A full assessment should cover topics like co-occurring medical and mental conditions, sleep problems, occurrence of pain, fall risk, and daily functioning.
• Diagnostic criteria for SUDs may not fully apply to older clients. Older clients' substance-related signs and symptoms may differ from those in the diagnostic criteria and in younger adults.
• Older adults with SUDs can benefit from a wide range of age-sensitive and age-specific treatment and services across the continuum of care, including prevention strategies, early and brief interventions, formal inpatient and outpatient treatment, and recovery management techniques.
• Mutual-aid support programs and family involvement are important components of the continuum of care for older adults with SUDs. Social support and connectedness are often lacking in older adults and can help those with substance misuse achieve and sustain recovery, optimal functioning, and good quality of life.

### Chapter 6: Substance Misuse and Cognitive Impairment

This chapter outlines the ways in which substance misuse can affect (and be affected by) declines in thinking, including the occurrence of dementia. This chapter will most benefit behavioral health, healthcare, and primary care service providers and prevention specialists who offer direct care to clients in behavioral health and healthcare settings and care for older adults who misuse substances.

Changes in thinking, like difficulties with memory, attention, and learning, are a normal part of aging for most of us. But for older adults with substance misuse, these changes in thinking can be more severe and may develop faster than in the absence of substance misuse. Substance misuse can increase the risk of certain cognitive problems and can make managing those cognitive problems more difficult. Furthermore, problems with thinking may make it harder for some older adults to remember how to take prescription medication appropriately or keep track of their alcohol consumption to ensure it does not exceed recommended guidelines. In other words, cognitive disorders can increase older adults' chances of experiencing substance-related problems. The key to offering timely and effective treatment is to engage in routine screening and assessment to detect potential cognitive impairment, like dementia and MCI, as soon as possible.

There are many age-appropriate interventions and services you can offer (or offer referrals for) to help maintain or improve older clients' mood, functioning, and quality of life. Involving caregivers is also important to make sure clients struggling with their thinking take prescription medication correctly, avoid or consume safe amounts of alcohol, avoid illicit drugs, and stay engaged in treatment and services.

In Chapter 6, you will learn about:

• Facts that show substance misuse can and does occur in older adults, particularly alcohol misuse.
• The latest research on the effects of substances and certain medications (e.g., benzodiazepines) on cognition and brain functioning in general.
• The link between substance misuse and the risk of developing cognitive disorders in the future, such as dementia and MCI.
• The many mental disorders/symptoms that co-occur with substance misuse and that negatively influence thinking, such as depression and depressive symptoms, anxiety, and PTSD and trauma. If offering treatment or services for older clients' substance misuse, it is critical to screen and assess for these mental disorders/symptoms because, if present and untreated, cognitive problems may persist.
• Screening instruments developed for and tested in populations of older individuals are available. These tools will help you detect possible co-occurring mental disorders as well as cognitive impairment.
• The numerous interventions for older clients with substance misuse and co-occurring behavioral health and cognitive disorders, including education, drug and alcohol counseling, brief counseling, referral to mutual-aid support programs and peer-recovery programs, and other interventions that do not involve pharmacotherapy.
• Why including caregivers is essential for successfully treating older adults with substance misuse and co-occurring dementia or MCI. Additionally, your role is to help ensure caregivers have the support and resources they need to maintain their own health and well-being (including avoiding substance misuse themselves).

### Chapter 7: Social Support and Other Wellness Strategies for Older Adults

This chapter outlines ways to help older clients with substance misuse leverage social supports and other wellness strategies to improve their chances of achieving and maintaining long-term recovery. This chapter will most benefit healthcare, behavioral health, and social service providers who work with older adults (physicians, nurse practitioners, physician assistants, nurses, social workers, psychologists, psychiatrists, mental health counselors, alcohol and drug counselors, and peer recovery support specialists).

Strong social networks are an essential part of older adults' health and well-being. You can help increase older adults' chances of recovery by offering interventions, services, and resources that target social supports and other aspects of wellness, like health literacy, illness management, and relapse prevention. Social isolation is unfortunately common among many older individuals and has been linked to risky behaviors, including substance misuse, as well as poor physical, cognitive, and mental health. But you can help older clients enhance their social functioning as a part of recovery treatment/services through interventions that expand your clients' social network, increase their feelings of connectedness, promote neighborhood/community supports, and engage their family members in recovery activities.

In addition to addressing socialization, do not overlook other areas of health and well-being that may help enhance recovery efforts and improve quality of life. This includes the older adult's physical health, emotional well-being, spirituality, vocational or volunteer work, and more.

In Chapter 7, you will learn that:

• Declines in social functioning are a normal part of aging for many individuals, but you can (and should) help older clients with substance misuse do something about this. By helping older adults increase and enhance their social network and feelings of connectedness, you are at the same time also helping them improve their chances of overcoming substance misuse.
• You should help older clients with substance misuse expand the size and diversity of their social network, engage neighborhood and community supports, and involve family members or caregivers in their recovery. Be sure to offer recovery-specific social supports, like mutual-aid support programs and peer support programs, among your services and referral options.
• Area Agencies on Aging are wonderful sources of information, support, and services to help your older clients engage in social support and other healthy activities. Online social networks, though often associated only with adolescents and young adults, also are a potential useful resource for older adults. Explore whether your older clients are interested in and need help accessing social media and related technologies; they can be an asset for older individuals who experience barriers to establishing or growing a social network of support.
• In addition to focusing on social functioning, help older clients with substance misuse establish all-around wellness by addressing multiple areas of functioning, like their physical health, spirituality, emotional health, finances, work, and cognition. All of these can play an important role in recovery.
• Wellness recovery activities keep your older clients engaged in all aspects of life, health, and well-being. Brainstorm ideas together and link your clients to a wide range of wellness activities, like exercising, joining a spiritual or religious fellowship, creating a safe and welcoming living environment, enrolling in adult education or senior college courses, and volunteering.
• Complementary therapies and activities, like animal-assisted therapy, may help your older clients improve certain aspects of their physical, social, and emotional health. But be sure to discuss with them both the benefits and potential limitations of these strategies.
• Older adults should learn self-management techniques to independently monitor and improve their health. This is important for addressing chronic illnesses, like heart disease and chronic pain, which often affect older individuals and, if unmanaged, can lead to significant impairments in functioning and quality of life. By learning to independently track and manage their symptoms, clients feel empowered and gain control of their health. This also applies to recovery; by continuing to engage in recovery activities, use relapse prevention techniques, and rely on social supports, older clients can strengthen their resilience and maintain a sense of control over their recovery.

### Chapter 8: Drinking as an Older Adult: What Do I Need To Know?

This chapter focuses on older adults' alcohol consumption and key facts and information they (and family members/caregivers) should know about alcohol use and misuse. This chapter is for older adults who drink (including those with questions about how much they should drink), their caregivers, and their families.

Many older adults drink alcohol but do not develop alcohol misuse or other alcohol-related problems. Understandably, they may have questions about what defines a “safe” level of consumption; the signs, symptoms, and effects of alcohol misuse; and how, why, and when to seek professional treatment or services. Family and caregivers should be similarly armed with this information so they can offer support to an older significant other in need of care for alcohol misuse.

In Chapter 8, you will learn about:

• Guidelines that define “moderate” and “at-risk/high-risk” amounts of alcohol for adults, including what counts as one drink. Keep in mind that what is high risk for older adults is often different than what is high risk for younger individuals, because older adults experience the negative effects of alcohol at lower amounts.
• The causes of older adults' alcohol misuse, such as certain stressful major life events (e.g., forced retirement, death of a significant other), increased isolation, physical disability, and boredom/lack of meaningful activities or hobbies.
• The signs and symptoms of alcohol misuse in older adults, including cognitive, physical, emotional, social, and behavioral conditions.
• Aspects of alcohol use that can lead to or worsen health conditions.
• How to make sense of media reports that suggest light or moderate drinking is healthy.
• Which medications can have harmful interactions with alcohol and what those interactions include.
• Tips and strategies for older adults who want to try to manage their alcohol misuse on their own and how to tell when it is time to seek help from a professional.
• The steps that occur when a person accesses professional treatment or services, such as screening, assessment, and follow-up visits. Also, you will learn about treatment options across the continuum of care, including formal and informal interventions, and how to select the best-fitting treatment.
• Ways to engage family and friends in support of recovery, as well as self-motivation strategies.
• Vital information for family and caregivers, like warning signs of alcohol misuse, helping an older adult access professional care, and the importance of self-care.

### Chapter 9: Resources for Treating Substance Use Disorder in Older Adults

Chapter 9 provides a compendium of resources described in all other portions of the TIP, plus additional resources.