# Chapter 8—Drinking as an Older Adult: What Do I Need To Know?

KEY MESSAGES

• As you age, alcohol can affect you more because:
  – Your body does not process alcohol as well as it used to.
  – You're more likely to be taking medications that interact negatively with alcohol.
  – You're more likely to have health conditions that will get worse if you drink alcohol.
• If you drink too much, reducing or cutting back on your alcohol consumption can improve your health and well-being.
• Family members, caregivers, friends, and other people in your life can help you quit or cut back on drinking.
• If you need treatment for a drinking problem, a range of effective options are available to you.
• Have hope! Many older adults are able to change their drinking habits to improve health and well-being.

Chapter 8 of this Treatment Improvement Protocol (TIP) benefits older adults, caregivers, and family members. It discusses the effects of alcohol and recommended guidelines for drinking in older adults. It will help older adults figure out whether they might have a drinking problem and how they can reduce or stop using alcohol. It will help families and friends recognize when an older adult in their lives is misusing alcohol and what they can do to support healthy changes in the older adult's drinking habits while also taking care of their own needs.

Older adults use alcohol more than any other substance.^1229^ Drinking carries more risks for older adults, and they are at risk even when they drink less than younger adults. Physical changes that come with age increase sensitivity to alcohol. Other common changes in later life—like the death of a spouse or close friend, retirement, or a move to a different neighborhood or living situation—can lead to unhealthy drinking. But don't be discouraged! Older adults in treatment can do as well as or even better than younger adults do.^1230,1231,1232^ That said, many older adults cut back on or quit drinking without specialized treatment.^1233,1234,1235^

## Organization of Chapter 8 of This TIP

Chapter 8 is for older adults who drink (including those who have questions about how much they should drink), their families, and their caregivers. It provides information about how alcohol can affect older adults' changing bodies, health, and life circumstances.

The first section of Chapter 8 discusses drinking guidelines specific to older adults. It also lists reasons why some older adults misuse alcohol and lists some effects and warning signs of misuse.

The second section describes alcohol's health effects and the ways alcohol and medication interact.

The third section gives tips and cautions for addressing your drinking on your own.

The fourth section describes treatment options.

The fifth section educates older adults' families and caregivers about alcohol misuse.

The final section lists some helpful resources. A more detailed resource guide is in Chapter 9 of this TIP. Exhibit 8.1 defines some key terms you'll see as you read further.

EXHIBIT 8.1 Key Terms

• Addiction^*^: The most severe form of substance use disorder (SUD), associated with compulsive or uncontrolled use of one or more substances. Addiction is a chronic brain disease that has the potential for both recurrence (relapse) and recovery.
• Alcohol misuse: The use of alcohol in any harmful way, including heavy drinking, binge drinking, and alcohol use disorder (AUD).
• At-risk/high-risk drinking: Drinking alcohol in excessive amounts. This definition encompasses both binge drinking and heavy drinking. Additionally, any alcohol consumption is considered risky when carried out by individuals with certain medical conditions that are worsened by alcohol, those taking medicine that can interact harmfully with alcohol, those driving a car or engaged in other activities that require alertness, or people recovering from AUD.^1236,1237^ Note that for purposes of this TIP, at-risk drinking and high-risk drinking are synonymous and either term is acceptable to describe an older adult's drinking patterns.
• AUD: A diagnosis that applies to people who have lost control of their drinking, continue to use alcohol despite negative consequences, and experience symptoms such as craving and withdrawal.
• Binge drinking: A drinking pattern that leads to blood alcohol concentration levels of 0.08 grams per deciliter or greater. This usually takes place after four or more drinks for women and five or more drinks for men.^1238,1239^ However, older adults are more sensitive to the effects of alcohol, and treatment providers may need to lower these numbers when screening for alcohol misuse.^1240^ Additionally, other factors such as weight, decrease in enzyme activity, and body composition (e.g., amount of muscle tissue present in the body) can also affect alcohol absorption rates.
• Caregivers: Informal caregivers provide unpaid care. They assist others with activities of daily living, including health and medical tasks. Informal caregivers may be spouses, partners, family members, friends, neighbors, or others who have a significant personal relationship with the person who needs care. Formal caregivers are paid providers who offer care in one's home or in a facility.^1241^ Most older adults do not need caregivers and are as able to address their own needs as younger adults, whether or not substance misuse is a factor in their lives.
• Heavy drinking: Consuming five or more drinks for men and four or more drinks for women in one period on each of 5 or more days in the past 30 days.^1242^
• Moderate drinking: According to the 2015–2020 Dietary Guidelines for Americans, moderate drinking is defined as up to two drinks per day for men and up to one drink per day for women.^1243,1244^ However, the Centers for Disease Control and Prevention (CDC) notes that these numbers apply to any given day and are not meant as an average over several days.^1245^ Additionally, individuals who don't metabolize alcohol well may need to consume even lower quantities. Some people, particularly those with certain alcohol-related illnesses or engaging in tasks requiring concentration, should not consume alcohol at all. The Dietary Guidelines stipulate that those who don't drink should not begin drinking for any reason.^1246^
• Peer support: The use of peer recovery support specialists (for example, someone in recovery who has lived experience in addiction plus skills learned in formal training) to provide nonclinical (in other words, not requiring training in diagnosis or treatment) recovery support services to individuals in recovery from addiction and to their families.
• Screening: A process for evaluating the possible presence of a specific problem. The outcome is normally a simple yes or no.
• Substance misuse^*^: The use of any substance in a manner, situation, amount, or frequency that can cause harm to users or to those around them. For some substances or individuals, any use would constitute misuse (for example, underage drinking, injection drug use).
• Substance use disorder^*^: A medical illness caused by repeated misuse of a substance or substances. According to the fifth edition of the Diagnostic and Statistical Manual of Mental Disorders,^1247^

SUDs are characterized by clinically significant impairments in health and social function and impaired control over substance use. They are diagnosed through assessing cognitive, behavioral, and psychological symptoms. SUDs range from mild to severe and from temporary to chronic. They typically develop gradually over time with repeated misuse, leading to changes in brain circuits governing incentive salience (the ability of substance-associated cues to trigger substance seeking), reward, stress, and executive functions like decision making and self-control. Multiple factors influence whether and how rapidly a person will develop an SUD. These factors include the substance itself; the genetic vulnerability of the user; and the amount, frequency, and duration of the misuse. Note: A severe SUD is commonly called an addiction.

* The defnitions of all terms marked with an asterisk correspond closely to those given in Facing Addiction in America: The Surgeon General's Report on Alcohol, Drugs, and Health. This resource provides a great deal of useful information about substance misuse and its impact on U.S. public health. The report is available online (https://addiction.surgeongeneral.gov/sites/default/fles/surgeon-generals-report.pdf).

## Drinking Guidelines and Alcohol Misuse in Older Adults

### What Is Moderate Drinking?

The Dietary Guidelines define moderate drinking as up to one drink a day for women and up to two drinks a day for men. Importantly, these numbers apply to any given day and are not meant to be interpreted as averages over numerous days.^1248,1249,1250^

To make sure that your drinking is not high risk, avoid binge drinking. Binge drinking means drinking more than three drinks (if you're a woman) or four drinks (if you're a man) per day. However, given the body's decreased ability to absorb alcohol with age, you may need to limit yourself to fewer drinks to avoid binge drinking.^1251^

Don't drink when you will be driving a car or boat or doing other activities that require you to be coordinated and alert.

Heavy or binge drinking at any age harms the brain.^1252^ These patterns of drinking slow down communication among brain cells. Over time, heavy or binge drinking also shrinks the brain and changes it in other ways that negatively affect how it works. These changes can affect behavior; cause dementia; and worsen memory, coordination, and the ability to plan and learn.^1253,1254^

For some older adults, any amount of alcohol is risky.^1255^ Don't drink if you:^1256,1257^

• Have a chronic medical condition that alcohol can worsen, like diabetes or heart disease.^1258,1259^
• Are recovering from AUD.^1260^
• Take medications to help you worry less or sleep. People often take a type of prescription medication called benzodiazepines to treat anxiety or sleeplessness.^1261^
• Take opioid pain relievers, which healthcare providers may prescribe for severe or chronic pain.^1262^
• Take other prescription or over-the-counter (OTC) medications that interact negatively with alcohol—that is, they may cause serious harmful effects if you take them and also drink alcohol.

For more information about how various medications interact with alcohol, see the “What Medications Interact With Alcohol?” section.

### Why Do Experts Suggest Lower Limits for Older Adults?

The two main reasons for lower drinking limits are:

• You're more likely than younger adults to experience harmful alcohol-medication interactions.
• As you age, your body responds differently to alcohol.

You may have already noticed that you feel the effects of alcohol sooner than you used to, even if you don't take any medications. That's because age-related changes affect how your body handles alcohol.^1263,1264,1265^ Exhibit 8.2 shows some of these age-related changes.

EXHIBIT 8.2 How Aging Affects the Body's Response to Alcohol^1266,1267,1268,1269,1270,1271^

DOES ALCOHOL USE OR MISUSE AFFECT OLDER WOMEN DIFFERENTLY THAN IT AFFECTS OLDER MEN?

If an older man and woman of about the same size and age drink the same amount of alcohol in the same amount of time, the woman will get drunk sooner. That's because the woman probably:^1272,1273,1274^

• Has less body water to dilute the alcohol.
• Has less lean muscle mass to absorb the alcohol.
• Has less of the enzyme that breaks down alcohol.

This means that older women who misuse alcohol over time are likely to have more alcohol-related health problems than older men who do so. These problems will likely appear sooner and be more severe.^1275^

Compared with older men, older women are also more likely to:^1276,1277,1278^

• Live alone longer, increasing their risk of drinking to cope with loneliness.
• Be less financially secure, increasing their risk of drinking to cope with financial worries.
• Take benzodiazepines, which have particularly harmful interactions with alcohol. (See the text box “Benzodiazepine Alert: Cautions for Older Adults Who Drink.”)

Nevertheless, research suggests that older women respond to alcohol treatment better than older men do.^1279^

### What Counts as One Drink?

To help you stay within the recommended limits, you need to know what counts as one drink.^1280^ It may be less than you think. In the United States, a standard drink contains 14 grams of pure alcohol, or about 0.6 fluid ounces. Exhibit 8.3 shows standard drink amounts by beverage type.

EXHIBIT 8.3 What Is a Standard Drink?

Image adapted from material in the public domain.^1281^

Alcohol content can vary by type of drink. Read container labels to see how much alcohol is in a serving.

What if you have a cocktail or mixed drink that combines a few different kinds of alcohol? You can figure out about how many standard drinks you're really consuming by using the Cocktail Content Calculator (www.rethinkingdrinking.niaaa_nih.gov/Tools/Calculators/Cocktail-Calculator.aspx) on the National Institute on Alcohol Abuse and Alcoholism's (NIAAA) Rethinking Drinking website. The calculator gives the alcohol content and standard drink equivalent for several common mixed drinks.

To keep track of your drinking, it helps to know the number of standard drinks in a bottle of wine or other type of alcohol container. NIAAA's Drink Size Calculator tells you how many standard servings are in many common kinds of beverage containers. It shows this information by type and strength of beverage (www.rethinkingdrinking.niaaa.nih.gov/Tools/Calculators/Drink-Size-Calculator.aspx).

ACTIVITY: HOW MUCH ARE YOU REALLY DRINKING?

For this activity, you'll need:

• Two glasses you typically use for drinking alcohol (the glasses must be identical).
• A measuring cup (make sure it's for liquids, not dry ingredients).
• The “What Is a Standard Drink?” diagram.

Using water instead of alcohol, ill one glass with what you think of as a single serving. Find in Exhibit 8.3 the standard drink amount for your type of drink. Fill the measuring cup with that amount of water, then pour it into the second glass. Compare the amounts in the two glasses.

### What Can Cause Older Adults To Misuse Alcohol?

Alcohol misuse can begin or resume at any age. People who misuse alcohol may not always realize they are doing so. Stressful life changes that may lead to alcohol misuse in older adults include:^1282,1283,1284,1285,1286,1287^

• The death of a spouse, partner, child, or close friend.
• Increasing isolation.
• Increasing disability or a chronic illness.
• Forced or unplanned retirement.^1288^
• A change of residence.
• Increased financial strain.^1289^
• Boredom; lack of meaningful activity.
• Physical separation from adult children.

Spending time with people who drink is linked with alcohol misuse. For example, older adults may begin drinking too much after moving to a retirement community where drinking is a big part of socializing.^1290^

If your drinking patterns worsen in response to a change in your life, take action. The sections “How Can I Quit or Cut Back on My Own?” and “How Do I Talk to My Healthcare Provider About Alcohol Use?” can help you.

Some older adults use alcohol to cope with physical or emotional problems.^1291^ This is called self-medicating. Drinking to self-medicate can lead to alcohol misuse^1292^ and can actually worsen the problem instead of helping. For example, drinking to cope with depression can make symptoms of depression worse.^1293^ Similarly, drinking to cope with sleep problems can worsen sleep by reducing time spent in deep sleep and by causing snoring and other problems that interfere with sleep.^1294,1295^

Also, what was low-risk drinking when you were a younger adult can become alcohol misuse as you age, simply because your body does not handle alcohol as well as it used to. Refer back to Exhibit 8.2.

Healthcare providers sometimes mistake AUD for other conditions that are common in older adults. Some providers wrongly believe that older adults are not likely to develop AUD. These are good reasons for you to educate yourself about alcohol misuse in older adults.

### How Can I Tell Whether I'm Misusing Alcohol?

Ask yourself whether any of these possible signs and symptoms of alcohol misuse apply to you:

• Cognitive symptoms:
  – Feeling confused after drinking^1296^
  – Having memory problems^1297^
• Physical and mental symptoms:
  – Having problems with balance^1298^
  – Falling after drinking^1299^
  – Feeling clumsy^1300^
  – Experiencing incontinence^1301^
  – Slurring words^1302^
  – Continuing to drink even if you take medication that interacts negatively with alcohol
  – Continuing to drink even if you have a medical condition made worse by alcohol
• Social symptoms:
  – Having relatives or friends who are concerned about your drinking^1303^
  – Losing friends because of your drinking^1304^
• Behavioral symptoms:
  – Bathing or showering infrequently^1305^
  – Taking less care of your appearance^1306^
  – Taking less care of your living space^1307^
  – Spending too much money on alcohol^1308^
  – Skipping meals because of drinking^1309^
  – Putting oneself in risky situations (like driving, having unsafe sex) while drinking^1310^

If you have experienced or are experiencing any of these warning signs, consider speaking with your healthcare provider or an addiction specialist about your drinking. Also see “What Should I Expect During My Medical Appointment?” and “What Are My Options for Specialized AUD Treatment?”

Contact your healthcare provider if you:

• Drink despite taking one or more medications that have severe interactions with alcohol.
• Have had symptoms of alcohol withdrawal. See the text box titled “Warning Signs of Alcohol Withdrawal” for more information.

## Alcohol's Effects on Older Adult Health

### Can Drinking Cause or Worsen Health Conditions?

Alcohol misuse causes or increases your risk of developing more than 200 health conditions.^1311^ Drinking also worsens many health conditions common among older adults, including diabetes, high blood pressure, osteoporosis, pain, sleep problems, stroke, and urinary incontinence.^1312,1313,1314,1315,1316^

Alcohol misuse can also make it harder for you to manage any chronic medical conditions you already have. For example, you may skip meals, forget to exercise, or mix up medications.

Alcohol misuse may put you and others at risk of injuries and other harms, like HIV. Harms linked with alcohol misuse by older adults commonly result from falls, motor vehicle crashes, and suicide attempts.^1317,1318,1319^ Alcohol misuse can also lead to risky sexual behavior (such as having unprotected sex with a new partner), which can spread HIV or other sexually transmitted diseases.^1320,1321,1322,1323^

### What About News Reports That Say Light or Moderate Drinking Is Healthy?

Don't base decisions about drinking on news reports of alcohol's benefits. News stories don't always clarify whether a study found that alcohol causes or is simply associated with a health benefit. If a study shows that alcohol is only associated with a health benefit, other factors like genetics or income level may have also played a role.^1324^ The report may ignore a study's limitations.^1325^ For example, the results of a study with only younger participants may not apply to older adults.

You and your healthcare provider should weigh the possible benefits of light or moderate drinking with the known negative effects of alcohol use, especially if you:

• Take medication that interacts badly with alcohol.
• Have a history of alcohol misuse.
• Have, or are at risk for, a medical condition worsened by alcohol.

Exhibit 8.4 presents just some of the health conditions linked to alcohol misuse.

EXHIBIT 8.4 Some Health Risks of Alcohol Misuse^1326,1327,1328,1329,1330,1331,1332,1333,1334,1335^

### What Medications Interact With Alcohol?

Many older adults who drink regularly take prescription medications that interact harmfully with alcohol.^1336,1337^ Drinking makes some medications less effective and can make others more potent. The results can be unpleasant, dangerous, and even deadly.^1338^

Alcohol and medication can make a dangerous mix, even if you do not consume them at the same time.^1339^

If you drink, ask your healthcare provider whether alcohol can interact harmfully with any of your medications. Negative interactions may occur even if you don't see signs or symptoms like vomiting or dizziness right away. Serious effects of alcohol-medication interactions, like liver damage, can develop “silently” over time.^1340^

Dietary supplements (e.g., vitamins, herbal products) and OTC medications (like aspirin) can interact harmfully with alcohol. Talk to your healthcare provider if you take any of these products and drink.^1341^

ACTIVITY: CHECK YOUR MEDICATIONS FOR ALCOHOL INTERACTIONS

Check labels on prescription bottles for warnings about drinking while taking the medication. If the medication came with a printed “Patient Package Insert” or “Medication Guide,” check for additional warnings on alcohol use. If you have questions about your medication and alcohol use, talk to your pharmacist or healthcare provider.

Check the “Drug Facts” labeling for your OTC medications: Look under “Warnings” for any mentions of alcohol.

Information that comes with prescription and OTC medications usually does not include warnings specifically for older adults. If you're unsure whether you can drink while taking a medication, be safe and don't drink.^1342^

Exhibit 8.5 lists 12 medications that interact badly with alcohol. Many older adults take these and similar medications. This list is provided for illustration only. Other medications for the same condition may have different interactions, and many conditions are not included. For more comprehensive lists, see the entries under “Alcohol and Medication Interactions” in the “Resources” section at the end of this Chapter.

EXHIBIT 8.5. Common Prescription Medication-Alcohol Interactions^1343,1344^

CONDITION | MEDICATION EXAMPLE | POSSIBLE INTERACTIONS WITH ALCOHOL
Anxiety | Clonazepam | Increased dizziness, drowsiness, and memory problems; decreased coordination; increased risk of fatal overdose^1345^
Arthritis | Naproxen | Ulcers, stomach bleeding, liver damage
Blood clots | Warfarin | Internal bleeding with occasional or heavy drinking; increased risk of blood clots, strokes, or heart attacks with heavy drinking
Cough | Dextromethorphan | Drowsiness, dizziness, difficulty concentrating,^1346^ higher overdose risk
Depression | Sertraline | Increased depression, drowsiness, dizziness
Diabetes | Metformin | Very low blood sugar (symptoms: dizziness, drowsiness, confusion), lactic acidosis (symptoms: muscle pain, slow heartrate, dizziness)
Heartburn | Ranitidine | Rapid heartbeat; increased alcohol levels^1347^
High blood pressure | Lisinopril | Dizziness, drowsiness, fainting, weakness from low blood pressure,^1348^ heart problems such as changes in the heart's normal rhythm
High cholesterol | Simvastatin | Liver damage
Insomnia | Zolpidem | Drowsiness, dizziness, sleepiness, slowed or difficult breathing, loss of coordination, unusual behavior, memory problems
Pain | Ibuprofen | Stomach bleeding and ulcers
Pain (severe) | Oxycodone | Drowsiness, dizziness, slowed or difficult breathing, loss of coordination, unusual behavior, memory problems, increased risk for fatal overdose

BENZODIAZEPINE ALERT: CAUTIONS FOR OLDER ADULTS WHO DRINK

Prescription benzodiazepines mainly treat anxiety or insomnia.^1349^ Common benzodiazepines include:

• Alprazolam (Xanax, Xanax XR).
• Diazepam (e.g., Valium, Diastat).
• Clonazepam (Klonopin).
• Lorazepam (Ativan).

Drinking while taking benzodiazepines puts you at great risk. Alcohol and benzodiazepines slow down critical bodily functions like breathing and heartbeat. Combining them can cause blackouts and even death.^1350,1351^

If you drink alcohol at all and take benzodiazepines, tell your healthcare provider.

Also ask whether you should try a different approach to treating the condition for which you take the benzodiazepines. If you and your healthcare provider decide you should keep taking the medication, even at a reduced dosage, that's a good reason for you to quit drinking.

Don't change benzodiazepine use on your own. You need medical advice when stopping or reducing benzodiazepine use. Your healthcare provider should give you a schedule to slowly reduce (taper) your dosage. Tapering helps avoid benzodiazepine withdrawal. Tapering also makes it less likely that the symptoms the medication treated will return.^1352^ Many older adults end or reduce benzodiazepine use through tapering alone, but you may also need counseling, such as cognitive-behavioral therapy (CBT), to achieve this goal.^1353^

Here are some more tips on avoiding negative interactions between alcohol and your medications:

• Ask your healthcare provider or pharmacist whether a newly prescribed medication interacts harmfully with alcohol, even if you don't drink often.
• Never take prescription medication offered to you by a family member or a friend, especially if you drink. The medication was prescribed with someone else's medical situation in mind, not yours. Taking it could harm you. In some cases, sharing prescription medications is illegal.
• Check the ingredients of cough and cold medications and laxatives, which may contain alcohol.

OPIOID ALERT: CAUTIONS FOR OLDER ADULTS WHO DRINK

Prescription opioid medications mainly treat severe or ongoing pain. Common opioid medications include:

• Codeine.
• Meperidine (Demerol).
• Hydrocodone combined with acetaminophen (e.g., Vicodin, Lorcet).
• Oxycodone (e.g., OxyContin).
• Oxycodone combined with acetaminophen (e.g., Percocet).

If you take opioid pain relievers and also drink alcohol, you put yourself at especially high risk for overdose, confusion, unusual behavior, and serious injury.^1354,1355^ Let your healthcare provider know immediately if you take opioid pain relievers and you drink, even just occasionally.

You and the healthcare provider who prescribed the opioids should discuss whether to treat your pain in a different way. Keep in mind that many alternative pain medications also interact harmfully with alcohol.^1356^

If only prescription opioids control your pain, you need to quit drinking while taking them. Talk with your provider about how to stop drinking safely.

## Tips and Cautions for Addressing Drinking on Your Own

### Is Alcohol Withdrawal a Concern?

If you drink more than is recommended for older adults—especially if you drink heavily or have been drinking regularly for a long time—don't sharply cut back on your drinking or suddenly quit on your own. Get medical advice first. Your body may be dependent on alcohol, so you could experience withdrawal if you go without drinking for longer than usual.^1357^ Severe alcohol withdrawal can be deadly if not treated right away in a hospital.^1358,1359^

WARNING SIGNS OF ALCOHOL WITHDRAWAL

Symptoms may occur up to 7 days after your last drink. They may vary in severity^1360^ and include:^1361,1362,1363,1364^

• Agitation.
• Anxiety.
• Diarrhea.
• Headache.
• Raised blood pressure.
• Increased pulse rate.
• Insomnia.
• Nausea.
• Sweating.
• Tremor.

Delirium tremens (also known as DTs) is the most severe form of alcohol withdrawal.^1365^ It can be fatal and must be treated in a hospital. It can develop 2 to 10 days after the last drink.^1366^ Possible symptoms include rapid heart rate, intense tremor, extreme agitation, confusion, fever, drenching sweats, and coma.^1367^

### How Can I Quit or Cut Back on My Own?

#### Consider Why You Want To Change Your Drinking Habits

Think about how drinking conflicts with your top values—values you want your life to reflect, like independence, generosity, health, and honesty. Try these value-identifying exercises available online:

• www.smartrecovery.org/smart-recovery-toolbox/values-and-goals-clarification
• https://harvard.az1.qualtrics.com/jfe/form/SVe35whN7tkXtvlHv (interactive)
• www.therapistaid.com/worksheets/values-clarification.pdf

Feel free to add any of your own top values that you don't see listed in these exercises. Here are just a few possibilities: alertness, dependability, and empathy. The activity below will help you understand the relationship between drinking and your top values.

ACTIVITY: DOES YOUR DRINKING CONFLICT WITH YOUR TOP VALUES?

Think about your top values in life—the principles, qualities, and beliefs most important to you that you want your life to reflect. Does drinking conflict with any of your top values? If so:

#### Make a Plan for Change

Writing a plan for change (Exhibit 8.6) will help you set and keep goals for cutting back or quitting drinking. Before making a plan, look at your answers to the “Does Your Drinking Conflict With Your Top Values?” activity. Consider first reading the “How Can I Get Support From Family and Friends?” section.

EXHIBIT 8.6 Writing a Change Plan

#### Pace Yourself When You Drink

Your main goal is to cut back and slow down your alcohol consumption when you drink.

Try:^1369,1370,1371^

• Putting your drink down between sips.
• Holding something in your hand besides your drink between sips.
• Following an alcoholic drink with a nonalcoholic one.
• Eating something while you drink—but avoid foods that make you thirsty.

#### Track Your Drinking

Using a drinking tracker card (Exhibit 8.7), write down how many drinks you have each day. This will help you keep better track of your drinking as you work to cut back or quit.^1372^

EXHIBIT 8.7 Four-Week Drinking Tracker Card

Reprinted from material in the public domain.^1373^

#### Find Alternatives to Drinking

You may drink out of habit, boredom, or loneliness, or when you're with friends who drink. Try to find other activities that appeal to you and fit your abilities and budget. Here are some ideas:

• Participate in recreation programs at your local community recreation center or senior center. (Be sure to consult with your healthcare provider before increasing your physical activity.)
• Put your experience and gifts to use by volunteering at a nonprofit organization or a school.
• Join a book discussion group hosted by a local library or bookstore.

Think about what your interests are and how you can make them a bigger part of your life.

#### Have a Plan for Dealing With Challenging Situations

Some occasions, like holiday parties or anniversaries of losses, may tempt you to drink or to drink too much. So may being around people or places that remind you of drinking. You can fight temptation better if you have a plan for handling such situations.^1374^ For example, you could plan to spend the evening of a difficult anniversary with an understanding friend. A written plan (Exhibit 8.6) can help you remember what steps to take to avoid temptation.

#### Join a Mutual-Help Group

Another action you can take is to join a mutual-help group. Members of these groups support each other in their recovery from the misuse of alcohol and other substances. Mutual-help groups meet regularly, are free, and usually take place in community spaces, such as houses of worship and schools.

Some groups follow the 12-Step approach, which has abstinence as its goal.^1375^ Alcoholics Anonymous (AA) was the first 12-Step group. To find a meeting, go to www.aa.org/pages/enUS/find-aa-resources or look in your local newspaper or community newsletter. Some communities have meetings designated as senior friendly.^1376^ If you have difficulty getting around, you can check out AA's online and telephone meetings (https://aa-intergroup.org/directory.php).

For older adults-only meetings, look into Seniors In Sobriety (SIS), which is part of AA. The SIS website (www.seniorsinsobriety.com) provides a list of meetings.

Alternatives to traditional 12-Step organizations include:

• SMART (Self-Management and Recovery Training) Recovery (www.smartrecovery.org).
• Women for Sobriety (https://womenforsobriety.org).
• Secular Organizations for Sobriety (www.sossobriety.org).
• Moderation Management (www.moderation.org).

You can find faith-based mutual-help organizations at www.recoverymonth.gov/resource-category/faith-based.

Consider dropping by a mutual-help group meeting to see whether it's a good fit for you. Call the local office or contact person first to make sure that the meeting is open to the public. If you want to attend a meeting but feel a little uncomfortable with the idea, think about going with a friend.

MOBILE APPS

If you have a smartphone or tablet, you have access to many free mobile apps that can help you overcome alcohol misuse, including addiction. Common features of these apps include:^1377,1378^

• Counters showing how long you've been alcohol free (some go down to the minute or second).
• Calculators showing how much money and time you've saved by not drinking.
• Support-meeting locators.
• Community forums for sharing information and support anonymously.
• Daily inspirational messages.
• Progress notifications.
• Virtual rewards, like “coins” or “trophies,” for milestones achieved.

Examples of such apps are I Am Sober (https://iamsoberapp.com) and Nomo – Sobriety Clocks (https://saynomo.com).^1379^

## When It's Time To Get Help

### How Do I Talk to My Healthcare Provider About Alcohol Use?

• If you have questions about your alcohol use or think you need help addressing it, you may need to raise the subject with your healthcare provider yourself. That's because some healthcare providers:
  – Feel uncomfortable asking an older adult about his or her alcohol use.^1380^
  – May mistake an older adult's alcohol misuse for another health condition.^1381^
  – Believe there's no point in encouraging an older adult to stop or reduce drinking.^1382^

Here are some ideas for starting the conversation:

• “I'm on several medications, so is it a problem that I have a couple of drinks in the evening?”
• “It takes me awhile to fall asleep, so I have a nightcap. Is that okay, given my medical conditions?”
• “My wife says I drink too much at parties. I'd like to know what you think.”

Whether you raise the subject of alcohol use or your healthcare provider does, be honest about how much and how often you drink. Your health and even your life may depend on it.

### What Should I Expect During My Medical Appointment?

#### Screening

If you bring up alcohol concerns with your healthcare provider, he or she will likely ask you to answer a screening instrument or questionnaire. The most common alcohol screening instruments have just 1 to 10 questions. Your healthcare provider may ask you the questions directly, or you may answer them on paper or on a computer or tablet. Examples of alcohol screening questions are “Have you ever felt you should cut down on your drinking?” and “Do you usually take a drink to calm your nerves?”^1383,1384^

Screening helps your healthcare provider decide whether to look further into your alcohol use. It will also help you and your healthcare provider decide whether you may need specialized treatment to address alcohol misuse.

#### Assessment

If screening suggests that you misuse alcohol, your healthcare provider will probably do an “assessment” or refer you to a specialist who can do it. Whoever does the assessment will ask you more questions about how much and how often you drink. The assessment will help your healthcare provider understand any negative effects of your drinking, your drinking history, and any previous treatment you may have had for misuse of alcohol or other substances. Other assessment questions may focus on your living situation and degree of support from family and friends.^1385^ You will likely have a physical exam, and you may also have lab tests to check for alcohol use and any resulting damage to your liver or other organs.

#### What Typically Happens Next?

During this or a follow-up visit, your healthcare provider should give you more information and feedback about your drinking. The feedback will help you understand the results of the assessment and lab tests. Any other information you receive may help explain the risks and health effects of your alcohol use. Your healthcare provider may diagnose you with AUD if you meet certain criteria.

CAN MEDICATION TREAT AUD?

The Food and Drug Administration has approved three medications for treating AUD.^1386^ All three require a prescription. If you receive a prescription for any of them, you'll need to take the medication for at least 3 months^1387^ and probably longer.^1388^ Although these medications don't work for everyone, they do appear to be as safe and effective for older adults as they are for younger adults.^1389^

Not all healthcare providers prescribe these medications. You may need to see an addiction specialist or psychiatrist if you want to explore this approach to treatment. Most people who take medication for AUD do better if they receive counseling too, especially early in treatment.^1390^

Some people incorrectly regard taking medication for AUD as substituting one addiction for another. You may even encounter this attitude in certain addiction treatment programs.^1391^ However, none of these medications is addictive. Using them is like taking medication for any other chronic illness, like diabetes or asthma.^1392^

You may also receive a referral to an addiction specialist or an addiction treatment facility, depending on your level of alcohol use and health status.^1393^ You should seek someone who specializes in addiction treatment with older adults who have been using alcohol for a long time or who have health conditions that could complicate treatment for alcohol misuse. Your healthcare provider may also refer you to a mutual-help group like AA.^1394^

### What Are My Options for Specialized AUD Treatment?

If you receive specialized treatment for AUD, you may move from one setting to another as the treatment proceeds. Whatever the setting, you will usually get counseling and education about alcohol misuse. Personal preference, availability, and eligibility requirements can affect your decision on where to get treatment. Cost can also affect your decision. Check with your health insurer to see how much coverage it provides for the treatment option you seek.

RESOURCE ALERT: TREATMENT LOCATOR FOR VETERANS

If you are a veteran or are covered by health benefits for veterans, the Department of Veterans Affairs (VA) can help you find VA services close to you. Use the VA SUD Program Locator at www.va.gov/directory/guide/SUD.asp for your search.

The following list describes the main specialized treatment options:

• Regular outpatient treatment typically consists of individual therapy, group therapy, or both, provided by a trained therapist. Additional services, such as family therapy and connection to mutual-help groups, may be included.^1395^ Some outpatient treatment is provided by healthcare providers or addiction specialists. In addition to doing assessments and diagnosing AUD, these specialists may provide counseling and prescribe medications for AUD. Outpatient programs differ a lot in how long they last and how intensive they are.
• Medically supervised withdrawal is a process during which healthcare providers monitor you as your body clears itself of alcohol. This process is sometimes called detoxification, or “detox.” In medically supervised withdrawal, medical staff monitor and treat withdrawal symptoms and manage other health conditions as needed.^1396^ Medically supervised withdrawal in an inpatient setting, such as a hospital, is normally recommended for older adults.^1397^ If you undergo medically supervised withdrawal, you may receive referrals from the medical staff to addiction counselors or other behavioral health service providers for continuing treatment of AUD. If no referral is offered, you can ask for one or explore other options for continuing treatment or recovery support, such as attending AA meetings or using a treatment locator like FindTreatment.gov or the Substance Abuse and Mental Health Services Administration's (SAMHSA) National Helpline (1-800-662-HELP).
• Intensive outpatient programs typically provide services at least 3 days a week, for at least 2 or 3 hours each day (or evening).^1398^ These services can include group and individual counseling, family therapy, medical and mental health evaluations, medication, and education about addiction and coping skills.^1399,1400^ These programs may take place at hospitals, mental health clinics, or office-based private practices.
• Partial hospitalization programs typically run 4 to 6 hours a day, 3 to 7 days a week. They are also called day treatment programs. As with intensive outpatient programs, you do not stay overnight for treatment. These programs often treat addiction and mental disorders at the same time.^1401^
• Specialized residential treatment facilities usually offer group and individual therapy, recreational activities, and mutual-help group meetings. Consider this type of facility if you would have difficulty getting to and from outpatient treatment or if you need more counseling, medical services, or ongoing guidance than an outpatient program would offer.

WHAT ARE RESIDENTIAL TREATMENT FACILITIES?

These facilities range from small group homes or recovery houses with few staff and services to specialized facilities with intensive, highly structured programs that keep physicians and nurses on staff. People staying in group homes or recovery houses may get outpatient treatment at another facility. A residential facility may be a good option for you if you think you'd do better in treatment while away from your home or neighborhood.^1402^

### How Do I Pick a Treatment Program?

NIAAA's Alcohol Treatment Navigator recommends 10 general questions to ask when looking for a quality alcohol treatment program. The Navigator is available online (https://alcoholtreatment.niaaa.nih.gov/how-to-find-alcohol-treatment/10-questions-for-alcohol-treatment-programs).

Think about the issues you most want help with in treatment. Ask the programs you're considering whether they address these issues. You may also want to ask:^1403^

• Does the program focus just on older adults or have a special track or groups for older adults?
• Does the program cover topics like grief, loss, and isolation?
• Can an older adult who uses a wheelchair/walker/cane easily enter and move around the facility?
• What modifications will the program make for older adults with vision/hearing problems?
• Do I need my own transportation to get there?

If you can't find a program just for older adults even though that's what you want, consider one that mixes age groups. Research shows that older adults can also do well in these programs.^1404,1405^ If possible, take tours of the facilities that you are considering.

RESOURCE ALERT: SAMHSA'S FREE NATIONAL HELPLINE

SAMHSA's free National Helpline at 1-800-662-HELP (4357) can refer you to SUD treatment facilities that accept Medicare or Medicaid. If you are uninsured, check this SAMHSA directory for the agency in your state to contact about possible help with paying for addiction services: www.samhsa.gov/sites/default/files/ssa-directory-01212020.pdf.

COMMON TYPES OF THERAPY

As part of inpatient or outpatient treatment, you'll likely participate in one or more forms of therapy to help you address the feelings and behaviors that led to your alcohol misuse. Some of the most common therapies are briefly described below. Often, two or more of these therapies are used together.^1406,1407^

Acceptance and commitment therapy encourages people to live a satisfying life by accepting losses that are final, reconnecting with their values, and working toward goals that reflect those values.^1408^

Example: Through therapy, a man who began drinking heavily alone after his wife's death recognizes that drinking conflicts with the value he places on being an involved grandfather. He could enter alcohol treatment with the goal of becoming abstinent so that he can spend more time with his granddaughter.

Behavioral couples therapy (BCT) seeks to encourage abstinence in someone who misuses substances by improving his or her relationship with a spouse or partner through better communication, shared activities, and positive reinforcement. The spouse or partner also participates in the therapy.

Example: Through BCT, a husband agrees to discuss his wife's drinking only during a set time each day, and both he and she agree to end the discussion with words of appreciation for each other.^1409^

CBT involves working with a therapist to identify and change unhelpful thought processes that trigger alcohol misuse and to develop healthier behaviors to replace drinking.^1410,1411^

Example: A man worries that he won't ft in with his golf group if he stops drinking with them after games. After talking about his beliefs and thoughts with his therapist, he could experiment with having only nonalcoholic drinks after games and realize that he's not bothered by his golf partners' reactions.

Coping skills therapy focuses on dealing with difficult thoughts (including cravings), emotions, and situations in ways that don't involve alcohol. Goals include learning how to manage anger and stress, become more assertive, and avoid people and places that encourage drinking.^1412^

Example: A woman who drinks after phone calls with her argumentative brother might role-play with a therapist how to change the subject during an argument or limit the length of calls.

Family therapy ideally involves the entire family of a person in treatment for AUD and seeks to improve how family members relate to each other. The goals are to support both the recovery of the individual in treatment and the family's well-being.^1413^

Example: Through family therapy, a widow who had avoided interacting with her two adult children because of her secret alcohol misuse could work on repairing her relationships with them. They in turn could become more understanding by learning how she drank to cope with their father's death.

Mindfulness-based relapse prevention (MBRP) is a group therapy approach that combines teaching mindful meditation practices and traditional relapse prevention techniques, such as how to refuse drinks. Mindfulness helps you accept awareness of impulses to drink and develop the ability not to act on them.^1414^

Example: Through MBRP, a woman who used to unwind from her job by drinking heavily at home after work could instead use breathing techniques and guided meditations on audiotapes to calm her mind.

Motivational interviewing is an approach for overcoming unhealthy habits in which the therapist helps the client explore and strengthen the desire for change, and then develop and act on a plan for change.^1415^

Example: A man who takes heart medication and socializes mainly at his independent living facility's daily happy hour could, through motivational interviewing, decide that he doesn't want to risk a medication-alcohol interaction. He could do his socializing instead after the facility's nightly movie showing.

Relapse prevention therapy helps people recognize and plan to respond constructively to high-risk situations for, or warning signs of, a return to alcohol use.

Example: A woman at risk of drinking when alone at night could work with a therapist to find activities to do instead of drinking, such as coloring or scrapbooking.

### How Can I Get Support From Family and Friends?

Don't be embarrassed or shy about involving supportive family members and friends in your effort to quit or cut back on drinking. They will probably want to help, especially if they have already told you they are concerned about your drinking. Consider asking them to:^1416,1417,1418^

• Avoid drinking in front of you.
• Offer you just nonalcoholic beverages.
• Join you in alcohol-free activities.
• Go along when you discuss your drinking with a healthcare professional, to help you take notes and to provide support.
• Accompany or drive you to mutual-help group meetings.
• Be available to talk to you if you get an urge to drink.

Another way that family members can help is by participating in family therapy or BCT with you, if you are in treatment and your provider recommends such therapy. For more information, refer family members to SAMHSA's Family Therapy Can Help booklet, which is available at no cost (https://store.samhsa.gov/product/Family-Therapy-Can-Help-For-People-in-Recovery-From-Mental-Illness-or-Addiction/SMA15-4784).^1419^

Also consider asking any family members that you live with to keep little or no alcohol at home.^1420^

WHAT IF MY FAMILY AND FRIENDS ARE NOT SUPPORTIVE?

What if you are uncomfortable asking those around you to actively support your abstinence, or you do ask but don't get a positive response? First, don't isolate yourself.^1421^ Instead, consider joining a mutual-help group and/or working with a recovery coach or peer recovery support specialist. This individual, who often has personal experience with addiction, acts as a mentor and a motivator. He or she can also help you find alcohol treatment. Some are volunteers and some are paid by you or a third party.^1422^

### How Can I Encourage Myself?

First, give yourself credit for realizing that you may need to do something about your drinking.

Remember that many different treatment options are available for alcohol misuse. These options have enabled many older adults like you to stop or reduce their alcohol consumption.^1423^ Congratulate yourself on any action you take to limit how much you drink. In addition, remind yourself that, no matter what your age, overcoming alcohol misuse can help you feel better and live longer.

## Information for Family and Caregivers

### What Can I Do as a Caregiver or Family Member?

#### Know the Warning Signs of Alcohol Misuse

If you think a family member may be misusing alcohol, review the list of warning signs in the “How Can I Tell Whether I'm Misusing Alcohol?” section. Other signs to look for include:^1424,1425^

• Hiding alcohol supplies.
• Denying or justifying drinking.
• Refusing to discuss drinking.
• Becoming annoyed when asked about drinking.^1426^
• Becoming aggressive or abusive.
• Displaying excessive mood swings.
• Having new problems with decision making.^1427^
• Appearing sleepy during the day.
• Falling behind on bills.
• Having unexplained burns or bruises.^1428^
• Having frequent car accidents.
• Talking about or attempting suicide.

Suicide attempts and talk of suicide require immediate attention. Call 911 if your family member attempts or threatens suicide. Call your family member's healthcare professional or the National Suicide Prevention Lifeline (1-800-273-8255) if you worry that he or she is thinking about suicide. Note that by July 2022, you will also be able to reach this hotline by dialing 988.

CHALLENGES TO RECOGNIZING ALCOHOL MISUSE

Alcohol misuse among older adults often goes unrecognized. These three examples illustrate the problem:

• A healthcare provider who cares for an older woman assumes that the broken capillaries on her face are the result of old age rather than her heavy drinking.
• An older man who drinks as much as he did in middle age does not realize that what was moderate drinking then is alcohol misuse now—especially given that he's developed diabetes.
• A daughter does not know that her widowed father misuses alcohol because he drinks only when home alone.

#### Know About Your Family Member's Medications

Know what prescription and OTC medications your relative takes. The same advice applies to dietary supplements, including vitamins and herbal products. Review the “Check Your Medications for Alcohol Interactions” text box for tips on finding out whether these products have harmful interactions with alcohol.

You may need written or verbal permission from your family member to discuss possible alcohol interactions with his or her healthcare provider or pharmacist.^1429^ Even without such permission, you can still inform these healthcare providers of any concerns you have about interactions.

#### Know How To Connect Your Family Member With Help

See “What Are My Options for Specialized AUD Treatment?” for information on finding treatment facilities and providers in your area. Look at the section “Join a Mutual-Help Group” for tips on finding mutual-help group meetings, if this type of support would be appropriate for your family member.

#### Know When and How To Talk About Getting Help

Talking constructively with a family member about a drinking problem takes patience. But the payoff may be a greater willingness on his or her part to address the problem. Where you can, connect the conversation to your concerns about your family member's health. Here are some other tips:^1430,1431,1432^

• Don't bring up the topic when your family member is intoxicated.
• Use “I” messages that express your feelings and concern, not “You” messages that criticize or blame the older adult. For example, you can say, “I worry that you'll have another bad fall if you don't cut back on your drinking” instead of “You drink so much that you get falling-down drunk!”
• Don't use guilt, threats, or bribes to try to get your family member to stop drinking.
• Avoid using offensive terms like “an alcoholic” or “an addict” or “a drunk.”
• Make positive comments about your family member's strengths and personality.
• Adjust what you say and how much you say at one time to match his or her ability to understand.
• Remind the person how drinking interferes with his or her values, relationships, or favorite activities.
• Offer to drive or arrange transportation for treatment or a mutual-help group.

#### Participate in Therapy

Participating in therapy with your family member can support his or her treatment. Your relationship with your family member could also benefit because of your participation. See “Family Therapy” and “Behavioral Couples Therapy” in the “Common Types of Therapy” section for brief descriptions of these approaches. You can read more about family therapy in SAMHSA's Family Therapy Can Help booklet at https://store.samhsa.gov/product/Family-Therapy-Can-Help-For-People-in-Recovery-From-Mental-Illness-or-Addiction/SMA15-4784.

#### Don't Enable Drinking

Sometimes it may seem easier just to pretend that a family member's drinking is not a problem. But doing so can be unhealthy for both of you. Also, if your family member has dementia, don't use alcohol to help him or her sleep or calm down. Doing so is unsafe and can worsen symptoms.

#### Help Your Family Member Avoid Alcohol Withdrawal

If your family member requires emergency hospitalization for any reason, tell the hospital staff immediately if he or she misuses alcohol. Otherwise, he or she may experience alcohol withdrawal, which the medical team could miss or mistake for another condition. The medical team involved in a planned hospitalization for your family member also needs to know in advance if he or she misuses alcohol.^1433^ See the “Is Alcohol Withdrawal a Concern?” section for more information.

#### Take Care of Yourself

Sometimes you have to put yourself first to continue to care for your family member. Accept offers of help and make time to socialize with others. Try to get enough sleep and exercise. Look after yourself by keeping medical appointments and not using alcohol or other substances to cope with stress or other difficult emotions.

WHAT IF I'M OVERWHELMED?

If you are concerned about caregiving's effects on your health or behavior, consider taking the Caregiver Self-Assessment Questionnaire (CSAQ), originally developed and tested by the American Medical Association. This questionnaire is available online (www.healthinaging.org/tools-and-tips/caregiver-self-assessment-questionnaire) without cost in interactive and downloadable versions.

The CSAQ is meant as a guide only. Discuss any concerns you have about your results with your healthcare provider.^1434^ Also consider talking with a therapist, especially one with experience with addiction issues.^1435^

#### Join a Mutual-Help Group

Al-Anon is a mutual-help group for people concerned about or affected by someone with alcohol misuse. If you cannot attend an in-person meeting, look into meetings that take place online or by phone. To learn more, call 1-888-425-2666 (toll-free) or go to the Al-Anon website (https://al-anon.org).

If your family member is in addiction treatment, find out whether the facility or individual provider runs support groups or programs for family members and friends.^1436^ Other options are listed in the Resource Alert at the end of this section.

#### What If My Family Member Won't Discuss Drinking?

Your family member may refuse to discuss his or her drinking habits no matter what you say. Options for next steps include talking to and involving:^1437^

• Your family member's healthcare provider.
• An adult family member.
• A close family friend.
• A clergyperson.
• Your family member's case manager or social worker, if applicable.

It may be easier for your family member to hear about his or her alcohol misuse from someone other than you. Getting another viewpoint may also help your family member see how serious the problem is.

Also consider taking a facility tour, if possible, so that you can better discuss the treatment experience.

RESOURCE ALERT: RESOURCES FOR CAREGIVERS

AARP offers online forums and information resources on caregiving at www.aarp.org/caregiving.

The Alzheimer's Association's locator for its caregiver support groups is available through www.alz.org/help-support/community/support-groups.

The Eldercare Locator, available at https://eldercare.acl.gov/Public/index.aspx or 1-800-677-1116, provides links to state and local agencies on aging and community-based organizations that serve older adults and their caregivers. You can search the site by ZIP Code, city/state, or topic.

The Family Caregiver Alliance has an information line for caregivers of adults with chronic medical illnesses living at home (1-800-445-8106), an online Family Care Navigator that provides a state-by-state list of services and assistance for caregivers, and a free website/app called FCA CareJourney that provides information tailored to individual caregivers' specific needs. To learn more, visit www.caregiver.org.

Through the VA, family caregivers for veterans have free access to a support line, telephone education groups on caregiving and self-care, a 6-week online workshop on caregiving, and peer recovery support mentoring. To learn more, call the support line at 1-855-260-3274 or visit www.caregiver.va.gov/Care_Caregivers.asp.

## Chapter 8 Resources

### General

National Institute on Aging (NIA)—Alcohol Use or Abuse (www.nia.nih.gov/health/topics/alcohol-use-or-abuse): This webpage provides tips on talking to a doctor about alcohol and reasons and resources for addressing alcohol use.

NIA—Older Adults and Alcohol: You Can Get Help (https://order.nia.nih.gov/sites/default/files/2018-01/older-adults-and-alcohol.pdf): This easy-to-read brochure lays out the issues and answers common questions that older adults have about drinking.

NIAAA—Rethinking Drinking (www.rethinkingdrinking.niaaa.nih.gov): This NIAAA website provides information about what a standard drink is; gives tips on how to refuse drinks and reduce or quit drinking; and offers interactive tools to help address alcohol misuse, such as an alcohol spending calculator. Note that the information provided is not specific to older adults.

VA—VetChange (https://mobile.va.gov/app/vetchange): VetChange is an app that, according to the VA, can be used by anyone interested in developing healthier drinking behaviors. Among the app's features are tools for cutting down or quitting drinking and tools for managing stress symptoms. The app is not meant to replace professional treatment.

### Alcohol-Medication Interactions

NIAAA—Harmful Interactions (www.niaaa.nih.gov/publications/brochures-and-fact-sheets/harmful-interactions-mixing-alcohol-with-medicines): This consumer guide provides information about the dangers of harmful medication-medication interactions and medication-alcohol interactions.

### Information on Finding and Accessing Treatment

FindTreatment.gov (https://findtreatment.gov): People seeking treatment for SUDs can use this federal locator maintained by SAMHSA to find treatment facilities based on location, availability of treatment for co-occurring mental disorders, availability of telemedicine care, payment option, age, languages spoken, and access to medication for OUD. The site also links to information on understanding addiction, understanding mental illness, and paying for treatment.

SAMHSA—Behavioral Health Treatment Services Locator (https://findtreatment.samhsa.gov/): This locator is another tool for finding facilities that offer treatment for substance use or mental disorders. The site includes a video tutorial on ways to filter search results by different criteria.

SAMHSA—Finding Quality Treatment for Substance Use Disorders (https://store.samhsa.gov/product/PEP18-TREATMENT-LOC): People seeking alcohol treatment can use this factsheet to learn about the necessary steps to complete before accessing a treatment center and the five signs of a quality treatment center.

MedicareInteractive.org—Treatment for Alcoholism and Substance Use Disorder (www.medicareinteractive.org/get-answers/medicare-covered-services/mental-health-services/treatment-for-alcoholism-and-substance-abuse): This webpage discusses Medicare coverage of treatment for SUDs.

NIAAA—Alcohol Treatment Navigator (https://alcoholtreatment.niaaa.nih.gov): This website helps people understand what alcohol use disorder is and how to locate high-quality treatment for it.