# Appendix—Bibliography

1 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
2 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
3 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
4 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
5 Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/healthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
6 Family Caregiver Alliance. (2019, April 17). Caregiver statistics: Demographics. Retrieved from www.caregiver.org/caregiver-statistics-demographics
7 Drugs.com. (2018). What are drug interactions? Retrieved August 27, 2018, from www.drugs.com/druginteractions.html
8 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
9 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
10 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
11 Centers for Disease Control and Prevention. (2018). Alcohol and Public Health. Frequently Asked Questions. Retrieved from www.cdc.gov/alcohol/faqs.htm
12 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
13 World Health Organization. (2018). Management of substance abuse: Psychoactive substances. Retrieved from www.who.int/substanceabuse/terminology/psychoactivesubstances/en/
14 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
15 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
16 Substance Abuse and Mental Health Services Administration. (2020). National Survey of Substance Abuse Treatment Services (N-SSATS): 2019, Data on substance abuse treatment facilities. Retrieved from https://www.dasis.samhsa.gov/dasis2/nssats/NSSATS2019/2019-NSSATS-R.pdf
17 Blazer, D. G. (2013). The Institute of Medicine report on the mental health and substance use workforce for older adults: A reflection. American Journal of Geriatric Psychiatry, 21(10), 1038–1042.
18 Substance Abuse and Mental Health Services Administration. (2020). National Survey of Substance Abuse Treatment Services (N-SSATS): 2019, Data on substance abuse treatment facilities. Retrieved from https://www.dasis.samhsa.gov/dasis2/nssats/NSSATS2019/2019-NSSATS-R.pdf
19 Grant, B. F., Chou, S. P., Saha, T. D., Pickering, R. P., Kerridge, B. T., Ruan, W. J., … Hasin, D. S. (2017). Prevalence of 12-month alcohol use, high-risk drinking, and DSM-IV alcohol use disorder in the United States, 2001–2002 to 2012–2013: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. JAMA Psychiatry, 74(9), 911–923.28793133
20 Han, B. H. (2018). Aging, multimorbidity, and substance use disorders: The growing case for integrating the principles of geriatric care and harm reduction. International Journal of Drug Policy, 85, 135–136.
21 Gfroerer, J., Penne, M., Pemberton, M., & Folsom, R. (2003). Substance abuse treatment need among older adults in 2020: The impact of the aging baby-boom cohort. Drug and Alcohol Dependence, 69(2), 127–135.12609694
22 Institute of Medicine. (2012). The mental health and substance use workforce for older adults: In whose hands? Washington, DC: National Academies Press.
23 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
24 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
25 Vincent, G. K., & Velkoff, V. A. (2010). The next four decades: The older population in the United States: 2010 to 2050. Washington, DC: Department of Commerce, Economics and Statistics Administration, U.S. Census Bureau.
26 Fox-Grage, W. (2016, April 18). The growing racial and ethnic diversity of older adults. Retrieved from https://blog.aarp.org/thinking-policy/the-growing-racial-and-ethnic-diversity-of-older-adults
27 Gfroerer, J., Penne, M., Pemberton, M., & Folsom, R. (2003). Substance abuse treatment need among older adults in 2020: The impact of the aging baby-boom cohort. Drug and Alcohol Dependence, 69(2), 127–135.12609694
28 Wu, L.-T., & Blazer, D. G. (2011). Illicit and nonmedical drug use among older adults: A review. Journal of Aging and Health, 23(3), 481–504.21084724
29 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115.27159818
30 Davies, E. A., & O'Mahony, M. S. (2015). Adverse drug reactions in special populations: The elderly. British Journal of Clinical Pharmacology, 80, 796–807.25619317
31 Grant, B. F., Goldstein, R. B., Saha, T. D., Chou, S. P., Jung, J., Zhang, H., … Hasin, D. S. (2015). The epidemiology of DSM-5 alcohol use disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions, III. JAMA Psychiatry, 72, 757–766.26039070
32 Grant, B. F., Saha, T. D., Ruan, W. J., Goldstein, R. B., Chou, S. P., Jung, J., … Hasin, D. S. (2016). Epidemiology of DSM-5 drug use disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions-III. JAMA Psychiatry, 73, 39–47.26580136
33 Choi, N. G., DiNitto, D. M., & Marti, C. N. (2016). Older-adult marijuana users and ex-users: Comparisons of sociodemographic characteristics and mental and substance use disorders. Drug and Alcohol Dependence, 165, 94–102.27282425
34 Reynolds, K., Pietrzak, R. H., El-Gabalawy, R., Mackenzie, C. S., & Sareen, J. (2015). Prevalence of psychiatric disorders in U.S. older adults: Findings from a nationally representative survey. World Psychiatry, 14(1), 74–81.25655161
35 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. Washington, DC: Department of Health and Human Services.
36 Whitlock, E. P., Polen, M. R., Green, C. A., Orleans, T., & Klein, J. (2004). Behavioral counseling interventions in primary care to reduce risky/harmful alcohol use by adults: A summary of the evidence for the U.S. Preventive Services Task Force. Annals of Internal Medicine, 140(7), 557–568.15068985
37 Kuerbis, A. N., Yuan, S. E., Borok, J., LeFevre, P., Kim, G. S., Lum, D., … Moore, A. A. (2015). Testing the initial efficacy of a mailed screening and brief feedback intervention to reduce at-risk drinking in middle-aged and older adults: The Comorbidity Alcohol Risk Evaluation Study. Journal of the American Geriatrics Society, 63(2), 321–326.25643851
38 Schonfeld, L., Hazlett, R. W., Hedgecock, D. K., Duchene, D. M., Burns, L. V., & Gum, A. M. (2015). Screening, brief intervention, and referral to treatment for older adults with substance misuse. American Journal of Public Health, 105(1), 205–211.24832147
39 Ettner, S. L., Xu, H., Duru, O. K., Ang, A., Tsengh C.-H., Tallen, L., … Moore, A. A. (2014). The effect of an educational intervention on alcohol consumption, at-risk drinking, and health care utilization in older adults: The Project SHARE study. Journal of Studies on Alcohol and Drugs, 75(3), 447–457.24766757
40 Satre, D. D., Mertens, J. R., Areán, P. A., & Weisner, C. (2004). Five-year alcohol and drug treatment outcomes of older adults versus middle-aged and younger adults in a managed care program. Addiction, 99(10), 1286–1297.15369567
41 Oslin, D. W., Pettinati, H., & Volpicelli, J. R., (2002). Alcoholism treatment adherence: Older age predicts better adherence and drinking outcomes. American Journal of Geriatric Psychiatry, 10(6), 740–747.
42 Taylor, M. H., & Grossberg, G. T. (2012). The growing problem of illicit substance abuse in the elderly: A review. Primary Care Companion for CNS Disorders, 74(4).
43 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
44 National Institute on Alcohol Abuse and Alcoholism, (n.d.). What's a “standard” drink? Retrieved June 14, 2019, from www.rethinkingdrinking.niaaa.nih.gov/How-much-is-too-much/What-counts-as-a-drink/Whats-A-Standard-Drink.aspx
45 Callahan, C. M., & Tierney, W. M. (1995). Health services use and mortality among older primary care patients with alcoholism. Journal of the American Geriatrics Society, 43(12), 1378–1383.7490389
46 Kirchner, J. E., Zubritsky, C., Cody, M., Coakley, E., Chen, H., Ware, J. H. … Levkoff, S. (2007). Alcohol consumption among older adults in primary care. Journal of General Internal Medicine, 22(1), 92–97.17351846
47 Weyerer, S., Schaufele, M., Eifflaender-Gorfer, S., Köhler, L., Maier, W., Haller, F., … Steffi, G. (2009). At-risk alcohol drinking in primary care patients aged 75 years and older. International Journal of Geriatric Psychiatry, 24(12), 1376–1385.19382111
48 Kirchner, J. E., Zubritsky, C., Cody, M., Coakley, E., Chen, H., Ware, J. H. … Levkoff, S. (2007). Alcohol consumption among older adults in primary care. Journal of General Internal Medicine, 22(1), 92–97.17351846
49 Substance Abuse and Mental Health Services Administration. (2012). Older Americans Behavioral Health Issue Brief 2: Alcohol misuse and abuse prevention (p. 1). Retrieved from www.acl.gov/sites/default/files/programs/2016-11/lssue%20Brief%202%20Alcohol%20Misuse.pdf
50 National Institute on Alcohol Abuse and Alcoholism, (n.d.). Older adults. Retrieved from www.niaaa.nih.gov/alcohol-health/special-populations-co-occurring-disorders/older-adults
51 Bagnardi, V., Rota, M., Botteri, E., Tramacere, I., Islami, F., Scotti, L., … LaVecchia, C. (2015). Alcohol consumption and site-specific cancer risk: A comprehensive dose-response meta-analysis. British Journal of Cancer, 772(3), 580–593.
52 Bagnardi, V., Rota, M., Botteri, E., Tramacere, I., Islami, F., Fedirki, L„ … LaVecchia, C. (2013). Light alcohol drinking and cancer: A meta-analysis. Annals of Oncology, 24(2), 301–308.22910838
53 Shaw, Β. Α., Agahi, N„ & Krause, Ν. (2011). Are changes in financial strain associated with changes in alcohol use and smoking among older adults? Journal of Studies on Alcohol and Drugs, 72(6), 917–925.22051205
54 Sacco, P., Bucholz, K. K. & Harrington, D. (2014). Gender differences in stressful life events, social support, perceived stress, and alcohol use among older adults: Results from a national survey. Substance Use and Misuse, 49(4), 456–465.24131262
55 Barry, K. L. & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
56 Holton, A. E., Gallagher, P., Fahey, T., & Cousins, G. (2017). Concurrent use of alcohol interactive medications and alcohol in older adults: A systematic review of prevalence and associated adverse outcomes. BMC Geriatrics, 77(1), 148.
57 Breslow, R. Α., Dong, C„ & White, A. (2015). Prevalence of alcohol-interactive prescription medication use among current drinkers: United States, 1999 to 2010. Alcoholism, Clinical and Experimental Research, 39(2), 371–379.25597432
58 Breslow, R. Α., Dong, C„ & White, A. (2015). Prevalence of alcohol-interactive prescription medication use among current drinkers: United States, 1999 to 2010. Alcoholism, Clinical and Experimental Research, 39(2), 371–379.25597432
59 Moore, Α. Α., Whiteman, E. J., & Ward, Κ. T. (2007). Risks of combined alcohol/medication use in older adults. American Journal of Geriatric Pharmacotherapy, 5(1), 64–74.17608249
60 National Center for Health Statistics. (2019). Health, United States, 2018. Retrieved from www.cdc.gov/nchs/data/hus/hus18.pdf
61 Qato, D. M., Wilder, J., Schümm, L. P., Gillet, V., & Alexander, G. C. (2016). Changes in prescription and over-the-counter medication and dietary supplement use among older adults in the United States, 2005 vs. 2011. JAMA Internal Medicine, 176(4), 473–482.26998708
62 Davies, Ε. Α., & O'Mahony, M. S. (2015). Adverse drug reactions in special populations: The elderly. British Journal of Clinical Pharmacology, 80, 796–807.25619317
63 Bush, D. M. (2013). Emergency department visits for drug misuse or abuse involving the pain medication tramadol. The CBHSQ Report. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/sites/default/files/report_1966/ShortReport-1966.html
64 Agency for Healthcare Research and Quality. (2019, September). Patient safety primer: Medication administration errors. Retrieved October 10, 2019, from https://psnet.ahrq.gov/primer/medication-administration-errors
65 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
66 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
67 Aira, M., Hartikainen, S., & Sulkava, R. (2008). Drinking alcohol for medicinal purposes by people aged over 75: A community-based interview study. Family Practice, 25(6), 445–449.18826990
68 Levi-Minzi, M. A., Surratt, H. L., Kurtz, S. P., & Buttram, M. E. (2013). Under treatment of pain: A prescription for opioid misuse among the elderly. Pain Medicine, 14(11), 1719–1729.23841571
69 Christie, M. M., Bamber, D., Powell, C., Arrindell, T., & Pant, A. (2013). Older adult problem drinkers: Who presents for alcohol treatment? Aging and Mental Health, 17(1), 24–32.22757629
70 Colliver, J. D., Compton, W. M., Gfroerer, J. C., & Condon, T. (2006). Projecting drug use among aging baby boomers in 2020. Annals of Epidemiology, 16, 257–265.16275134
71 Olfson, M., Wang, S., Iza, M., Crystal, S., & Blanco, C. (2013). National trends in the office-based prescription of schedule II opioids. Journal of Clinical Psychiatry, 74(9), 932–939.24107767
72 Dobscha, S. K., Loveyoy, T. I., Morasco, B. J., Kovas, A. E., Peters, D. M., Hart, K., … McFarland, B. H. (2016). Predictors of improvements in pain intensity in a national cohort of older veterans with chronic pain. Journal of Pain, 17(7), 824–835.27058162
73 Jones, C. M., Paulozzi, L. J., & Mack, K. A. (2014). Alcohol involvement in opioid pain reliever and benzodiazepine drug abuse-related emergency department visits and drug-related deaths: United States, 2010. Morbidity and Mortal Weekly Report, 63(40), 881–885.
74 Food and Drug Administration. (2017). FDA Drug Safety Communication: FDA warns about serious risks and death when combining opioid pain or cough medicines with benzodiazepines; Requires its strongest warning. Retrieved from www.fda.gov/Drugs/DrugSafety/ucm518473.htm
75 van der Schrier, R., Roozekrans, M., Olofsen, E., Aarts, L., & van Velzen, M. (2017). Influence of ethanol on oxycodone-induced respiratory depression: A dose-escalating study in young and elderly individuals. Anesthesiology, 126(3), 534–542.28170358
76 Centers for Disease Control and Prevention, National Center for Health Statistics. (2020). Multiple cause of death data 1999–2018 on CDC WONDER [Data set]. Retrieved April 14, 2020, from https://wonder.cdc.gov/mcd.html
77 Food and Drug Administration. (2017). FDA Drug Safety Communication: FDA urges caution about withholding opioid addiction medications from patients taking benzodiazepines or CNS depressants: Careful medication management can reduce risks. Retrieved from www.fda.gov/drugs/drug-safety-and-availability/fda-drug-safety-communication-fda-urges-caution-about-withholding-opioid-addiction-medications
78 Maust, D. T., Kales, H. C., Wiechers, I. R., Blow, F. C., & Olfson, M. (2016). No end in sight: Benzodiazepine use in older adults in the United States. Journal of the American Geriatrics Society, 64, 2546–2553.27879984
79 Woolcott, J. C., Richardson, K. J., & Wiens, M. O. (2009). Meta-analysis of the impact of 9 medication classes on falls in elderly persons. Archives of Internal Medicine, 169(21), 1952–1960.19933955
80 Tannenbaum, C., Paquette, A., Hilmer, S., Holroyd-Leduc, J., & Carnahan, R. (2012). A systematic review of amnestic and non-amnestic mild cognitive impairment induced by anticholinergic, antihistamine, GABAergic, and opioid drugs. Drugs and Aging, 29(8), 639–658.22812538
81 Dassanayake, T., Michie, P., Carter G., & Jones, A. (2011). Effects of benzodiazepines, antidepressants and opioids on driving. Drug Safety, 34(2), 125–156.21247221
82 Jones, C. M., Mack, K. A., & Paulozzi, L. J. (2013). Pharmaceutical overdose deaths, United States, 2010. JAMA, 309(7), 657–659.23423407
83 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
84 Compton, W. M., Han, B., Hughes, A., Jones, C. M., & Blanco, C. (2017). Use of marijuana for medical purposes among adults in the United States. JAMA, 317, 209–211.27992636
85 Minerbi, A., Häuser, W., & Fitzcharles, M. A. (2019). Medical cannabis for older patients. Drugs and Aging, 36(1), 39–51.30488174
86 Minerbi, A., Häuser, W., & Fitzcharles, M. A. (2019). Medical cannabis for older patients. Drugs and Aging, 36(1), 39–51.30488174
87 Briscoe, J., & Casarett, D. (2018). Medical marijuana use in older adults. Journal of the American Geriatrics Society, 66, 859–863.29668039
88 McCance-Katz, E. F. (2019). Urgent and emerging issues in prevention: Marijuana, kratom, e-cigarettes. Retrieved from www.samhsa.gov/sites/default/files/samhsas15thannual_prevention_day_afternoon_plenary_recording.pdf
89 Alsherbiny, M. A., & Li, C. G. (2018). Medicinal cannabis—Potential drug interactions. Medicines (Basel), 6(1), 3.
90 Bolla, K. I., Brown, K., Eldreth, D., Tate, K., & Cadet, J. L. (2002). Dose-related neurocognitive effects of marijuana use. Neurology, 59(9), 1337–1343.12427880
91 Hayatbakhsh, M. R., Najman, J. M., Jamrozik, K., Mamun, A. A., Alati, R., & Bor, W. (2007). Cannabis and anxiety and depression in young adults: A large prospective study. Journal of the American Academy of Child and Adolescent Psychiatry, 46(3), 408–417.17314727
92 van Laar, M., van Dorsselaer, S., Monshouwer, K., & de Graaf, R. (2007). Does cannabis use predict the first incidence of mood and anxiety disorders in the adult population? Addiction, 102(8), 1251–1260.17624975
93 Briscoe, J., & Casarett, D. (2018). Medical marijuana use in older adults. Journal of the American Geriatrics Society, 66, 859–863.29668039
94 ElSohly, M. A., Mehmedic, Z., Foster, S., Gon, C., Chandra, S., & Church, J. C. (2016). Changes in cannabis potency over the last 2 decades (1995–2014): Analysis of current data in the United States. Biological Psychiatry, 79(7), 613–619.26903403
95 Substance Abuse and Mental Health Services Administration. (2014). Results from the 2013 National Survey on Drug Use and Health: Summary of national findings. NSDUH Series H-48. HHS Publication No. (SMA) 14–4863. Rockville, MD: Substance Abuse and Mental Health Services Administration.
96 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
97 Chhatre, S., Cook, R., Mallik, E., & Jayadevappa, R. (2017). Trends in substance use admissions among older adults. BMC Health Services Research, 17(1), 584.28830504
98 Qato, D. M., Wilder, J., Schumm, L. P., Gillet, V., & Alexander, G. C. (2016). Changes in prescription and over-the-counter medication and dietary supplement use among older adults in the United States, 2005 vs. 2011. JAMA Internal Medicine, 176(4), 473–482.26998708
99 Qato, D. M., Wilder, J., Schumm, L. P., Gillet, V., & Alexander, G. C. (2016). Changes in prescription and over-the-counter medication and dietary supplement use among older adults in the United States, 2005 vs. 2011. JAMA Internal Medicine, 176(4), 473–482.26998708
100 Satre, D. D., Chi, F., Mertens, J., & Weisner, C. (2012). Effects of age and life transitions on alcohol and drug treatment outcome over nine years. Journal of Studies on Alcohol and Drugs, 73, 459–468.22456251
101 Sajatovik, M., Blow, F., & Ignacio, R. V. (2006). Psychiatric comorbidity in older adults with bipolar disorder. International Journal of Geriatric Psychiatry, 21, 582–587.16783798
102 Bartels, S. J., Blow, F. C., Van Citters, A. D., & Brockmann, L. M. (2006). Dual diagnosis among older adults: Co-occurring substance abuse and psychiatric illness. Journal of Dual Diagnosis, 2(3), 9–30.
103 Bartels, S. J., Miles, K. M., Oxman, T. E., Zimmerman, S., Cori, L. A., Pomerantz, A. S., Mendolevicz, N. (2006). Correlates of co-occurring depressive symptoms and alcohol use in an older primary care clinic population. Journal of Dual Diagnosis, 2(3), 57–72.
104 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
105 Satre, D. D., Chi, F., Mertens, J., & Weisner, C. (2012). Effects of age and life transitions on alcohol and drug treatment outcome over nine years. Journal of Studies on Alcohol and Drugs, 73, 459–468.22456251
106 Satre, D. D., Chi, F., Mertens, J., & Weisner, C. (2012). Effects of age and life transitions on alcohol and drug treatment outcome over nine years. Journal of Studies on Alcohol and Drugs, 73, 459–468.22456251
107 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS Publication No. (SMA) 03–3824. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
108 Wu, L. T., & Blazer, D. G. (2011). Illicit and nonmedical drug use among older adults: A review. Journal of Aging and Health, 23(3), 481–504.21084724
109 Klein, W. C., & Jess, C. (2002). One last pleasure? Alcohol use among elderly people in nursing homes. Health and Social Work, 27(3), 193–203.12230044
110 Benshoff, J. J., Harrawood, L. K., & Koch, D. S. (2003). Substance abuse and the elderly: Unique issues and concerns. Journal of Rehabilitation, 69(2), 43.
111 Whitlock, E. P., Green, C. A., & Polen, M. R. (2004). Behavioral counseling interventions in primary care to reduce risky/harmful alcohol use by adults: A summary of the evidence for the U.S. Preventive Services Task Force. Annals of Internal Medicine, 140(7), 557–568.15068985
112 Kuerbis, A. N., Yuan, S. E., Borok, J., LeFevre, P., Kim, G. S., Lum, D., … Moore, A. A. (2015). Testing the initial efficacy of a mailed screening and brief feedback intervention to reduce at-risk drinking in middle-aged and older adults: The Comorbidity Alcohol Risk Evaluation Study. Journal of the American Geriatrics Society, 63(2), 321–326.25643851
113 Schonfeld, L., King-Kallimanis, B. L., Duchene, D. M., Etheridge, R. L., Herrera, J. R., Barry, K. L., & Lynn, N. (2015). Screening, brief intervention, and referral to treatment for older adults with substance misuse. American Journal of Public Health, 105(1), 205–211.24832147
114 Ettner, S. L., Xu, H., Duru, O. K., Ang, A., Tseng, C.-H., Tallen, L., … Moore, A. A. (2014). The effect of an educational intervention on alcohol consumption, at-risk drinking, and health care utilization in older adults: The Project SHARE study. Journal of Studies on Alcohol and Drugs, 75(3), 447–457.24766757
115 Satre, D. D., Mertens, J. R., Areán, P. A., & Weisner, C. (2004). Five-year alcohol and drug treatment outcomes of older adults versus middle-aged and younger adults in a managed care program. Addiction, 99(10), 1286–1297.15369567
116 Oslin, D. W., Pettinati, H., & Volpicelli, J. R. (2002). Alcoholism treatment adherence: Older age predicts better adherence and drinking outcomes. American Journal of Geriatric Psychiatry, 10(6), 740–747.
117 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115.27159818
118 Barry, K. L., Brockmann, L., & Blow, F. C. (2010). Brief interventions for alcohol and drug problems. In N. S. Miller & M. S. Gold (Eds.), Addictive disorders in medical populations (pp. 557–573). Hoboken, NJ: Wiley-Blackwell.
119 Schonfeld, L. Hazlett, R. W., Hedgecock, D. K., Duchene, D. M., Burns, L. V., & Gum, A. M. (2015). Screening, brief intervention, and referral to treatment for older adults with substance misuse. American Journal of Public Health, 105(1), 205–211.24832147
120 Barry, K., & Fleming, M. (1990). Computerized administration of alcoholism screening tests in a primary care setting. Journal of the American Board of Family Practice, 3(2), 93–98.2185611
121 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
122 Gfroerer, J., Penne, M., Pemberton, M., & Folsom, R. (2003). Substance abuse treatment need among older adults in 2020: The impact of the aging baby-boom cohort. Drug and Alcohol Dependence, 69(2), 127–135.12609694
123 Chhatre, S., Cook, E., Mallik, E., & Jayadevappa, R. (2017). Trends in substance use admissions among older adults. BMC Health Services Research, 17(1), 584.28830504
124 Chhatre, S., Cook, E., Mallik, E., & Jayadevappa, R. (2017). Trends in substance use admissions among older adults. BMC Health Services Research, 17(1), 584.28830504
125 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
126 Babatunde, O. T., Outlaw, K. R., Forbe, B., & Gay, T. (2014). Revisiting baby boomers and alcohol use: Emerging treatment trends. Journal of Human Behavior in the Social Environment, 24, 597–611.
127 Kinney, J. (2011). Loosening the grip: A handbook of alcohol information (10th ed.). Boston, MA: McGraw-Hill.
128 Bommersbach, T. J., Lapid, M. A., Rumman, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
129 Babatunde, O. T., Outlaw, K. R., Forbe, B., & Gay, T. (2014). Revisiting baby boomers and alcohol use: Emerging treatment trends. Journal of Human Behavior in the Social Environment, 24, 597–611.
130 Jonas, D. E., Amick, H. R., Feltner, C., Bobashev, G., Thomas, K., Wines, R., … Garbutt, J. C. (2014). Pharmacotherapy for adults with alcohol use disorders in outpatient settings: A systematic review and meta-analysis. JAMA, 311(18), 1889–1900.24825644
131 Winslow, B. T., Onysko, M., & Hebert, M. (2016). Medications for alcohol use disorder. American Family Physician, 93(6), 457–465.26977830
132 Witkiewitz, K., Saville, K., & Hamreus, K. (2012). Acamprosate for treatment of alcohol dependence: Mechanisms, efficacy, and clinical utility. Therapeutics and Clinical Risk Management, 8, 45–53.22346357
133 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
134 Mooney, L. J., & McCance-Katz, E. F. (2016). Psychopharmacological treatments. In A. H. Mack, K. T. Brady, S. I. Miller, & R. F. Frances (Eds.), Clinical textbook of addictive disorders (4th ed., pp. 668–694). New York, NY: Guilford Press.
135 Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
136 Winslow, B. T., Onysko, M., & Hebert, M. (2016). Medications for alcohol use disorder. American Family Physician, 93(6), 457–465.26977830
137 Mooney, L. J., & McCance-Katz, E. F. (2016). Psychopharmacological treatments. In A. H. Mack, K. T. Brady, S. I. Miller, & R. F. Frances (Eds.), Clinical textbook of addictive disorders (4th ed., pp. 668–694). New York, NY: Guilford Press.
138 Hassell, C., Wilkins, K., & Trevisan, L. A. (2017). Pharmacology of geriatric substance use disorders: Considerations and future directions. Current Treatment Options in Psychiatry, 4(1), 102–115.
139 Le Roux, C., Tang, Y., & Drexler, K. (2016). Alcohol and opioid use disorder in older adults: Neglected and treatable illnesses. Current Psychiatry Reports, 18, 87.27488204
140 Lal, R., & Pattanayak, R. D. (2017). Alcohol use among the elderly: Issues and considerations. Journal of Geriatric Mental Health, 4(1), 4–10.
141 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
142 Skinner, M. D., Lahmek, P., Pham, H., & Aubin, H. J. (2014). Disulfiram efficacy in the treatment of alcohol dependence: A meta-analysis. PLoS One, 9(2), e87366. doi:10.1371/journal.pone.0087366 24520330
143 Winslow, B. T., Onysko, M., & Hebert, M. (2016). Medications for alcohol use disorder. American Family Physician, 93(6), 457–465.26977830
144 Sinclair, J., Chambers, S., Shiles, C., & Baldwin, D. S. (2016). Safety and tolerability of pharmacological treatment of alcohol dependence: Comprehensive review of evidence. Drug Safety, 39, 627–645.27023898
145 Connery, H. S. (2015). Medication-assisted treatment of opioid use disorder: Review of the evidence and future directions. Harvard Review of Psychiatry, 23(2), 63–75.25747920
146 Substance Abuse and Mental Health Services Administration. (2020). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP20-02-01-006. Rockville, MD: Substance Abuse and Mental Health Services Administration.
147 Substance Abuse and Mental Health Services Administration. (2020). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP20-02-01-006. Rockville, MD: Substance Abuse and Mental Health Services Administration.
148 Oslin, D., Liberto, J. G., O'Brien, J., & Krois, S. (1997). Tolerability of naltrexone in treating older, alcohol-dependent patients. American Journal on Addictions, 6(3), 266–270.9256993
149 Oslin, D., Liberto, J. G., O'Brien, J., Krois, S., & Norbeck, J. (1997). Naltrexone as an adjunctive treatment for older patients with alcohol dependence. American Journal of Geriatric Psychiatry, 5(4), 324–332.
150 World Health Organization. (2017). WHO model list of essential medications. Retrieved from https://apps.who.int/iris/bitstream/handle/10665/273826/EML-20-eng.pdf?ua=1
151 Herget, G. (2005). Methadone and buprenorphine added to the WHO list of essential medicines. HIV/AIDS Policy and Law Review, 10(3), 23–24.
152 Joshi, P., Shah, N. K., & Kirane, H. D. (2019). Medication-assisted treatment for opioid use disorder in older adults: An emerging role for the geriatric psychiatrist. American Journal of Geriatric Psychiatry, 27(4), 455–457.
153 Karp, J. F., Butters, M. A., Begley, A. E., Miller, M. D., Lenze, E. J., Blumberger, D. M., … Reynolds, C. F., III. (2014). Safety, tolerability, and clinical effect of low-dose buprenorphine for treatment-resistant depression in midlife and older adults. Journal of Clinical Psychiatry, 75(8), e785–e793.25191915
154 Purdue Pharma L.P. (2017). Advisory Committee briefing materials for Joint Meeting of the Anesthetic and Analgesic Drug Products Advisory Committee and Drug Safety and Risk Management Advisory Committee. Retrieved from www.fda.gov/media/107620/download
155 Pergolizzi, J. V., Raffa, R. B., Marcum, Z., Colucci, S., & Ripa, S. R. (2017). Safety of buprenorphine transdermal system in the management of pain in older adults. Postgraduate Medicine, 129(1), 92–101.27929709
156 Substance Abuse and Mental Health Services Administration. (2020). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP20-02-01-006. Rockville, MD: Substance Abuse and Mental Health Services Administration.
157 World Health Organization. (2017). WHO model list of essential medications. Retrieved from https://apps.who.int/iris/bitstream/handle/10665/273826/EML-20-eng.pdf?ua=1
158 Herget, G. (2005). Methadone and buprenorphine added to the WHO list of essential medicines. HIV/AIDS Policy and Law Review, 10(3), 23–24.
159 Sullivan, M., & Levin, F. (2016). Addiction in the older patient. New York, NY: Oxford University Press.
160 Abdulla, A., Adams, N., Bone, M., Elliott, A. M., Gaffin, J., … Schofield, P. (2013). Guidance on management of pain in older people. Age and Ageing, 42, i1–i57.23420266
161 Malec, M., & Shega, J. W. (2015). Pain management in the elderly. Medical Clinics of North America, 99(2), 337–350.25700587
162 Gallagher, R. (2009). Methadone: An effective, safe drug of first choice for pain management in frail older adults. Pain Medicine, 10(2), 319–326.19207240
163 Martin, J. A., Campbell, A., Killip, T., Kotz, M., Krantz, M. J., Kreek, M. J., … Substance Abuse and Mental Health Services Administration. (2011). QT interval screening in methadone maintenance treatment: Report of a SAMHSA expert panel. Journal of Addictive Diseases, 30(4), 283–306.22026519
164 Vu Bach, T., Pan, J., Kirstein, A., Grief, C. J., & Grossman, D. (2016). Use of methadone as an adjuvant medication to low-dose opioids for neuropathic pain in the frail elderly: A case series. Journal of Palliative Medicine, 19(12), 1351–1355.27726521
165 Lehn, J. M., & Pinderhughes, S. T. (2017, January). Methadone for treating pain in older adults. Elder Care. Retrieved from www.uofazcenteronaging.com/sites/default/files/methadone_for_treatment_of_pain.pdf
166 World Health Organization. (2017). WHO model list of essential medications. Retrieved from https://apps.who.int/iris/bitstream/handle/10665/273826/EML-20-eng.pdf?ua=1
167 Chau, D. L., Walker, V., Pai, L., & Cho, L. M. (2008). Opiates and elderly: Use and side effects. Clinical Interventions in Aging, 3(2), 273–278.18686750
168 Satre, D. D., Mertens, J. R., Areán, P. A., & Weisner, C. (2004). Five-year alcohol and drug treatment outcomes of older adults versus middle-aged and younger adults in a managed care program. Addiction, 99(10), 1286–1297.15369567
169 Oslin, D. W., Pettinati, H., & Volpicelli, J. R. (2002). Alcoholism treatment adherence: Older age predicts better adherence and drinking outcomes. American Journal of Geriatric Psychiatry, 10(6), 740–747.
170 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse: Research and Treatment, 7, 13–37.23471422
171 Lemke, S., & Moos, R. H. (2003). Treatment and outcomes of older patients with alcohol use disorders in community residential programs. Journal of Studies on Alcohol, 64(2), 219–226.12713195
172 Substance Abuse and Mental Health Services Administration. (2020). National Survey of Substance Abuse Treatment Services (N-SSATS): 2019, Data on substance abuse treatment facilities. Retrieved from https://wwwdasis.samhsa.gov/dasis2/nssats/NSSATS_2019/2019-NSSATS-R.pdf
173 Shutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2014). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. Rao, & P. Crome (Eds.), Substance use and older people. West Sussex, UK: Wiley-Blackwell.
174 D'Agostino, C. S., Blow, F. C., Barry, K., & Podgorski, C. (2006). Community interventions for older adults with comorbid substance abuse: The Geriatric Addictions Program (GAP). Journal of Dual Diagnosis, 2(3), 31–45.
175 Schonfeld, L., Hazlett, R. W., Hedgecock, D. K., Duchene, D. M., Burns, L. V., & Gum, A. M. (2015). Screening, brief intervention, and referral to treatment for older adults with substance misuse. American Journal of Public Health, 105(1), 205–211.24832147
176 Han, B. H., Masukawa, K., Rosenbloom, D., Kuerbis, A., Helmuth, E., Liao, D. H., & Moore, A. A. (2018). Use of web-based screening and brief intervention for unhealthy alcohol use by older adults. Journal of Substance Abuse Treatment, 86, 70.29415854
177 Choi, N. G., DiNitto, D. M., & Marti, N. C. (2014). Treatment use, perceived need, and barriers to seeking treatment for substance abuse and mental health problems among older adults compared to younger adults. Drug and Alcohol Dependence, 145, 113–120.25456572
178 Blais, R. K., Tsai, J., Southwick, S. M., & Pietrzak, R. H. (2015). Barriers and facilitators related to mental health care use among older veterans in the United States. Psychiatric Services, 66(5), 500–506.25639990
179 Crome, I. (2013). Substance misuse in the older person: Setting higher standards. Clinical Medicine (London), 13(Suppl. 6), s46–s49.
180 Royal College of Psychiatrists. (2015). Substance misuse in older people: An information guide. Older Persons' Substance Misuse Working Group faculty report. Retrieved from www.researchgate.net/publication/278779731SubstancemisuseinOlderPeopleaninformationguide
181 Crome, I. (2013). Substance misuse in the older person: Setting higher standards. Clinical Medicine (London), 13(Suppl. 6), s46–s49.
182 Substance Abuse and Mental Health Services Administration. (2020). National Survey of Substance Abuse Treatment Services (N-SSATS): 2019, Data on substance abuse treatment facilities. Retrieved from https://wwwdasis.samhsa.gov/dasis2/nssats/NSSATS_2019/2019-NSSATS-R.pdf
183 Priester, M. A., Browne, T., Iachini, A., Clone, S., DeHart, D., & Seay, K. D. (2016). Treatment access barriers and disparities among individuals with co-occurring mental health and substance use disorders: An integrative literature review. Journal of Substance Abuse Treatment, 61, 47–59.26531892
184 Sacco, P., & Kuerbis, A. (2013). Older adults. In M. G. Vaughn & B. E. Perron (Eds.), Social work practice in the addictions. New York, NY: Springer.
185 Borok, J., Galier, P., Dinolfo, M., Welgreen, S., Hoffing, M., Davis, J. W., … Moore, A. A. (2013). Why do older unhealthy drinkers decide to make changes or not in their alcohol consumption? Data from the Healthy Living as You Age study. Journal of the American Geriatrics Society, 61(8), 1296–1302.23889690
186 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
187 Royal College of Psychiatrists. (2015). Substance misuse in older people: An information guide. Older Persons' Substance Misuse Working Group faculty report. Retrieved from www.researchgate.net/publication/278779731SubstancemisuseinOlderPeopleaninformationguide
188 Briggs, W., Magnus, V., Lassiter, P., Patterson, A., & Smith, L. (2011). Substance use, misuse, and abuse among older adults: Implications for clinical mental health counselors. Journal of Mental Health Counseling, 33(2), 112–127.
189 Royal College of Psychiatrists. (2015). Substance misuse in older people: An information guide. Older Persons' Substance Misuse Working Group faculty report. Retrieved through www.researchgate.net/publication/278779731SubstancemisuseinOlderPeopleaninformationguide
190 Chrisler, J. C., Barney, A., & Palatino, B. (2016). Ageism can be hazardous to women's health: Ageism, sexism, and stereotypes of older women in the healthcare system. Journal of Social Issues, 72(1), 86–104.
191 Royal College of Psychiatrists. (2015). Substance misuse in older people: An information guide. Older Persons' Substance Misuse Working Group faculty report. Retrieved through www.researchgate.net/publication/278779731SubstancemisuseinOlderPeopleaninformationguide
192 Choi, N. G., DiNitto, D. M., & Marti, N. C. (2014). Treatment use, perceived need, and barriers to seeking treatment for substance abuse and mental health problems among older adults compared to younger adults. Drug and Alcohol Dependence, 145, 113–120.25456572
193 Osborn, R., Doty, M. M., Moulds, D., Sarnak, D. O., & Shah, A. (2017). Older Americans were sicker and faced more financial barriers to health care than counterparts in other countries. Health Affairs (Millwood), 36(12), 2123–2132.
194 Choi, N. G., DiNitto, D. M., & Marti, N. C. (2014). Treatment use, perceived need, and barriers to seeking treatment for substance abuse and mental health problems among older adults compared to younger adults. Drug and Alcohol Dependence, 145, 113–120.25456572
195 Hadley Strout, E., Fox, L., Castro, A., Haroun, P., Leavitt, B., Ross, C., … Carney, J. K. (2016). Access to transportation for Chittenden County Vermont older adults. Aging Clinical and Experimental Research, 28(4), 769–774.26542413
196 Castle, N., Wagner, L., Ferguson-Rome, J., Smith, M., & Handler, S. (2012). Alcohol misuse and abuse reported by nurse aides in assisted living. Research on Aging, 34(3), 321–336.
197 Klein, W. C., & Jess, C. (2002). One last pleasure? Alcohol use among elderly people in nursing homes. Health and Social Work, 27(3), 193–203.12230044
198 White, J. B., Duncan, D. F., Burr, D., Nicholson, B. T., Bonaguro, J., & Abrahamson, K. (2015). Substance abuse policies in long-term care facilities: A survey with implications for education of long-term care providers. Educational Gerontology, 41(7), 519–526.
199 Moos, R. H., Schutte, K. K., Brennan, P. L., & Moos, B. S. (2011). Personal, family and social functioning among older couples concordant and discordant for high-risk alcohol consumption. Addiction, 106(2), 324–334.20883458
200 Bremer, D., Inhestern, L., & von dem Knesebeck, O. (2017). Social relationships and physician utilization among older adults: A systematic review. PLoS One, 12(9), e0185672. https://doi.org/10.1371/journal.pone.0185672 28957429
201 Graham, C. L., Scharlach, A. E., & Price Wolf, J. (2014). The impact of the “Village” model on health, well-being, service access, and social engagement of older adults. Health Education Behavior, 41(Suppl. 1), 91S–97S.24799128
202 Institute of Medicine. (2012). The mental health and substance use workforce for older adults: In whose hands? Washington, DC: National Academies Press.
203 Bartels, S. J., Pepin, R., & Gill, L. E. (2014). The paradox of scarcity in a land of plenty: Meeting the needs of older adults with mental health and substance use disorders. Generations, 38(3), 6–13.25663741
204 Institute of Medicine. (2012). The mental health and substance use workforce for older adults: In whose hands? Washington, DC: National Academies Press.
205 Gage, S., & Melillo, K. D. (2011). Substance abuse in older adults: Policy issues. Journal of Gerontology Nursing, 37(12), 8–11.
206 Institute of Medicine. (2012). The mental health and substance use workforce for older adults: In whose hands? Washington, DC: National Academies Press.
207 National Research Council. (2006). When I'm 64. In L. L. Carstensen & C. R. Hartel (Eds.), Motivation and behavior change. Committee on Aging Frontiers in Social Psychology, Personality, and Adult Developmental Psychology. Board on Behavioral, Cognitive, and Sensory Sciences, Division of Behavioral and Social Sciences and Education. Washington, DC: National Academies Press.
208 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
209 Stahl, S. T., & Schulz, R. (2014). Changes in routine health behaviors following late-life bereavement: A systematic review. Journal of Behavioral Medicine, 37(4), 736–755.23881308
210 Kelly, S., Olanrewaju, O., Cowan, A., Brayne, C., & Lafortune, L. (2018). Alcohol and older people: A systematic review of barriers, facilitators and context of drinking in older people and implications for intervention design. PLoS One, 13(1), e0191189.29370214
211 Levy, H., & Janke, A. (2016). Health literacy and access to care. Journal of Health Communication, 21(Suppl. 1), 43–50.27043757
212 Geboers, B., Reijneveld, S. A., Jansen, C. J. M., & de Winter, A. F. (2016). Health literacy is associated with health behaviors and social factors among older adults: Results from the LifeLines Cohort Study. Journal of Health Communication, 21(Suppl. 2), 45–53.27661472
213 Findley, A. (2015). Low health literacy and older adults: Meanings, problems, and recommendations for social work. Social Work in Health Care, 54(1), 65–81.25588097
214 Royal College of Psychiatrists. (2015). Substance misuse in older people: An information guide. Older Persons' Substance Misuse Working Group faculty report. Retrieved through www.researchgate.net/publication/278779731_Substance_misuse_in_Older_People_an_information_guide
215 Barrio, C., Palinkas, L. A., Yamada, A. M., Fuentes, D., Criado, V., Garcia, P., & Jeste, D. V. (2008). Unmet needs for mental health services for Latino older adults: Perspectives from consumers, family members, advocates, and service providers. Community Mental Health Journal, 44(1), 57–74.18026876
216 Jimenez, D. E., Bartels, S. J., Cardenas, V., & Alegria, M. (2013). Stigmatizing attitudes toward mental illness among racial/ethnic older adults in primary care. International Journal of Geriatric Psychiatry, 28(10), 1061–1068.23361866
217 De Guzman, E., Woods-Giscombe, C. L., & Beeber, L. S. (2015). Barriers and facilitators of Hispanic older adult mental health service utilization in the USA. Issues in Mental Health Nursing, 36(1), 11–20.25398071
218 Barrio, C., Palinkas, L. A., Yamada, A. M., Fuentes, D., Criado, V., Garcia, P., & Jeste, D. V. (2008). Unmet needs for mental health services for Latino older adults: Perspectives from consumers, family members, advocates, and service providers. Community Mental Health Journal, 44(1), 57–74.18026876
219 Sorkin, D. H., Murphy, M., Nguyen, H., & Biegler, K. A. (2016). Barriers to mental health care for an ethnically and racially diverse sample of older adults. Journal of the American Geriatrics Society, 64(10), 2138–2143.27565017
220 Auldridge, A., Tamar-Mattis, A., Kennedy, S., Ames, E., & Tobin, H. J. (2012). Improving the lives of transgender older adults: Recommendations for policy and practice. Services and Advocacy for GLBT Elders and the National Center for Transgender Equality. Retrieved from https://transequality.org/issues/resources/improving-lives-transgender-older-adults-full-report
221 Koenig, T. L., & Crisp, C. (2008). Ethical issues in practice with older women who misuse substances. Substance Use and Misuse, 43(8–9), 1045–1061.18649229
222 Chrisler, J. C., Barney, A., & Palatino, B. (2016). Ageism can be hazardous to women's health: Ageism, sexism, and stereotypes of older women in the healthcare system. Journal of Social Issues, 72(1), 86–104.
223 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
224 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
225 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
226 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
227 Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/healthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
228 Family Caregiver Alliance. (2019, April 17). Caregiver statistics: Demographics. Retrieved from www.caregiver.org/caregiver-statistics-demographics
229 Drugs.com. (2018). What are drug interactions? Retrieved August 27, 2018, from www.drugs.com/drug_interactions.html
230 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
231 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
232 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
233 Centers for Disease Control and Prevention. (2018). Alcohol and Public Health. Frequently Asked Questions. Retrieved from www.cdc.gov/alcohol/faqs.htm
234 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
235 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
236 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
237 Moy, I., Crome, P., Crome, I., & Fisher, M. (2011). Systematic and narrative review of treatment for older people with substance problems. European Geriatric Medicine, 2(4), 212–236.
238 Satre, D. D. (2015). Alcohol and drug use problems among older adults. Clinical Psychology: Science and Practice, 22(3), 238–254.
239 Rothrauff, T. C., Abraham, A. J., Bride, B. E., & Roman, P. M. (2011). Substance abuse treatment for older adults in private centers. Substance Abuse, 32(1), 7–15.21302179
240 Substance Abuse and Mental Health Services Administration. (2020). National Survey of Substance Abuse Treatment Services (N-SSATS): 2019, Data on substance abuse treatment facilities. Retrieved from https://wwwdasis.samhsa.gov/dasis2/nssats/NSSATS_2019/2019-NSSATS-R.pdf
241 Benshoff, J. J., Harrawood, L. K., & Koch, D. S. (2003). Substance abuse and the elderly: Unique issues and concerns. Journal of Rehabilitation, 69(2), 43–48.
242 Babatunde, O. T., Outlaw, K. R., Forbes, B., & Gay, T. (2014). Revisiting baby boomers and alcohol use: Emerging treatment trends. Journal of Human Behavior in the Social Environment, 24(5), 597–611.
243 National Evaluation Data Services. (2002). Substance abuse among aging adults: A literature review. Rockville, MD: Center for Substance Abuse Treatment. Retrieved from www.readkong.com/page/substance-abuse-among-aging-adults-a-literature-review-5220038
244 Rothrauff, T. C., Abraham, A. J., Bride, B. E., & Roman, P. M. (2011). Substance abuse treatment for older adults in private centers. Substance Abuse, 32(1), 7–15.21302179
245 Rothrauff, T. C., Abraham, A. J., Bride, B. E., & Roman, P. M. (2011). Substance abuse treatment for older adults in private centers. Substance Abuse, 32(1), 7–15.21302179
246 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14–4849. Rockville, MD: Substance Abuse and Mental Health Services Administration.
247 American Psychological Association, Committee on Aging. (2009). Multicultural competency in geropsychology. Washington, DC: American Psychological Association. Retrieved from www.apa.org/pi/aging/programs/pipeline/multicultural-competency.pdf
248 American Psychological Association, Committee on Aging. (2009). Multicultural competency in geropsychology. Washington, DC: American Psychological Association. Retrieved from www.apa.org/pi/aging/programs/pipeline/multicultural-competency.pdf
249 American Psychological Association, Committee on Aging. (2009). Multicultural competency in geropsychology. Washington, DC: American Psychological Association. Retrieved from www.apa.org/pi/aging/programs/pipeline/multicultural-competency.pdf
250 American Psychological Association, Committee on Aging. (2009). Multicultural competency in geropsychology. Washington, DC: American Psychological Association. Retrieved from www.apa.org/pi/aging/programs/pipeline/multicultural-competency.pdf
251 Shutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2014). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. Rao, & P. Crome (Eds.), Substance use and older people. West Sussex, UK: Wiley-Blackwell.
252 Shutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2014). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. Rao, & P. Crome (Eds.), Substance use and older people. West Sussex, UK: Wiley-Blackwell.
253 American Psychological Association, Committee on Aging. (2009). Multicultural competency in geropsychology. Washington, DC: American Psychological Association. Retrieved from www.apa.org/pi/aging/programs/pipeline/multicultural-competency.pdf
254 Fung, H. H. (2013). Aging in culture. Gerontologist, 53(3), 369–377.23585454
255 Fung, H. H. (2013). Aging in culture. Gerontologist, 53(3), 369–377.23585454
256 Babatunde, O. T., Outlaw, K. R., Forbes, B., & Gay, T. (2014). Revisiting baby boomers and alcohol use: Emerging treatment trends. Journal of Human Behavior in the Social Environment, 24(5), 597–611.
257 Sahker, E., Schultz, S. K., & Arndt, S. (2015). Treatment of substance use disorders in older adults: Implications for care delivery. Journal of the American Geriatrics Society, 63(11), 2317–2323.26502741
258 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
259 Barry, K. L. & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
260 Kuerbis, A. N., Yuan, S. E., Borok, J., LeFevre, P. M., Kim, G. S., Lum, D. … Moore, A. A. (2015). Testing the initial efficacy of a mailed screening and brief feedback intervention to reduce at-risk drinking in middle-aged and older adults: The Comorbidity Alcohol Risk Evaluation Study. Journal of the American Geriatrics Society, 63(2), 321–326.25643851
261 Schonfeld, L., Hazlett, R. W., Hedgecock, D. K., Duchene, D. M., Burns, L. V., & Gum, A. M. (2015). Screening, brief intervention, and referral to treatment for older adults with substance misuse. American Journal of Public Health, 705(1), 205–211. doi:10.2105/AJPH.2013.301859
262 Lin, J. C., Karno, M. P., Barry, K. L., Blow, F. C., Davis, J. W., Tang, L., & Moore, A. A. (2010). Determinants of early reductions in drinking in older at-risk drinkers participating in the intervention arm of a trial to reduce at-risk drinking in primary care. Journal of the American Geriatrics Society, 58(2), 227–233.20070414
263 Gordon, A. J., Conigliaro, J., Maisto, S. Α., McNeil, M., Kraemer, K. L. & Kelley, Μ. E. (2003). Comparison of consumption effects of brief interventions for hazardous drinking elderly. Substance Use and Misuse, 38(8), 1017–1035.12901447
264 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
265 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
266 Schonfeld, L., King-Kallimanis, B. L., Duchene, D. M., Etheridge, R. L., Herrera, J. R., Barry, K. L., & Lynn, N. (2010). Screening and brief intervention for substance misuse among older adults: The Florida BRITE Project. American Journal of Public Health, 700(1), 108–114.
267 American Geriatrics Society Consensus Panel on Person-Centered Care. (2016). Person-centered care: A definition and essential elements. Journal of the American Geriatrics Society, 64(1), 15–18.26626262
268 American Geriatrics Society Consensus Panel on Person-Centered Care. (2016). Person-centered care: A definition and essential elements. Journal of the American Geriatrics Society, 64(1), 15–18.26626262
269 Schutte, Κ., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
270 Kuerbis, Α., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
271 Horvath, A. O., Del Re, Α., Flückiger, C., & Symonds, D. (2011). Alliance in individual psychotherapy. In J. C. Norcross (Ed.), Psychotherapy relationships that work (2nd ed.). New York, NY: Oxford University Press.
272 Horvath, A. O., Del Re, Α., Flückiger, C., & Symonds, D. (2011). Alliance in individual psychotherapy. In J. C. Norcross (Ed.), Psychotherapy relationships that work (2nd ed.). New York, NY: Oxford University Press.
273 Kuerbis, Α., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
274 Kuerbis, Α., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
275 Kuerbis, Α., Sacco, P., Blazer, D. G. & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
276 Kuerbis, Α., Sacco, P., Blazer, D. G. & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
277 Satre, D. D., Chi, F. W., Mertens, J. R., & Weisner, C. M. (2012). Effects of age and life transitions on alcohol and drug treatment outcome over nine years. Journal of Studies on Alcohol and Drugs, 73(3), 459–468.22456251
278 Nicholson, N. R. (2012). A review of social isolation: An important but underassessed condition in older adults. Journal of Primary Prevention, 33(2–3), 137–152.22766606
279 Mannes, Ζ. L., Burreil, L. E., Bryant, V. E., Dunne, Ε. M., Hearn, L. E., & Whitehead, N. E. (2016). Loneliness and substance use: The influence of gender among HIV+ Black/African American adults 50+. AIDS Care, 28(5), 598–602.26654243
280 Kuerbis, Α., Sacco, P., Blazer, D. G., & Moore, Α. Α. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
281 McCrady, B. S. (2006). Family and other close relationships. In W. R. Miller & Κ. M. Carroll (Eds.), Rethinking substance abuse: What the science shows, and what we should do about it (pp. 166–181). New York, NY: Guilford Press.
282 National Academies of Sciences, Engineering, and Medicine. (2016). Families caring for an aging America. Washington, DC: National Academies Press.
283 National Academies of Sciences, Engineering, and Medicine. (2016). Families caring for an aging America. Washington, DC: National Academies Press.
284 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
285 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14–4849. Rockville, MD: Substance Abuse and Mental Health Services Administration.
286 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14–4849. Rockville, MD: Substance Abuse and Mental Health Services Administration.
287 Institute of Medicine. (2012). The mental health and substance use workforce for older adults: In whose hands? Washington, DC: National Academies Press.
288 Kuerbis, A., Sacco, P., Blazer, D., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30, 629–654.25037298
289 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. Washington, DC: Department of Health and Human Services.
290 Schulte, M. T., & Hser, Y. I. (2014). Substance use and associated health conditions throughout the lifespan. Public Health Reviews, 35(2), ii.
291 Institute of Medicine. (2012). The mental health and substance use workforce for older adults: In whose hands? Washington, DC: National Academies Press.
292 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
293 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
294 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
295 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
296 Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/healthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
297 Family Caregiver Alliance. (2019, April 17). Caregiver statistics: Demographics. Retrieved from www.caregiver.org/caregiver-statistics-demographics
298 Drugs.com. (2018). What are drug interactions? Retrieved August 27, 2018, from www.drugs.com/druginteractions.html
299 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
300 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
301 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
302 Centers for Disease Control and Prevention. (2018). Alcohol and Public Health. Frequently Asked Questions. Retrieved from www.cdc.gov/alcohol/faqs.htm
303 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
304 World Health Organization. (2018). Management of substance abuse: Psychoactive substances. Retrieved August 27, 2018, from www.who.int/substanceabuse/terminology/psychoactivesubstances/en/
305 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
306 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
307 Alpert, P. T. (2014). Alcohol abuse in older adults: An invisible population. Home Health Care Management and Practice, 26(4), 269–272.
308 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30, 629–654.25037298
309 Choi, N. G., DiNitto, D. M., & Marti, C. N. (2014). Treatment use, perceived need, and barriers to seeking treatment for substance abuse and mental health problems among older adults compared to younger adults. Drug and Alcohol Dependence, 145, 113–120.25456572
310 Kuerbis, A., Sacco, P., Blazer, D., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30, 629–654.25037298
311 Pace, C. A., & Uebelacker, L. A. (2018). Addressing unhealthy substance use in primary care. Medical Clinics of North America, 102(4), 567–586.29933816
312 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
313 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
314 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
315 West, N. A., Severtson, S. G., Green, J. L., & Dart, R. C. (2015). Trends in abuse and misuse of prescription opioids among older adults. Drug and Alcohol Dependence, 149, 117–121.25678441
316 Choi, N. G., DiNitto, D. M., & Marti, C. N. (2015). Treatment use, perceived need, and barriers to seeking treatment for substance abuse and mental health problems among older adults compared to younger adults. Drug and Alcohol Dependence, 145, 113–120.
317 Kuerbis, A., Hagman, B. T., & Sacco, P. (2013). Functioning of alcohol use disorders criteria among middle-aged and older adults: Implications for DSM-5. Substance Use and Misuse, 48(4), 309–322.23373632
318 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. Washington, DC: Department of Health and Human Services.
319 2019 American Geriatrics Society Beers Criteria® Update Expert Panel. (2019). Updated AGS Beers Criteria® for potentially inappropriate medication use in older adults. Journal of the American Geriatrics Society, 67(4), 674–694.30693946
320 Tansil, K. A., Esser, M. B., Sandhu, P., Reynolds, J. A., Elder, R. W., Williamson, R. S., … Fielding, J. E. (2016). Alcohol electronic screening and brief intervention: A community guide systematic review. American Journal of Prevention Medicine, 51(5), 801–811.
321 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
322 Centers for Disease Control and Prevention. (2018). Alcohol and Public Health. Frequently Asked Questions. Retrieved from www.cdc.gov/alcohol/faqs.htm
323 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
324 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
325 U.S. Preventive Services Task Force. (2018). Final recommendation statement: Unhealthy alcohol use in adolescents and adults: Screening and behavioral counseling interventions. Retrieved from www.uspreventiveservicestaskforce.org/Page/Document/RecommendationStatementFinal/unhealthy-alcohol-use-in-adolescents-and-adults-screening-and-behavioral-counseling-interventions
326 U.S. Prevention Services Task Force. (2018). Screening and behavioral counseling interventions to reduce unhealthy alcohol use in adolescents and adults: Recommendation statement. JAMA, 320(18), 1899–1909.30422199
327 U.S. Preventive Services Task Force. (2018). Final recommendation statement: Unhealthy alcohol use in adolescents and adults: Screening and behavioral counseling interventions. Retrieved from www.uspreventiveservicestaskforce.org/Page/Document/RecommendationStatementFinal/unhealthy-alcohol-use-in-adolescents-and-adults-screening-and-behavioral-counseling-interventions
328 Aalto, M., Alho, H., Halm, J., & Seppä, K. (2011). The Alcohol Use Disorders Identification Test (AUDIT) and its derivatives in screening for heavy drinking among the elderly. International Journal of Geriatric Psychiatry, 26, 881–885.20661878
329 Selin, K. H. (2003). Test-retest reliability of the Alcohol Use Disorder Identification Test in a general population sample. Alcoholism, Clinical and Experimental Research, 27(9), 1428–1435.14506403
330 Purcell, B., & Olmstead, M. C. (2014). The performance and feasibility of three brief alcohol screening tools in a senior population. Canadian Psychology, 55(2a), 19.
331 Purcell, B., Flower, M. C., & Busto, U. (2017). Senior Alcohol Misuse Indicator (SAMI) tool. Centre for Addiction and Mental Health. Retrieved June 19, 2019, from www.porticonetwork.ca/documents/21686/0/SAMI+fillable/f6668443-559f-4ad8-9e5f-6de47a38e70a
332 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
333 Adamson, S. J., Kay-Lambkin, F. J., Baker, A. L., Lewin, T. J., Thornton, L., … Sellman, J. D. (2010). An improved brief measure of cannabis misuse: The Cannabis Use Disorders Identification Test-Revised (CUDIT-R). Drug and Alcohol Dependence, 110, 137–143.20347232
334 Adamson, S. J., Kay-Lambkin, F. J., Baker, A. L., Lewin, T. J., Thornton, L., … Sellman, J. D. (2010). An improved brief measure of cannabis misuse: The Cannabis Use Disorders Identification Test-Revised (CUDIT-R). Drug and Alcohol Dependence, 110, 137–143.20347232
335 McNeely, J., Strauss, S. M., Rotrosen, J., Ramautar, A., & Gourevitch, M. N. (2016). Validation of an audio computer-assisted self-interview (ACASI) version of the Alcohol, Smoking and Substance Involvement Screening Test (ASSIST) in primary care clients. Addiction, 111(2), 233–244.26360315
336 Gryczynski, J., Kelly, S. M., Mitchell, S. G., Kirk, A., O'Grady, K. E., & Schwartz, R. P. (2015). Validation and performance of the Alcohol, Smoking and Substance Involvement Screening Test (ASSIST) among adolescent primary care patients. Addiction, 110(2), 240–247.25311148
337 Ali, R., Meena, S., Eastwood, B., Richards, I., & Marsden, J. (2013). Ultra-rapid screening for substance use disorders: The Alcohol, Smoking and Substance Involvement Screening Test (ASSIST-Lite). Drug and Alcohol Dependence, 132, 352–361.23561823
338 Cacciola, J. S., Alterman, A. I., Dephilippis, D., Drapkin, M. L., Valadez, C., Jr., Fala, N. C., … McKay, J. R. (2013). Development and initial evaluation of the Brief Addiction Monitor (BAM). Journal of Substance Abuse Treatment, 44(3), 256–263.22898042
339 Cacciola, J. S., Alterman, A. I., Dephilippis, D., Drapkin, M. L., Valadez, C., Jr., Fala, N. C., … McKay, J. R. (2013). Development and initial evaluation of the Brief Addiction Monitor (BAM). Journal of Substance Abuse Treatment, 44(3), 256–263.22898042
340 Brown, R. L., & Rounds, L. A. (1995). Conjoint screening questionnaires for alcohol and other drug abuse: Criterion validity in a primary care practice. Wisconsin Medical Journal, 94(3), 135–140.7778330
341 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
342 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
343 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
344 Searby, A., Maude, P., & McGrath, I. (2015). Dual diagnosis in older adults: A review. Issues in Mental Health Nursing, 36(2), 104–111.25625710
345 Hendrie, H. C., Lindgren, D., Hay, D. P., Lane, K. A., Gao, S., Purnell, C., … Callahan, C. M. (2013). Comorbidity profile and healthcare utilization in elderly patients with serious mental illnesses. American Journal of Geriatric Psychiatry, 21(12), 1267–1276.
346 Lane, S. D., Costa, S. C., Teixiera, A. L., Reynolds, C. F., & Diniz, B. S. (2018). The impact of substance use disorders on clinical outcomes in older-adult psychiatric inpatients. International Journal of Geriatric Psychiatry, 33(2), 323–329.
347 Searby, A., Maude, P., & McGrath, I. (2015). Dual diagnosis in older adults: A review. Issues in Mental Health Nursing, 36(2), 104–111.25625710
348 Sacco, P., Unick, G. J., Zanjani, F., & Camlin, E. A. S. (2015). Hospital outcomes in major depression among older adults: Differences by alcohol comorbidity. Journal of Dual Diagnosis, 11(1), 83–92.25671685
349 Cleary, M., Sayers, J., Bramble, M., Jackson, D., & Lopez, V. (2017). Overview of substance use and mental health among the “baby boomers” generation. Issues in Mental Health Nursing, 38(1), 61–65.27936334
350 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2015). Associations of mental health and substance use disorders with presenting problems and outcomes in older adults' emergency department visits. Academic Emergency Medicine, 22(11), 1316–1326.26473592
351 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2015). Associations of mental health and substance use disorders with presenting problems and outcomes in older adults' emergency department visits. Academic Emergency Medicine, 22(11), 1316–1326.26473592
352 Bartels, S. J., Blow, F. C., Van Citters, A. D., & Brockmann, L. M. (2006). Dual diagnosis among older adults: Co-occurring substance abuse and psychiatric illness. Journal of Dual Diagnosis, 2(3), 9–30.
353 Moore, A. A., Beck, J. C., Barbor, T. F., Hays, R. D., & Reuben, D. B. (2002). Beyond alcoholism: Identifying older, at-risk drinkers in primary care. Journal of Studies on Alcohol, 63, 316–324.12086132
354 Ettner, S. L., Xu, H., Duru, O. K., Ang, A., Tseng, C. H., Tallen L., … Moore A. A. (2014). The effect of an educational intervention on alcohol consumption, at-risk drinking, and health care utilization in older adults: The Project SHARE study. Journal of Studies on Alcohol and Drugs, 75(3), 447–457.24766757
355 Barnes, A. J., Moore, A. A., Xu, H., Ang, A., Tallen, L., Mirkin, M., & Ettner, S. L. (2010). Prevalence and correlates of at-risk drinking among older adults: The Project SHARE study. Journal of General Internal Medicine, 25(8), 840–846.20396975
356 Barnes, A. J., Moore, A. A., Xu, H., Ang, A., Tallen, L., Mirkin, M., & Ettner, S. L. (2010). Prevalence and correlates of at-risk drinking among older adults: The Project SHARE study. Journal of General Internal Medicine, 25(8), 840–846.20396975
357 Searby, A., Maude, P., & McGrath, I. (2015). Dual diagnosis in older adults: A review. Issues in Mental Health Nursing, 36(2), 104–111.25625710
358 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
359 Searby, A., Maude, P., & McGrath, I. (2015). Dual diagnosis in older adults: A review. Issues in Mental Health Nursing, 36(2), 104–111.25625710
360 Wu, L. T., & Blazer, D. G. (2014). Substance use disorders and psychiatric comorbidity in mid and later life: A review. International Journal of Epidemiology, 43(2), 304–317.24163278
361 Yesavage, J. A. (n.d.). Geriatric Depression Scale. Retrieved from https://web.stanford.edu/~yesavage/GDS.html
362 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 41(11), 15–21.
363 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 41(11), 15–21.
364 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 41(11), 15–21.
365 Yesavage, J. A. (n.d.). Geriatric Depression Scale. Retrieved from https://web.stanford.edu/~yesavage/GDS.html
366 U.S. Preventive Services Task Force. (2019). Final recommendation statement: Depression in adults: Screening. Retrieved from www.uspreventiveservicestaskforce.org/Page/Document/RecommendationStatementFinal/depression-in-adults-screening1
367 Phelan, E., Williams, B., Meeker, K., Bonn, K., Frederick, J., Logerfo, J., & Snowden, M. (2010). A study of the diagnostic accuracy of the PHQ-9 in primary care elderly. BMC Family Practice, 11, 63.20807445
368 Richardson, T. M., He, H., Podgorski, C., Tu, X., & Conwell, Y. (2010). Screening for depression in aging services clients. American Journal of Geriatric Psychiatry, 18(12), 1116–1123.
369 Richardson, T. M., He, H., Podgorski, C., Tu, X., & Conwell, Y. (2010). Screening for depression in aging services clients. American Journal of Geriatric Psychiatry, 18(12), 1116–1123.
370 Kroenke, K., Spitzer, R. L., & Williams, J. B. (2001). The PHQ-9: Validity of a brief depression severity measure. Journal of General Internal Medicine, 16(9), 606–613.11556941
371 Kroene, K., & Spitzer, R. L. (2002). The PHQ-9: A new depression diagnostic and severity measure. Psychiatric Annals, 32, 509–521.
372 Richardson, T. M., He, H., Podgorski, C., Tu, X., & Conwell, Y. (2010). Screening for depression in aging services clients. American Journal of Geriatric Psychiatry, 18(12), 1116–1123.
373 Bower, E. S., Wetherell, J. L., Mon, T., & Lenze, E. J. (2015). Treating anxiety disorders in older adults: Current treatments and future directions. Harvard Review of Psychiatry, 23(5), 329–342.26332216
374 Reynolds, K., Pietrzak, R. H., El-Gabalawy, R., Mackenzie, C. S., & Sareen, J. (2015). Prevalence of psychiatric disorders in U.S. older adults: Findings from a nationally representative survey. World Psychiatry, 14(1), 74–81.25655161
375 Bower, E. S., Wetherell, J. L., Mon, T., & Lenze, E. J. (2015). Treating anxiety disorders in older adults: Current treatments and future directions. Harvard Review of Psychiatry, 23(5), 329–342.26332216
376 Reynolds, K., Pietrzak, R. H., El-Gabalawy, R., Mackenzie, C. S., & Sareen, J. (2015). Prevalence of psychiatric disorders in U.S. older adults: Findings from a nationally representative survey. World Psychiatry, 14(1), 74–81.25655161
377 Koychev, I., & Ebmeier, K. P. (2016). Anxiety in older adults often goes undiagnosed. Practitioner, 260(1789), 17–20, 2–3.
378 Wolitzky-Taylor, K. B., Castriotta, N., Lenze, E. J., Stanley, M. A., & Craske, M. G. (2010). Anxiety disorders in older adults: A comprehensive review. Depression and Anxiety, 27(2), 190–211.20099273
379 Koychev, I., & Ebmeier, K. P. (2016). Anxiety in older adults often goes undiagnosed. Practitioner, 260(1789), 17–20, 2–3.
380 Bower, E. S., Wetherell, J. L., Mon, T., & Lenze, E. J. (2015). Treating anxiety disorders in older adults: Current treatments and future directions. Harvard Review of Psychiatry, 23(5), 329–342.26332216
381 Kessler, R. C., Petukhova, M., Sampson, N. A., Zaslavsky, A. M., & Wittchen, H.-U. (2012). Twelve-month and lifetime prevalence and lifetime morbid risk of anxiety and mood disorders in the United States. International Journal of Methods in Psychiatric Research, 21(3), 169–184.22865617
382 Kessler, R. C., Petukhova, M., Sampson, N. A., Zaslavsky, A. M., & Wittchen, H.-U. (2012). Twelve-month and lifetime prevalence and lifetime morbid risk of anxiety and mood disorders in the United States. International Journal of Methods in Psychiatric Research, 21(3), 169–184.22865617
383 Reynolds, K., Pietrzak, R. H., Mackenzie, C. S., Chou, K. L., Sareen, J. (2016). Post-traumatic stress disorder across the adult lifespan: Findings from a nationally representative survey. American Journal of Geriatric Psychiatry, 24(1), 81–93.
384 Bryant, C., Jackson, H., & Ames, D. (2008). The prevalence of anxiety in older adults: Methodological issues and a review of the literature. Journal of Affective Disorders, 109(3), 233–250.18155775
385 Lin, J. C., Karno, M. P., Grella, C. E., Ray, L. A., Liao, D. H., & Moore, A. A. (2014). Psychiatric correlates of alcohol and tobacco use disorders in U.S. adults aged 65 years and older: Results from the 2001–2002 National Epidemiologic Survey of Alcohol and Related Conditions. American Journal of Geriatric Psychiatry, 22(11), 1356–1363.
386 Lin, J. C., Karno, M. P., Grella, C. E., Ray, L. A., Liao, D. H., & Moore, A. A. (2014). Psychiatric correlates of alcohol and tobacco use disorders in U.S. adults aged 65 years and older: Results from the 2001–2002 National Epidemiologic Survey of Alcohol and Related Conditions. American Journal of Geriatric Psychiatry, 22(11), 1356–1363.
387 Christie, M. M., Bamber, D., Powell, C., Arrindell, T., & Pant, A. (2013). Older adult problem drinkers: Who presents for alcohol treatment? Aging and Mental Health, 17(1), 24–32.22757629
388 Mackenzie, C. S., Reynolds, K., Chou, K. L., Pagura, J., & Sareen, J. (2011). Prevalence and correlates of generalized anxiety disorder in a national sample of older adults. American Journal of Geriatric Psychiatry, 19(4), 305–315.
389 Blazer, D. G., & Wu, L. T. (2012). Patterns of tobacco use and tobacco-related psychiatric morbidity and substance use among middle-aged and older adults in the United States. Aging and Mental Health, 16(3), 296–304.22292514
390 Therrien, Z., & Hunsley, J. (2012). Assessment of anxiety in older adults: A systematic review of commonly used measures. Aging and Mental Health, 16(1), 1–16.21838650
391 Gould, C. E., Segal, D. L., Yochim, B. P., Pachana, N. A., Byrne, G. J., & Beaudreau, S. A. (2014). Measuring anxiety in late life: A psychometric examination of the Geriatric Anxiety Inventory and Geriatric Anxiety Scale. Journal of Anxiety Disorder, 28(8), 804–811.
392 Mueller, A. E., Segal, D. L., Gavett, B., Marty, M. A., Yochim, B., June, A., & Coolidge, F. L. (2015). Geriatric Anxiety Scale: Item response theory analysis, differential item functioning, and creation of a ten-item short form (GAS-10). International Psychogeriatrics, 27(7), 1099–1111.24576589
393 Balsamo, M., Cataldi, F., Carlucci, L., & Fairfield, B. (2018). Assessment of anxiety in older adults: A review of self-report measures. Clinical Interventions in Aging, 13, 573–593.29670342
394 Segal, D. L., June, A., Payne, M., Coolidge, F. L., & Yochim, B. (2010). Development and initial validation of a self-report assessment tool for anxiety among older adults: The Geriatric Anxiety Scale. Journal of Anxiety Disorders, 24, 709–714.20558032
395 Meyer, T., Miller, M., Metzger, R., & Borkovec, T. D. (1990). Development and validation of the Penn State Worry Scale. Behaviour Research and Therapy, 28, 487–495.2076086
396 Therrien, Z., & Hunsley, J. (2012). Assessment of anxiety in older adults: A systematic review of commonly used measures. Aging and Mental Health, 16(1), 1–16.21838650
397 Flanagan, J. C., Korte, K. J., Killeen, T. K., & Back, S. E. (2016). Concurrent treatment of substance use and PTSD. Current Psychiatry Reports, 18(8), 70.27278509
398 Forman-Hoffman, V. L., Bose, J., Batts, K. R., Glasheen, C., Hirsch, E., Karg, R. S., … Hedden, S. L. (2016). Correlates of lifetime exposure to one or more potentially traumatic events and subsequent posttraumatic stress among adults in the United States: Results from the Mental Health Surveillance Study, 2008–2012. CBHSQ Data Review. Rockville, MD: Substance Abuse and Mental Health Services Administration.
399 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2017). Association of adverse childhood experiences with lifetime mental and substance use disorders among men and women aged 50+ years. International Psychogeriatrics, 29(3), 359–372.27780491
400 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2017). Association of adverse childhood experiences with lifetime mental and substance use disorders among men and women aged 50+ years. International Psychogeriatrics, 29(3), 359–372.27780491
401 Kessler, R. C., Petukhova, M., Sampson, N. A., Zaslavsky, A. M., & Wittchen, H.-U. (2012). Twelve-month and lifetime prevalence and lifetime morbid risk of anxiety and mood disorders in the United States. International Journal of Methods in Psychiatric Research, 21(3), 169–184.22865617
402 Reynolds, K., Pietrzak, R. H., Mackenzie, C. S., Chou, K. L., & Sareen, J. (2016). Post-traumatic stress disorder across the adult lifespan: Findings from a nationally representative survey. American Journal of Geriatric Psychiatry, 24(1), 81–93.
403 Cukor, J., Wyka, K., Jayasinghe, N., & Difede, J. (2010). The nature and course of subthreshold PTSD. Journal of Anxiety Disorder, 24(8), 918–923.
404 Centers for Disease Control and Prevention. (2017). Elder abuse prevention. Retrieved April 9, 2019, from www.cdc.gov/features/elderabuse/index.html
405 Hall, J. E., Karch, D. L., & Crosby, A. E. (2016). Elder abuse surveillance: Uniform definitions and recommended core data elements for use In elder abuse surveillance, version 1.0. Atlanta, GA: National Center for Injury Prevention and Control, Centers for Disease Control and Prevention. Retrieved from www.cdc.gov/violenceprevention/pdf/ea_book_revised_2016.pdf
406 Knight, L., & Hester, M. (2016). Domestic violence and mental health in older adults. International Review of Psychiatry, 28(5), 464–474.27564268
407 Dong, X. Q. (2015). Elder abuse: Systematic review and implications for practice. Journal of the American Geriatrics Society, 63(6), 1214–1238.26096395
408 Dong, X. Q. (2015). Elder abuse: Systematic review and implications for practice. Journal of the American Geriatrics Society, 63(6), 1214–1238.26096395
409 Acierno, R., Hernandez-Tejada, M. A., Anetzberger, G. J., Loew, D., & Muzzy, W. (2017). The National Elder Mistreatment Study: An 8-year longitudinal study of outcomes. Journal of Elder Abuse and Neglect, 29, 254–269.28837418
410 Dong, X. Q. (2015). Elder abuse: Systematic review and implications for practice. Journal of the American Geriatrics Society, 63(6), 1214–1238.26096395
411 Pless Kaiser, A., Cook, J. M., Glick, D. M., & Moye, J. (2019). Posttraumatic stress disorder in older adults: A conceptual review. Clinical Gerontologist, 42(4), 359–376.30422749
412 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13–4801. Rockville, MD: Substance Abuse and Mental Health Services Administration.
413 Tsai, J., Armour, C., Southwick, S. M., & Pietrzak, R. H. (2015). Dissociative subtype of DSM-5 posttraumatic stress disorder in U.S. veterans. Journal of Psychiatric Research, 66, 67–74.25969340
414 Ho, C. L., Schlenger, W. E., Kulka, R. A., & Marmar, C. R. (2017). The influence of different criteria for establishing optimal cutoff scores on performance of two self-report measures for warzone PTSD. Psychological Assessment, 29(2), 232–237.27183044
415 Shrira, A. (2016). A youthful age identity mitigates the effect of post-traumatic stress disorder symptoms on successful aging. American Journal of Geriatric Psychiatry, 24(2), 174–175.
416 Ho, C. L., Schlenger, W. E., Kulka, R. A., & Marmar, C. R. (2017). The influence of different criteria for establishing optimal cutoff scores on performance of two self-report measures for warzone PTSD. Psychological Assessment, 29(2) 232–237.27183044
417 Weathers, F. W., Litz, B. T., Keane, T. M., Palmieri, P. A., Marx, B. P., & Schnurr, P. P. (2013). PTSD Checklist for DSM-5 (PCL-5). Retrieved from www.ptsd.va.gov/professional/assessment/adult-sr/ptsd-checklist.asp
418 Weathers, F. W., Litz, B. T., Keane, T. M., Palmieri, P. A., Marx, B. P., & Schnurr, P. P. (2013). The PTSD Checklist for DSM-5 (PCL-5). Scale available from the National Center for PTSD at www.ptsd.va.gov/professional/assessment/adult-sr/ptsd-checklist.asp
419 Prins, A., Bovin, M. J., Smolenski, D. J., Marx, B. P., Kimerling, R., Jenkins-Guarnieri, M. A., … Tiet, Q. Q. (2016). The Primary Care PTSD Screen for DSM-5 (PC-PTSD-5): Development and evaluation within a veteran primary care sample. Journal of General Internal Medicine, 31(10), 1206–1211.27170304
420 Prins, A., Bovin, M. J., Smolenski, D. J., Marx, B. P., Kimerling, R., Jenkins-Guarnieri, M. A., … Tiet, Q. Q. (2016). The Primary Care PTSD Screen for DSM-5 (PC-PTSD-5): Development and evaluation within a veteran primary care sample. Journal of General Internal Medicine, 31(10), 1206–1211.27170304
421 Prins, A., Bovin, M. J., Smolenski, D. J., Marx, B. P., Kimerling, R., Jenkins-Guarnieri, M. A., … Tiet, Q. Q. (2016). The Primary Care PTSD Screen for DSM-5 (PC-PTSD-5): Development and evaluation within a veteran primary care sample. Journal of General Internal Medicine, 31(10), 1206–1211.27170304
422 Yaffe, M. J., & Tazkarji, B. (2012). Understanding elder abuse in family practice. Canadian Family Physician, 58(12), 1336–1340.23242889
423 Langa, Κ. M., Larson, E. Β., Crimmins, E. M., Faul, J. D., Levine, D. Α., Kabeto, M. U. & Weir, D. R. (2017). A comparison of the prevalence of dementia in the United States in 2000 and 2012. JAMA Internal Medicine, 777(1), 51–58.
424 Langa, Κ. M., Larson, E. Β., Crimmins, Ε. M., Faul, J. D., Levine, D. Α., Kabeto, M. U. & Weir, D. R. (2017). A comparison of the prevalence of dementia in the United States in 2000 and 2012. JAMA Internal Medicine, 777(1), 51–58.
425 Petersen, R. C. (2011). Clinical practice: Mild cognitive impairment. New England Journal of Medicine, 364(23), 2227–2234.21651394
426 Petersen, R. C. (2016). Mild cognitive impairment. Continuum (Minneapolis, Minnesota), 22(2 Dementia), 404–408.
427 Petersen, R. C., Caracciolo, B., Brayne, C., Gauthier, S., Jelic, V., & Fratiglioni, L. (2014). Mild cognitive impairment: A concept in evolution. Journal of Internai Medicine, 275(3), 214–228.
428 González-Reimers, E., Santolaria-Fernández, F., Martín-González, M. C., Fernández-Rodríguez, C. M., & Quintero-Platt, G. (2014). Alcoholism: A systemic proinflammatory condition. World Journal of Gastroenterology, 20(40), 14660–14671.25356029
429 Björk, J. M., & Gilman, J. M. (2014). The effects of acute alcohol administration on the human brain: Insights from neuroimaging. Neuropharmacology, 84, 101–110.23978384
430 Downer, B., Zanjani, F., & Fardo, D. W. (2014). The relationship between midlife and late life alcohol consumption, APOE e4 and the decline in learning and memory among older adults. Alcohol and Alcoholism, 49(1), 17–22.24049153
431 Gongvatana, Α., Morgan, Ε. E., ludicello, J. E., Letendre, S. L., Grant, I., & Woods, S. P. (2014). A history of alcohol dependence augments HIV-associated neurocognitive deficits in persons aged 60 and older. Journal of Neurovirology, 20(5), 505–513.25201556
432 Kuzma, E., Llewellyn, D. J., Langa, Κ. M., Wallace, R. Β., & Lang, I. Α. (2014). History of alcohol use disorders and risk of severe cognitive impairment: A 19-year prospective cohort study. American Journal of Geriatric Psychiatry, 22(10), 1047–1054.
433 de la Monte, S. M. & Kril, J. J. (2014). Human alcohol-related neuropathology. Acta Neuropathologica, 727(1), 71–90.
434 Topiwala, Α., Allan, C. L., Valkanova, V., Zsoldos, E., Filippini, N., Sexton, C. … Ebmeier, K. P. (2017). Moderate alcohol consumption as risk factor for adverse brain outcomes and cognitive decline: Longitudinal cohort study. BMJ, 357, \2353.
435 Woods, A. J., Porges, E. C., Bryant, V. E., Seider, T., Gongvatana, Α., Kahler, C. W., … Cohen, R. A. (2016). Current heavy alcohol consumption is associated with greater cognitive impairment in older adults. Alcoholism, Clinical and Experimental Research, 40(11), 2435–2444.27658235
436 Zhong, G., Wang, Y., Zhang, Y. & Zhao, Y. (2015). Association between benzodiazepine use and dementia: A meta-analysis. PLoS One, 70(5), e0127836.
437 Billioti de Gage, S., Pariente, Α., & Bégaud, Β. (2015). Is there really a link between benzodiazepine use and the risk of dementia? Expert Opinion on Drug Safety, 74(5), 733–747.
438 Puustinen, J., Lähteenmäki, R., Polo-Kantola, P., Salo, P., Vahlberg, T., Lyles, Α., … & Kivelä, S. L. (2014). Effect of withdrawal from long-term use of temazepam, zopiclone or Zolpidem as hypnotic agents on cognition in older adults. European Journal of Clinical Pharmacology, 70(3), 319–329.24337417
439 Curran, H. V., Freeman, T. P., Mokrysz, C., Lewis, D. Α., Morgan, C. J., & Parsons, L. H. (2016). Keep off the grass? Cannabis, cognition and addiction. National Reviews: Neuroscience, 77(5), 293–306.
440 Volkow, N. D., Swanson, J. M., Evins, A. E., DeLisi, L. E., Meier, M. H., Gonzalez, R. … & Baler R. (2016). Effects of cannabis use on human behavior, including cognition, motivation, and psychosis: A review. JAMA Psychiatry, 73(3), 292–297.26842658
441 Broyd, S. J., van Hell, H. H., Beale, C., Yücel, M., & Solowij, Ν. (2016). Acute and chronic effects of cannabinoids on human cognition: A systematic review. Biological Psychiatry, 79(7), 557–567.26858214
442 Mahoney, J. J. (2019). Cognitive dysfunction in individuals with cocaine use disorder: Potential moderating factors and pharmacological treatments. Experimental and Clinical Psychopharmacology, 27(3), 203–214.30556731
443 Zhong, G., Wang, Y., Zhang, Y., Guo, J. J., & Zhao, Y. (2015). Smoking is associated with an increased risk of dementia: A meta-analysis of prospective cohort studies with investigation of potential effect modifiers. PLoS One, 70(3), e0118333.
444 National Institute on Aging, (n.d.). Assessing cognitive impairment in older patients. Retrieved from www.nia.nih.gov/health/assessing-cognitive-impairment-older-patients#bunn
445 Alzheimer's Association, (n.d.). Cognitive assessment. Retrieved from www.alz.org/professionals/health-systems-clinicians/cognitive-assessment
446 Fage, B. A., Chan, C. C., Gill, S. S., Noel-Storr, A. H., Herrmann, N., Smailagic, N., … Seitz, D. P. (2015). Mini-Cog for the diagnosis of Alzheimer's disease dementia and other dementias within a community setting. Cochrane Database of Systematic Reviews, 2015(2), 1–33. doi:10.1002/14651858.CD010860.pub2.
447 Yokomizo, J. E., Simon, S. S., & Bottino, C. M. (2014). Cognitive screening for dementia in primary care: A systematic review. International Psychogeriatrics, 26(11), 1783–1804.25023857
448 Tsoi, K. K., Chan, J. Y., Hirai, H. W., Wong, S. Y., & Kwok, T. C. (2015). Cognitive tests to detect dementia: A systematic review and meta-analysis. JAMA Internal Medicine, 175(9), 1450–1458.26052687
449 Montreal Cognitive Assessment. (n.d.). FAQ. Retrieved from www.mocatest.org/faq
450 PAR. (n.d.). MMSE. Retrieved from www.parinc.com/Products/Pkey/237
451 Shapiro, B., Coffa, D., & McCance-Katz, E. F. (2013). A primary care approach to substance misuse. American Family Physician, 88(2), 113–121.23939642
452 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
453 Substance Abuse and Mental Health Services Administration. (1999). Brief interventions and brief therapies for substance abuse. Treatment Improvement Protocol (TIP) Series. 34. HHS Publication No. (SMA) 12–3952. Rockville, MD: Substance Abuse and Mental Health Services Administration.
454 Boucek, L., Kane, I., Lindsay, D. L., Hagle, H., Salvio, K., & Mitchell, A. M. (2019). Screening, brief intervention, and referral to treatment (SBIRT) education of residential care nursing staff: Impact on staff and residents. Geriatric Nursing, 40(6), 553–557.31036404
455 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
456 National Institute on Drug Abuse. (2014). Principles of drug abuse treatment for criminal justice populations: A research-based guide. Retrieved from www.drugabuse.gov/publications/principles-drug-abuse-treatment-criminal-justice-populations/legally-mandated-treatment-effective
457 Schonfeld, L., King-Kallimanis, B. L., Duchene, D. M., Etheridge, R. L., Herrera, J. R., Barry, K. L., & Lynn, N. (2010). Screening and brief intervention for substance misuse among older adults: The Florida BRITE project. American Journal of Public Health, 100(1), 108–114.19443821
458 Schonfeld, L., Hazlett, R. W., Hedgecock, D. K., Duchene, D. M., Burns, L. V., & Gum, A. M. (2015). Screening, brief intervention, and referral to treatment for older adults with substance misuse. American Journal of Public Health, 105(1), 205–211.24832147
459 Schonfeld, L., King-Kallimanis, B. L., Duchene, D. M., Etheridge, R. L., Herrera, J. R., Barry, K. L., & Lynn, N. (2010). Screening and brief intervention for substance misuse among older adults: The Florida BRITE project. American Journal of Public Health, 100(1), 108–114.19443821
460 Colrain, I. M., Nicholas, C. L., & Baker, F. C. (2014). Alcohol and the sleeping brain. Handbook of Clinical Neurology, 125, 415–431.25307588
461 Garcia, A. N., & Salloum, I. M. (2015). Polysomnographic sleep disturbances in nicotine, caffeine, alcohol, cocaine, opioid, and cannabis use: A focused review. American Journal on Addictions, 24(7), 590–598.26346395
462 Canham, S. L., Kaufmann, C. N., Mauro, P. M., Mojtabai, R., & Spira, A. P. (2015). Binge drinking and insomnia in middle-aged and older adults: The Health and Retirement Study. International Journal of Geriatric Psychiatry, 30(3), 284–291.24798772
463 Cohrs, S., Rodenbeck, A., Riemann, D., Szagun, B., Jaehne, A., Brinkmeyer, J., … Winterer, G. (2014). Impaired sleep quality and sleep duration in smokers— Results from the German Multicenter Study on Nicotine Dependence. Addiction Biology, 19(3), 486–496.22913370
464 Garcia, A. N., & Salloum, I. M. (2015). Polysomnographic sleep disturbances in nicotine, caffeine, alcohol, cocaine, opioid, and cannabis use: A focused review. American Journal on Addictions, 24(7), 590–598.26346395
465 Correa, D., Farney, R. J., Chung, F., Prasad, A., Lam, D., & Wong, J. (2015). Chronic opioid use and central sleep apnea: A review of the prevalence, mechanisms, and perioperative considerations. Anesthesia and Analgesia, 120(6), 1273–1285.25988636
466 Substance Abuse and Mental Health Services Administration. (2014). Treating sleep problems of people in recovery from substance use disorders. In Brief, 8(2). Retrieved from https://store.samhsa.gov/product/Treating-Sleep-Problems-of-People-in-Recovery-From-Substance-Use-Disorders/SMA14-4859
467 Wu, L., & Sun, D. (2017). Sleep duration and falls: A systemic review and meta-analysis of observational studies. Journal of Sleep Research, 26(3), 293–301.28220576
468 Stone, K. L., Blackwell, T. L., Ancoli-Israel, S., Cauley, J. A., Redline, S., Marshall, L. M., & Ensrud, K. E. (2014). Sleep disturbances and risk of falls in older community-dwelling men: The outcomes of Sleep Disorders in Older Men (MrOS Sleep) Study. Journal of the American Geriatrics Society, 62(2), 299–305.24428306
469 da Silva, A. A., de Mello, R. G. B., Schaan, C. W., Fuchs, F. D., Redline, S., & Fuchs, S. C. (2016). Sleep duration and mortality in the elderly: A systematic review with meta-analysis. BMJ Open, 6(2), e008119.
470 Saccomano, S. J. (2014). Sleep disorders in older adults. Journal of Gerontological Nursing, 40(3), 38–45.
471 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2017). Association between nonmedical marijuana and pain reliever uses among individuals aged 50+. Psychoactive Drugs, 49(4), 267–278.
472 Brennan, P. L., & Soohoo, S. (2013). Pain and use of alcohol in later life: Prospective evidence from the Health and Retirement Study. Journal of Aging and Health, 25(4), 656–677.23640817
473 Brennan, P. L., & Soohoo, S. (2013). Pain and use of alcohol in later life: Prospective evidence from the Health and Retirement Study. Journal of Aging and Health, 25(4), 656–677.23640817
474 Gilson, K. M., Bryant, C., & Judd, F. (2014). The hidden harms of using alcohol for pain relief in older adults. International Psychogeriatrics, 26(11), 1929–1930.25075722
475 Kang, Y., & Demiris, G. (2017). Self-report pain assessment tools for cognitively intact older adults: Integrative review. International Journal of Older People Nursing, 13(2), e12170.28980440
476 Schofield, P., & Abdulla, A. (2018). Pain assessment in the older population: What the literature says. Age and Ageing, 47(3), 324–327.29584807
477 Schofield, P., & Abdulla, A. (2018). Pain assessment in the older population: What the literature says. Age and Ageing, 47(3), 324–327.29584807
478 Horgas, A. L. (2017). Pain assessment in older adults. Nursing Clinics of North America, 52(3), 375–385.28779820
479 Horgas, A. L. (2017). Pain assessment in older adults. Nursing Clinics of North America, 52(3), 375–385.28779820
480 Booker, S. Q., & Herr, K. A. (2016). Assessment and measurement of pain in adults in later life. Clinics in Geriatric Medicine, 32(4), 677–692.27741963
481 Booker, S. Q., & Herr, K. A. (2016). Assessment and measurement of pain in adults in later life. Clinics in Geriatric Medicine, 32(4), 677–692.27741963
482 Booker, S. Q., & Herr, K. A. (2016). Assessment and measurement of pain in adults in later life. Clinics in Geriatric Medicine, 32(4), 677–692.27741963
483 Kang, Y., & Demiris, G. (2017). Self-report pain assessment tools for cognitively intact older adults: Integrative review. International Journal of Older People Nursing, 13(2), e12170.28980440
484 Kang, Y., & Demiris, G. (2017). Self-report pain assessment tools for cognitively intact older adults: Integrative review. International Journal of Older People Nursing, 13(2), e12170.28980440
485 Shega, J. W., Tiedt, A. D., Grant, K., & Dale, W. (2014). Pain measurement in the National Social Life, Health, and Aging Project: Presence, intensity, and location. Journals of Gerontology, Series B: Psychological Sciences and Social Sciences, 69(8), S191–S197.25360020
486 American Geriatrics Society Panel on the Pharmacological Management of Persistent Pain in Older Persons. (2009). Pharmacological management of persistent pain in older persons. Journal of the American Geriatrics Society, 57, 1331–1346.19573219
487 American Geriatrics Society Panel on the Pharmacological Management of Persistent Pain in Older Persons. (2009). Pharmacological management of persistent pain in older persons. Journal of the American Geriatrics Society, 57, 1331–1346.19573219
488 American Geriatrics Society Panel on the Pharmacological Management of Persistent Pain in Older Persons. (2009). Pharmacological management of persistent pain in older persons. Journal of the American Geriatrics Society, 57, 1331–1346.19573219
489 American Geriatrics Society Panel on the Pharmacological Management of Persistent Pain in Older Persons. (2009). Pharmacological Management of Persistent Pain in Older Persons. Journal of the American Geriatrics Society, 57, 1331–1346.19573219
490 Centers for Disease Control and Prevention, National Center for Health Statistics. (2020). Multiple cause of death data 1999–2018 on CDC WONDER [Data set]. Retrieved April 14, 2020, from https://wonder.cdc.gov/mcd.html
491 Centers for Disease Control and Prevention, National Center for Health Statistics. (2020). Multiple cause of death data 1999–2018 on CDC WONDER [Data set]. Retrieved April 14, 2020, from https://wonder.cdc.gov/mcd.html
492 McGuire, B. E., Nicholas, M. K., Asghari, A., Wood, B. M., & Main, C. J. (2014). The effectiveness of psychological treatments for chronic pain in older adults: Cautious optimism and an agenda for research. Current Opinion in Psychiatry, 27(5), 380–384.25010990
493 Reid, M. C., Ong, A. D., & Henderson, C. R. (2016). Why we need nonpharmacologic approaches to manage chronic low back pain in older adults. JAMA Internal Medicine, 176(3), 338–339. doi: 10.1001/jamainternmed.2015.8348.26902856
494 Davies, P. S. (2017). Opioids for pain management in older adults: Strategies for safe prescribing. Nurse Practitioner, 42(2), 20–26.
495 Dowell, D., Haegerich, T. M., & Chou, R. (2016). CDC guideline for prescribing opioids for chronic pain: United States, 2016. JAMA, 315(15), 1624–1645.26977696
496 Dowell, D., Haegerich, T. M., & Chou, R. (2016). CDC guideline for prescribing opioids for chronic pain: United States, 2016. JAMA, 315(15), 1624–1645.26977696
497 Ali, A., Arif, A. W., Bhan, C., Kumar, D., Malik, M. B., Sayyed, Z., … Ahmad, M. Q. (2018). Managing chronic pain in the elderly: An overview of the recent therapeutic advancements. Cureus, 10(9), e3293.30443463
498 Makris, U. E., Abrams, R. C., Gurland, B., & Reid, M. C. (2014). Management of persistent pain in the older patient: A clinical review. JAMA, 312(8), 825–836.25157726
499 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
500 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
501 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
502 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
503 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
504 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
505 Lai, H. M., Cleary, M., Sitharthan, T., & Hunt, G. E. (2015). Prevalence of comorbid substance use, anxiety and mood disorders in epidemiological surveys, 1990–2014: A systematic review and meta-analysis. Drug and Alcohol Dependence, 154, 1–13.26072219
506 Fink, D. S., Hu, R., Cerdá, M., Keyes, K. M., Marshall, B.D., Galea, S., & Martins, S. S. (2015). Patterns of major depression and nonmedical use of prescription opioids in the United States. Drug and Alcohol Dependence, 153, 258–264.26026492
507 Dworkin, E. R., Wanklyn, S., Stasiewicz, P. R., & Coffey, S. F. (2018). PTSD symptom presentation among people with alcohol and drug use disorders: Comparisons by substance of abuse. Addictive Behaviors, 76, 188–194.28846939
508 Pietrzak, R. H., Goldstein, R. B., Southwick, S. M., & Grant, B. F. (2011). Prevalence and Axis I comorbidity of full and partial posttraumatic stress disorder in the United States: Results from Wave 2 of the National Epidemiologic Survey on Alcohol and Related Conditions. Journal of Anxiety Disorders, 25(3), 456–465.21168991
509 Espinoza, R., & Kaufman, A. H. (2014). Diagnosis and treatment of late-life depression. Psychiatric Times, 31(10), 1–8.
510 Lagana, L. (2009). Pilot testing a new short screen for the assessment of older women's PTSD symptomatology. Educational Gerontology, 35(8), 732–751.25400322
511 Jeste, D. V., Peschin, S., Buckwalter, K., Blazer, D. G., McGuire, M., Moutier, C., … Reynolds, C. F. (2018). Promoting wellness in older adults with mental illnesses and substance use disorders: Call to action to all stakeholders. American Journal of Geriatric Psychiatry, 26(6), 617–630.
512 Soper, R. G. (2014, October 6). Intimate partner violence and co-occurring substance abuse/addiction. ASAM Magazine. Retrieved from www.asam.org/resources/publications/magazine/read/article/2014/10/06/intimate-partner-violence-and-co-occurring-substance-abuse-addiction
513 Lachs, M., & Pillemer, K. (2015). Elder abuse. New England Journal of Medicine, 373, 1947–1956.26559573
514 Stone, A. L., Becker, L. G., Huber, A. M., & Catalano, R. F. (2012). Review of risk and protective factors of substance use and problem use in emerging adulthood. Addictive Behaviors, 37(7), 747–775.22445418
515 Urbanoski, K. A., & Kelly, J. F. (2012). Understanding genetic risk for substance use and addiction: A guide for non-geneticists. Clinical Psychology Reviews, 32(1), 60–70.
516 Urbanoski, K. A., & Kelly, J. F. (2012). Understanding genetic risk for substance use and addiction: A guide for non-geneticists. Clinical Psychology Reviews, 32(1), 60–70.
517 Hummel, A., Shelton, K. H., Heron, J., Moore, L., & van den Bree, M. B. (2013). A systematic review of the relationships between family functioning, pubertal timing and adolescent substance use. Addiction, 108(3), 487–496.23163243
518 Katz, S., Ford, A. B., Moskowitz, R. W., Jackson, B. A., & Jaffe, M. W. (1963). Studies of illness in the aged: The Index of ADL; a standardized measure of biological and psychosocial function. JAMA, 185(12), 914–919.14044222
519 Mahoney, F., & Barthel, D. (1965). Functional evaluation: The Barthel Index. Maryland State Medical Journal, 14, 61–65.
520 NINDS Common Data Elements. (n.d.). Report Viewer [for Barthel Index]. Retrieved from www.commondataelements.ninds.nih.gov/report-viewer/23804/www.mapi-trust.org
521 Pfeffer, R. I., Kurosaki, T. T., Harrah, C. H., Chance, J. M., & Filos, S. (1982). Measurement of functional activities in older adults in the community. Journal of Gerontology, 37(3), 323–329.7069156
522 Marshall, G. A., Zoller, A. S., Lorius, N., Amariglio, R. E., Locascio, J. J., Johnson, K. A., … Alzheimer's Disease Neuroimaging Initiative. (2015). Functional Activities Questionnaire items that best discriminate and predict progression from clinically normal to mild cognitive impairment. Current Alzheimer Research, 12(5), 493.26017560
523 Centers for Disease Control and Prevention. (2016, September 22). Falls are leading cause of injury and death in older Americans. Retrieved April 11, 2019, from www.cdc.gov/media/releases/2016/p0922-older-adult-falls.html
524 Centers for Disease Control and Prevention. (2016). Older adult falls data. Retrieved February 12, 2018, from www.cdc.gov/homeandrecreationalsafety/falls/fallcost.html
525 Bergen, G., Stevens, M. R., & Burns, E. R. (2016). Falls and fall injuries among adults aged >65 years — United States, 2014. MMWR: Morbidity and Mortality Weekly Report, 65(37), 993–998.27656914
526 Burns, E. B., Stevens, J. A., & Lee, R. L. (2016). The direct costs of fatal and non-fatal falls among older adults: United States. Journal of Safety Research, 58, 99–103.27620939
527 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2015). Associations of mental health and substance use disorders with presenting problems and outcomes in older adults' emergency department visits. Academic Emergency Medicine, 22(11), 1316–1326.26473592
528 Ambrose, A. F., Paul, G., & Hausdorff, J. M. (2013). Risk factors for falls among older adults: A review of the literature. Maturitas 75(1), 51–61.23523272
529 Arora, A., O'Neill, A., Crome, P., & Martin, F. C. (2015). Clinical medicine and substance misuse: Research, assessments and treatment. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 35–55). Hoboken, NJ: Wiley-Blackwell.
530 Richardson, K., Bennett, K., & Kenny, R. A. (2015). Polypharmacy including falls risk-increasing medications and subsequent falls in community-dwelling middle-aged and older adults. Age and Ageing, 44(1), 90–96.25313240
531 Stone, K. L., Blackwell, T. L., Ancoli-Israel, S., Cauley, J. A., Redline, S., Marshall, L. M., & Ensrud, K. E. (2014). Sleep disturbances and risk of falls in older community-dwelling men: The outcomes of Sleep Disorders in Older Men (MrOS Sleep) Study. Journal of the American Geriatrics Society, 62(2), 299–305.24428306
532 Hayley, A. C., Williams, L. J., Kennedy, G. A., Holloway, K. L., Berk, M., Brennan-Olsen, S. L., & Pasco, J. A. (2015). Excessive daytime sleepiness and falls among older men and women: Cross-sectional examination of a population-based sample. BMC Geriatrics, 15, 74.26141865
533 Panel on Prevention of Falls in Older Persons, American Geriatrics Society and British Geriatrics Society. (2011). Summary of the updated American Geriatrics Society/British Geriatrics Society clinical practice guideline for prevention of falls in older persons. Journal of the American Geriatrics Society, 59(1), 148–157.21226685
534 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
535 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
536 American Association of Community Psychiatrists. (2015). LOCUS: Level of Care Utilization System for Psychiatric and Addiction Services Adult Version 20. Retrieved from www.communitypsychiatry.org/resources/locus
537 National Guardianship Association. (2013). Standards of practice (4th ed.). Retrieved from www.guardianship.org/wp-content/uploads/2017/07/NGA-Standards-with-Summit-Revisions-2017.pdf
538 Wilkins, J. M. (2017). Dementia, decision making, and quality of life. AMA Journal of Ethics, 19, 637–639.
539 Friedrichs, A., Spies, M., Härter, M., & Buchholz, A. (2016). Patient preferences and shared decision making in the treatment of substance use disorders: A systematic review of the literature. PLoS One, 11(1), e0145817.26731679
540 Friedrichs, A., Spies, M., Härter, M., & Buchholz, A. (2016). Patient preferences and shared decision making in the treatment of substance use disorders: A systematic review of the literature. PLoS One, 11(1), e0145817 26731679
541 Elwyn, G., Dehlendorf, C., Epstein, R. M., Marrin, K., White, J., & Frosch, D. L. (2014). Shared decision making and motivational interviewing: Achieving patient-centered care across the spectrum of health care problems. Annals of Family Medicine, 12(3), 270–275.24821899
542 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. HHS Publication No. PEP19-02-01-003. Rockville, MD: Substance Abuse and Mental Health Services Administration.
543 Purath, J., Keck, A., & Fitzgerald, C. (2014). Motivational interviewing for older adults in primary care: A systematic review. Geriatric Nursing, 35(3), 219–224.24656051
544 Elwyn, G., Dehlendorf, C., Epstein, R. M., Marrin, K., White, J., & Frosch, D. L. (2014). Shared decision making and motivational interviewing: Achieving patient-centered care across the spectrum of health care problems. Annals of Family Medicine, 12(3), 270–275.24821899
545 Sahker, E., Schultz, S. K., & Arndt, S. (2015). Treatment of substance use disorders in older adults: Implications for care delivery. Journal of the American Geriatrics Society, 63(11), 2317–2323.26502741
546 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
547 Sahker, E., Schultz, S. K., & Arndt, S. (2015). Treatment of substance use disorders in older adults: Implications for care delivery. Journal of the American Geriatrics Society, 63(11), 2317–2323.26502741
548 Carew, A. M., & Comiskey, C. (2018). Treatment for opioid use and outcomes in older adults: A systematic literature review. Drug and Alcohol Dependence, 182, 48–57.29136566
549 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
550 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
551 Moy, I., Crome, P., Crome, I., & Fisher, M. (2011). Systematic and narrative review of treatment for older people with substance problems. European Geriatric Medicine, 358, 212–236.
552 Bhatia, U., Nadkarni, A., Murthy, P., Rao, R., & I. Crome. (2015). Recent advances in treatment for older people with substance use problems: An updated systematic and narrative review. European Geriatric Medicine, 358, 580–586.
553 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
554 Aalto, M., Alho, H., Halme, J. T., & Seppä, K. (2011). The Alcohol Use Disorders Identification Test (AUDIT) and its derivatives in screening for heavy drinking among the elderly. International Journal of Geriatric Psychiatry, 26(9), 881–885.20661878
555 Barbor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). AUDIT: The Alcohol Use Disorders Identification Test: Guidelines for use in primary care (2nd ed., p. 17). Geneva, Switzerland: World Health Organization.
556 Bush, K., Kivlahan, D. R., McDonell, M. B., Fihn, S. D., & Bradley, K. A. (1998). The AUDIT alcohol consumption questions (AUDIT-C): An effective brief screening test for problem drinking. Ambulatory Care Quality Improvement Project (ACQUIP). Archives of Internal Medicine, 158, 1789–1795.9738608
557 U.S. Department of Veterans Affairs. (n.d.). AUDIT-C Frequently Asked Questions. Retrieved from www.queri.research.va.gov/tools/alcohol-misuse/alcohol-faqs.cfm#top
558 Blow, F. C., et al. (1998). Brief screening for alcohol problems in elderly populations using the Short Michigan Alcoholism Screening Test-Geriatric Version (SMAST-G). Hilton Head Island, SC: Research Society on Alcoholism Annual Scientific Meeting.
559 Purcell, B. (2003). Senior Alcohol Misuse Indicator. Toronto, Canada: Centre for Addiction and Mental Health, University of Toronto.
560 Adamson, S. J., Kay-Lambkin, F. J., Baker, A. L., Lewin, T. J., Thornton, L., Kelly, B. J., & Sellman, J. D. (2010). An improved brief measure of cannabis misuse: The Cannabis Use Disorders Identification Test-Revised (CUDIT-R). Drug and Alcohol Dependence, 110, 137–143.20347232
561 Meyer, T., Miller, M., Metzger, R., & Borkovec, T. D. (1990). Development and validation of the Penn State Worry Questionnaire. Behaviour Research and Therapy, 28, 487–495.2076086
562 Therrien, Z., & Hunsley, J. (2012). Assessment of anxiety in older adults: A systematic review of commonly used measures, Aging and Mental Health, 16(1), 1–16.21838650
563 Prins, A., Bovin, M. J., Kimerling, R., Kaloupek, D. G., Marx, B. P., Pless Kaiser, A., & Schnurr, P. P. (2015). The Primary Care PTSD Screen for DSM-5 (PC-PTSD-5). Retrieved from www.ptsd.va.gov/professional/assessment/screens/pc-ptsd.asp
564 Prins, A., Bovin, M. J., Smolenski, D. J., Marx, B. P., Kimerling, R., Jenkins-Guarnieri, M. A., … Tiet, Q. Q. (2016). The Primary Care PTSD Screen for DSM-5 (PC-PTSD-5): Development and evaluation within a veteran primary care sample. Journal of General Internal Medicine, 31(10), 1206–1211.27170304
565 Ware, L. J., Herr, K. A., Booker, S. S., Dotson, K., Key, J., Poindexter, N., … Packard, A. (2015). Psychometric evaluation of the revised Iowa Pain Thermometer (IPT-R) in a sample of diverse cognitively intact and impaired older adults: A pilot study. Pain Management Nursing, 16(4), 475–482.26256217
566 Katz, S., Down, T. D., Cash, H. R., & Grotz, R. C. (1970). Progress in the development of the index of ADL. Gerontologist, 10, 20–30.5420677
567 Grant, B. F., Chou, S. P., Saha, T. D., Pickering, R. P., Kerridge, B. T., Ruan, W. J., … Hasin, D. S. (2017). Prevalence of 12-month alcohol use, high-risk drinking, and DSM-IV Alcohol Use Disorder in the United States, 2001–2002 to 2012–2013: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. JAMA Psychiatry, 74(9), 911–923.28793133
568 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
569 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
570 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
571 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
572 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
573 Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/healthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
574 Family Caregiver Alliance. (2019). Caregiver statistics: Demographics. Retrieved from www.caregiver.org/caregiver-statistics-demographics
575 Drugs.com. (2018). What are drug interactions? Retrieved August 27, 2018, from www.drugs.com/druginteractions.html
576 World Health Organization. (2018). Lexicon of alcohol and drug terms published by the World Health Organization, Management of Substance Abuse. Retrieved from www.who.int/substanceabuse/terminology/wholexicon/en/
577 World Health Organization. (2018). Lexicon of alcohol and drug terms published by the World Health Organization, Management of Substance Abuse. Retrieved from www.who.int/substanceabuse/terminology/wholexicon/en/
578 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
579 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
580 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
581 Centers for Disease Control and Prevention. (2018). Alcohol and Public Health. Frequently Asked Questions. Retrieved from www.cdc.gov/alcohol/faqs.htm
582 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
583 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
584 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
585 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
586 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
587 DiBartolo, M. C., & Jarosinski, J. M. (2017). Alcohol use disorder in older adults: Challenges in assessment and treatment. Issues in Mental Health Nursing, 38(1), 25–32.27936333
588 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
589 Arndt, S., & Schultz, S. K. (2015). Epidemiology and demography of alcohol and the older person. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people. (pp. 75–90). West Sussex, UK: Wiley-Blackwell.
590 Wilson, S. R., Knowles, S. B., Huang, Q., & Fink, A. (2014). The prevalence of harmful and hazardous alcohol consumption in older U.S. adults: Data from the 2005–2008 National Health and Nutrition Examination Survey (NHANES). Journal of General Internal Medicine, 29(2), 312–319.24101531
591 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
592 Simou, E., Britton, J., & Leonardi-Bee, J. (2018). Alcohol and the risk of sleep apnoea: A systematic review and meta-analysis. Sleep Medicine, 42(2018), 38–46.29458744
593 Grant, B. F., Chou, S. P., Saha, T. D., Pickering, R. P., Kerridge, B. T., Ruan, W. J., … Hasin, D. S. (2017). Prevalence of 12-month alcohol use, high-risk drinking, and DSM-IV alcohol use disorder in the United States, 2001–2002 to 2012–2013: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. JAMA Psychiatry, 74(9), 911–923. doi:10.1001/jamapsychiatry.2017.2161 28793133
594 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
595 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
596 Ramchandani, V. A., Slattum, P. W., Patkar, A. A., Wu, L.-T., Lee, J. C., Mohanty, M., … Li, T.-K. (2014). Psychopharmacology and the consequences of alcohol and drug interactions. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 149–170). West Sussex, UK: Wiley-Blackwell.
597 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
598 Chernick, R., & Kuerbis, A. (2016). Social and familial contexts for drinking among older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 149–166). New York, NY: Springer.
599 Schonfeld, L. (2016). Adapting SBIRT for older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 215–232). New York, NY: Springer.
600 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
601 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
602 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
603 Arndt, S., & Schultz, S. K. (2015). Epidemiology and demography of alcohol and the older person. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 75–90). West Sussex, UK: Wiley-Blackwell.
604 Han, B. H., Moore, A. A., Sherman, S., Keyes, K. M., & Palamar, J. J. (2017). Demographic trends of binge alcohol use and alcohol use disorders among older adults in the United States, 2005–2014. Drug and Alcohol Dependence, 170, 198–207.27979428
605 Arndt, S., & Schultz, S. K. (2015). Epidemiology and demography of alcohol and the older person. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 75–90). West Sussex, UK: Wiley-Blackwell.
606 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
607 Chou, K. L., Liang, K., & Mackenzie, C. S. (2011). Binge drinking and Axis I psychiatric disorders in community-dwelling middle-aged and older adults: Results from the National Epidemiology Survey on Alcohol and Related Conditions (NESARC). Journal of Clinical Psychiatry, 72(5), 640–647.21294995
608 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
609 Grant, B. F., Chou, S. P., Saha, T. D., Pickering, R. P., Kerridge, B. T., Ruan, W. J., … Hasin, D. S. (2017). Prevalence of 12-month alcohol use, high-risk drinking, and DSM-IV alcohol use disorder in the United States, 2001–2002 to 2012–2013: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. JAMA Psychiatry, 74(9), 911–923.28793133
610 U.S. Census Bureau. (2017). 2017 national population projections tables: Main series (Table 2). Retrieved April 17, 2020, from www.census.gov/data/tables/2017/demo/popproj/2017-summary-tables.html
611 U.S. Census Bureau. (2019, October 8). Older people projected to outnumber children for first time in U.S. history [Revised press release]. Retrieved April 14, 2020, from www.census.gov/newsroom/press-releases/2018/cb18-41-population-projections.html
612 Arndt, S., & Schultz, S. K. (2015). Epidemiology and demography of alcohol and the older person. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 75–90). West Sussex, UK: Wiley-Blackwell.
613 Caputo, F., Vignoli, T., Leggio, L., Addolorato, G., Zoli, G., & Bernardi, M. (2012). Alcohol use disorders in the elderly: A brief overview from epidemiology to treatment options. Experimental Gerontology, 47(6), 411–416.22575256
614 Arndt, S., & Schultz, S. K. (2015). Epidemiology and demography of alcohol and the older person. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people. (pp. 75–90). West Sussex, UK: Wiley-Blackwell.
615 Bryant, C., Jackson, H., & Ames, D. (2008). The prevalence of anxiety in older adults: Methodological issues and a review of the literature. Journal of Affective Disorders, 109(3), 233–250.18155775
616 Wolitzky-Taylor, K. B., Castriotta, N., Lenze, E. J., Stanley, M. A., & Craske, M. G. (2010). Anxiety disorders in older adults: A comprehensive review. Depression and Anxiety, 27(2), 190–211.20099273
617 Bryant, C., Jackson, H., & Ames, D. (2008). The prevalence of anxiety in older adults: Methodological issues and a review of the literature. Journal of Affective Disorders, 109(3), 233–250.18155775
618 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
619 Meeks, T. W., Vahia, I. V., Lavretsky, H., Kulkarni, G., & Jeste, D. V. (2011). A tune in “A minor” can “B major”: A review of epidemiology, illness course, and public health implications of subthreshold depression in older adults. Journal of Affective Disorders, 129(1–3), 126–142.20926139
620 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
621 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
622 Wilson, D., Jackson, S., Crome, I. B., Rao, R. T., & Crome, P. (2015). Comprehensive geriatric assessment and the special needs of older people. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 171–191). West Sussex, UK: Wiley-Blackwell.
623 Osterweil, N. (2012, November 12). Older adults with schizophrenia can achieve remission. Clinical Psychiatry News. Retrieved from www.mdedge.com/clinicalpsychiatrynews/article/56692/schizophrenia-other-psychotic-disorders/older-adults
624 Lane, S. D., da Costa, S. C., Teixeira, A. L., Reynolds, C. F., & Diniz, B. S. (2018). The impact of substance use disorders on clinical outcomes in older-adult psychiatric inpatients. International Journal of Geriatric Psychiatry, 33(2), e323–e329.29044798
625 Patel, K. V., Guralnik, J. M., Dansie, E. J., & Turk, D. C. (2013). Prevalence and impact of pain among older adults in the United States: Findings from the 2011 National Health and Aging Trends Study. Pain, 154(12), 2649–2657.24287107
626 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
627 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
628 DiBartolo, M. C., & Jarosinski, J. M. (2017). Alcohol use disorder in older adults: Challenges in assessment and treatment. Issues in Mental Health Nursing, 38(1), 25–32.27936333
629 Klein, W. C., & Jess, C. (2002). One last pleasure? Alcohol use among elderly people in nursing homes. Health and Social Work, 27(3), 193–203.12230044
630 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
631 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
632 Massachusetts Department of Public Health, Bureau of Substance Abuse Services. (2015). Alcohol and medication issues for older adults. Retrieved from http://files.hria.org/files/SA1003.pdf
633 Blow, F. C., et al. (1998). Brief screening for alcohol problems in elderly populations using the Short Michigan Alcoholism Screening Test-Geriatric Version (SMAST-G). Hilton Head Island, SC: Research Society on Alcoholism Annual Scientific Meeting.
634 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
635 Barbor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). AUDIT: The Alcohol Use Disorders Identification Test: Guidelines for use in primary care (2nd ed.). Geneva, Switzerland: World Health Organization. Retrieved from http://apps.who.int/iris/bitstream/10665/67205/1/WHOMSPMSB01.6a.pdf
636 Aalto, M., Alho, H., Halme, J. T., & Seppä, K. (2011). The Alcohol Use Disorders Identification Test (AUDIT) and its derivatives in screening for heavy drinking among the elderly. International Journal of Geriatric Psychiatry, 26(9), 881–885. doi:10.1002/gps.2498 20661878
637 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
638 Blow, F. C. & Barry, K. L. (2012). Alcohol and substance misuse in older adults. Current Psychiatry Reports, 14(4), 310–319.22660897
639 Arndt, S., & Schultz, S. K. (2015). Epidemiology and demography of alcohol and the older person. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 75–90). West Sussex, UK: Wiley-Blackwell.
640 Substance Abuse and Mental Health Services Administration. (2017). A guide to preventing older adult alcohol and psychoactive medication misuse/abuse: Screening and brief interventions. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.ncoa.org/wp-content/uploads/SBIRT-Older-Adult-Manual-Final.pdf
641 Substance Abuse and Mental Health Services Administration. (2017). A guide to preventing older adult alcohol and psychoactive medication misuse/abuse: Screening and brief interventions. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.ncoa.org/wp-content/uploads/SBIRT-Older-Adult-Manual-Final.pdf
642 Sacco, P. (2016). Understanding alcohol consumption patterns among older adults: Continuity and change. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 19–34). New York, NY: Springer.
643 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
644 Moore, Α. Α., Kuerbis, Α., Sacco, P., Chen, G. I., & Garcia, Μ. B. (2016). Screening and assessment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 169–180). New York, NY: Springer.
645 Barry, K. L., Blow, F. C. & Oslin, D. W. (2002). Substance abuse in older adults: Review and recommendations for education and practice in medical settings. Substance Abuse, 23(3 Suppl.), 105–131.
646 Kuerbis, Α., Sacco, P., Blazer, D. G. & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
647 Satre, D. D. (2015). Alcohol and drug use problems among older adults. Clinical Psychology: Science and Practice, 22(3), 238–254.
648 Alpert, P. T. (2014). Alcohol abuse in older adults: An invisible population. Home Health Care Management and Practice, 26(4), 269–272.
649 Barry, K. L. & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
650 Fink, Α., Morton, S. C., Beck, J. C., Hays, R. D., Spritzer, K., Oishi, S. M. & Moore, A. A. (2002). The Alcohol-Related Problems Survey: Identifying hazardous and harmful drinking in older primary care patients. Journal of American Geriatrics Society, 50, 1717–1722.
651 Moore, Α. Α., Kuerbis, Α., Sacco, P., Chen, G. I., & Garcia, Μ. B. (2016). Screening and assessment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 169–180). New York, NY: Springer.
652 Barnes, A. J., Moore, Α. Α., Xu, Η., Ang, Α., Tallen, L., Mirkin, M., & Ettner, S. L. (2010). Prevalence and correlates of at-risk drinking among older adults: The Project SHARE study. Journal of General Internal Medicine, 25(8), 840–846.20396975
653 Cummings, S. M., Bride, B., Cassie, Κ. M., & Rawlins-Shaw, A. (2009). Substance abuse. In S. M. Cummings & N. P. Kropf (Eds.), Handbook of psychosocial interventions with older adults: Evidence-based approaches (pp. 215–241). New York, NY: Haworth Press.
654 Emiliussen, J., S0gaard Nielsen, Α., & Andersen, K. (2017). Identifying risk factors for late-onset (50+) alcohol use disorder and heavy drinking: A systematic review. Substance Use and Misuse, 52(12), 1575–1588.28524740
655 Kuerbis, Α., Sacco, P., Blazer, D. G. & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
656 Slättum, P. W. & Hassan, Ο. E. (2016). Medications, alcohol, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 117–129). New York, NY: Springer.
657 Barnes, A. J., Moore, A. A., Xu, H., Ang, A., Tallen, L., Mirkin, M., & Ettner, S. L. (2010). Prevalence and correlates of at-risk drinking among older adults: The Project SHARE study. Journal of General Internal Medicine, 25(8), 840–846.20396975
658 Gilson, K. M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
659 Breslow, R., Dong, C., & White, A. (2015). Prevalence of alcohol-interactive prescription medication use among current drinkers: United States, 1999 to 2010. Alcoholism, 39, 371–379.25597432
660 Slattum, P. W., & Hassan, O. E. (2016). Medications, alcohol, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 117–129). New York, NY: Springer.
661 DiBartolo, M. C., & Jarosinski, J. M. (2017). Alcohol use disorder in older adults: Challenges in assessment and treatment. Issues in Mental Health Nursing, 38(1), 25–32.27936333
662 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
663 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
664 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
665 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
666 Moore, A. A., Blow, F. C., Hoffing, M., Welgreen, S., Davis, J. W., Lin, J. C., … Barry, K. L. (2011). Primary care-based intervention to reduce at-risk drinking in older adults: A randomized controlled trial. Addiction, 106(1), 111–120.21143686
667 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
668 Blow, F. C., & Barry, K. L. (2000). Older patients with at-risk and problem drinking patterns: New developments in brief interventions. Journal of Geriatric Psychiatry and Neurology, 13(3), 115–123.11001133
669 Moore, A. A., Blow, F. C., Hoffing, M., Welgreen, S., Davis, J. W., Lin, J. C., … Barry, K. L. (2011). Primary care-based intervention to reduce at-risk drinking in older adults: A randomized controlled trial. Addiction, 106(1), 111–120.21143686
670 Moore, A. A., Blow, F. C., Hoffing, M., Welgreen, S., Davis, J. W., Lin, J. C., … Barry, K. L. (2011). Primary care-based intervention to reduce at-risk drinking in older adults: A randomized controlled trial. Addiction, 106(1), 111–120.21143686
671 Miller, W. R., Forcehimes, A., & Zweben, A. (2011). Treating addiction: A guide for professionals. New York, NY: Guilford Press.
672 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
673 Satre, D. D., & Leibowitz, A. (2015). Brief alcohol and drug interventions and motivational interviewing for older adults. In P. A. Areán (Ed.), Treatment of late-life depression, anxiety, trauma, and substance abuse (pp. 163–180). Washington, DC: American Psychological Association.
674 Serdarevic, M. (2016). Literature review: Motivational interviewing with the older adult. Journal of Psychology and Clinical Psychiatry, 6(7), 00409. doi:10.15406/jpcpy.2016.06.00409
675 Satre, D. D., & Leibowitz, A. (2015). Brief alcohol and drug interventions and motivational interviewing for older adults. In P. A. Areán (Ed.), Treatment of late-life depression, anxiety, trauma, and substance abuse (pp. 163–180). Washington, DC: American Psychological Association.
676 Cummings, S. M., Cooper, R. L., & Cassie, K. M. (2009). Motivational interviewing to affect behavioral change in older adults. Research on Social Work Practice, 19(2), 195–204.
677 Lundahl, B., Moleni, T., Burke, B., Butters, R., Tollefson, D., Butler, C., & Rollnick, S. (2013). Motivational interviewing in medical care settings: A systematic review and meta-analysis of randomized controlled trials. Patient Education and Counseling, 93(2), 157–168.24001658
678 Kuerbis, A., Treloar Padovano, H., Shao, S., Houser, J., Muench, F., & Morgenstern, J. (2018). Comparing daily drivers of problem drinking among older and younger adults: An electronic daily diary study using smartphones. Drug and Alcohol Dependence, 183, 240–246.29306171
679 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
680 Miller, W. R., Forcehimes, A., & Zweben, A. (2011). Treating addiction: A guide for professionals. New York, NY: Guilford Press.
681 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex: UK: Wiley-Blackwell.
682 Miller, W. R., Forcehimes, A., & Zweben, A. (2011). Treating addiction: A guide for professionals. New York, NY: Guilford Press.
683 Blow, F. C., & Barry, K. L. (2000). Older patients with at-risk and problem drinking patterns: New developments in brief interventions. Journal of Geriatric Psychiatry and Neurology, 13(3), 115–123.11001133
684 National Institute on Alcohol Abuse and Alcoholism. (n.d.). What's a “standard” drink? Retrieved June 14, 2019, from www.rethinkingdrinking.niaaa.nih.gov/How-much-is-too-much/What-counts-as-a-drink/Whats-A-Standard-Drink.aspx
685 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
686 Magill, M., Stout, R. L., & Apodaca, T. R. (2013). Therapist focus on ambivalence and commitment: A longitudinal analysis of motivational interviewing treatment ingredients. Psychology of Addictive Behaviors, 27(3), 754–762.22905897
687 Magill, M., Kiluk, B. D., McCrady, B. S., Tonigan, J. S., & Longabaugh, R. (2015). Active ingredients of treatment and client mechanisms of change in behavioral treatments for alcohol use disorders: Progress 10 years later. Alcoholism, Clinical and Experimental Research, 39(10), 1852–1862.26344200
688 Magill, M., Gaume, J., Apodaca, T. R., Walthers, J., Mastroleo, N. R., Borsari, B., & Longabaugh, R. (2014). The technical hypothesis of motivational interviewing: A meta-analysis of MI's key causal model. Journal of Consulting and Clinical Psychology, 82(6), 973–983.24841862
689 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
690 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
691 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
692 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
693 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
694 Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
695 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS Publication No. (SMA) 03–3824. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
696 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
697 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
698 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
699 Satre, D. D., Knight, B. G., & David, S. (2006). Cognitive-behavioral interventions with older adults: Integrating clinical and gerontological research. Professional Psychology: Research and Practice, 37(5), 489–498.
700 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
701 Satre, D. D., Knight, B. G., & David, S. (2006). Cognitive-behavioral interventions with older adults: Integrating clinical and gerontological research. Professional Psychology: Research and Practice, 37(5), 489–498.
702 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
703 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
704 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
705 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
706 Satre, D. D. (2015). Alcohol and drug use problems among older adults. Clinical Psychology: Science and Practice, 22(3), 238–254.
707 Satre, D. D., Knight, B. G., & David, S. (2006). Cognitive-behavioral interventions with older adults: Integrating clinical and gerontological research. Professional Psychology: Research and Practice, 37(5), 489–498.
708 Substance Abuse and Mental Health Services Administration. (2005). Substance abuse relapse prevention for older adults: A group treatment approach. HHS Publication No. (SMA) 05–4053. Rockville, MD: Substance Abuse and Mental Health Services Administration. https://preventionlane.org/wp-content/uploads/2018/01/SMA05-4053.pdf
709 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
710 Center for Substance Abuse Treatment. (2005). Substance abuse relapse prevention for older adults: A group treatment approach (p. 23). HHS Publication No. (SMA) 05-4053. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://preventionlane.org/wp-content/uploads/2018/01/SMA05-4053.pdf
711 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
712 Kiosses, D. N., & Alexopoulos, G. S. (2014). Problem-solving therapy in the elderly. Current Treatment Options in Psychiatry, 1(1), 15–26.24729951
713 Kiosses, D. N., & Alexopoulos, G. S. (2014). Problem-solving therapy in the elderly. Current Treatment Options in Psychiatry, 1(1), 15–26.24729951
714 Kiosses, D. N., & Alexopoulos, G. S. (2014). Problem-solving therapy in the elderly. Current Treatment Options in Psychiatry, 1(1), 15–26.24729951
715 Kiosses, D. N., & Alexopoulos, G. S. (2014). Problem-solving therapy in the elderly. Current Treatment Options in Psychiatry, 1(1), 15–26.24729951
716 Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-Step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3–4), 313–332.23731422
717 Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-Step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3–4), 313–332.23731422
718 Kelly, J. F., Stout, R. L., Magill, M., & Tonigan, J. S. (2011). The role of Alcoholics Anonymous in mobilizing adaptive social network changes: A prospective lagged mediational analysis. Drug and Alcohol Dependence, 114(2–3), 119–126.21035276
719 Kelly, J. F., Stout, R. L., Magill, M., Tonigan, J. S., & Pagano, M. E. (2011). Spirituality in recovery: A lagged mediational analysis of Alcoholics Anonymous' principal theoretical mechanism of behavior change. Alcoholism, Clinical and Experimental Research, 35(3), 454–463.21158876
720 Montes, K. S., & Tonigan, J. S. (2017). Does age moderate the effect of spirituality/religiousness in accounting for Alcoholics Anonymous benefit? Alcoholism Treatment Quarterly, 35(2), 96–112.28824222
721 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
722 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
723 Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
724 Klotz, U. (2009). Pharmacokinetics and drug metabolism in the elderly. Drug Metabolism Reviews, 41(2), 67–76.19514965
725 Lal, R., & Pattanayak, R. D. (2017). Alcohol use among the elderly: Issues and considerations. Journal of Geriatric Mental Health, 4(1), 4–10.
726 Ramchandani, V. A., Slattum, P. W., Patkar, A. A., Li-Tzy, W., Lee, J. C., Mohanty, M., … Ting-Kai, L. (2015). Psychopharmacology and the consequences of alcohol and drug interactions. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 149–170). West Sussex, UK: Wiley-Blackwell.
727 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
728 Witkiewitz, K., Saville, K., & Hamreus, K. (2012). Acamprosate for treatment of alcohol dependence: Mechanisms, efficacy, and clinical utility. Therapeutics and Clinical Risk Management, 8, 45–53.22346357
729 Hassell, C., Wilkins, K., & Trevisan, L. A. (2017). Pharmacology of geriatric substance use disorders: Considerations and future directions. Current Treatment Options in Psychiatry, 4(1), 102–115.
730 Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
731 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
732 Sinclair, J., Chambers, S., Shiles, C., & Baldwin, D. S. (2016). Safety and tolerability of pharmacological treatment of alcohol dependence: Comprehensive review of evidence. Drug Safety, 39, 627–645.27023898
733 Hassell C., Wilkins, K., & Trevisan, L. A. (2017). Pharmacology of geriatric substance use disorders: Considerations and future directions. Current Treatment Options in Psychiatry, 4(1), 102–115.
734 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
735 Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
736 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892. Retrieved from https://store.samhsa.gov/product/Clinical-Use-of-Extended-Release-Injectable-Naltrexone-in-the-Treatment-of-Opioid-Use-Disorder-A-Brief-Guide/SMA14-4892R
737 Substance Abuse and Mental Health Services Administration. (2015). Clinical use of extended-release injectable naltrexone in the treatment of opioid use disorder: A brief guide. HHS Publication No. (SMA) 14-4892. Retrieved from https://store.samhsa.gov/product/Clinical-Use-of-Extended-Release-Injectable-Naltrexone-in-the-Treatment-of-Opioid-Use-Disorder-A-Brief-Guide/SMA14-4892R
738 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
739 Hassell, C., Wilkins, K., & Trevisan, L. A. (2017). Pharmacology of geriatric substance use disorders: Considerations and future directions. Current Treatment Options in Psychiatry, 4(1), 102–115.
740 Le Roux, C., Tang, Y., & Drexler, K. (2016). Alcohol and opioid use disorder in older adults: Neglected and treatable illnesses. Current Psychiatry Reports, 18, 87.27488204
741 Lal, R., & Pattanayak, R. D. (2017). Alcohol use among the elderly: Issues and considerations. Journal of Geriatric Mental Health, 4(1), 4–10.
742 Lal, R., & Pattanayak, R. D. (2017). Alcohol use among the elderly: Issues and considerations. Journal of Geriatric Mental Health, 4(1), 4–10.
743 Friedmann, P. D. (2013). Alcohol use in adults. New England Journal of Medicine, 368(17), 1655–1656.
744 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
745 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
746 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
747 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
748 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
749 Taheri, A., Dahri, K., Chan, P., Shaw, M., Aulakh, A., & Tashakkor, A. (2014). Evaluation of a symptom-triggered protocol approach to the management of alcohol withdrawal syndrome in older adults. Journal of the American Geriatrics Society, 62(8), 1551–1555.24962514
750 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
751 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
752 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
753 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
754 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
755 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
756 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery (p. 3). Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/SAMHSA-s-Working-Definition-of-Recovery/PEP12-RECDEF
757 Kelly, J. F., & White, W. L. (2011) Addiction recovery management: Theory, research and practice. In W. L. White & J. F. Kelly (Eds.), Addiction recovery management: Theory, research and practice (pp. xi, 326). Totowa, NJ: Humana Press.
758 McKay, J. R. (2011). Continuing care and recovery. In J. F. Kelly & W. L. White (Eds.), Addiction recovery management: Theory, research and practice (pp. 163–183). Totowa, NJ: Humana Press.
759 Atkinson, R. M., & Misra, S. (2002). Further strategies in the treatment of aging alcoholics. In A. M. Gurnack, R. Atkinson, & N. J. Osgood (Eds.), Treating alcohol and drug abuse in the elderly (pp. 131–154). New York, NY: Springer.
760 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
761 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
762 McCrady, B. S. (2006). Family and other close relationships. In W. R. Miller & K. M. Carroll (Eds.), Rethinking substance abuse: What the science shows, and what we should do about it (pp. 166–181). New York, NY: Guilford Press.
763 McCrady, B. S. (2006). Family and other close relationships. In W. R. Miller & K. M. Carroll (Eds.), Rethinking substance abuse: What the science shows, and what we should do about it (pp. 166–181). New York, NY: Guilford Press.
764 National Academies of Sciences, Engineering. and Medicine. (2016). Families caring for an aging America (p. 366). Washington, DC: National Academies Press.
765 National Academies of Sciences, Engineering. and Medicine. (2016). Families caring for an aging America (p. 366). Washington, DC: National Academies Press.
766 National Academies of Sciences, Engineering. and Medicine. (2016). Families caring for an aging America (p. 366). Washington, DC: National Academies Press.
767 National Academies of Sciences, Engineering. and Medicine. (2016). Families caring for an aging America (p. 366). Washington, DC: National Academies Press.
768 Satre, D. D., Chi, F. W., Mertens, J. R., & Weisner, C. M. (2012). Effects of age and life transitions on alcohol and drug treatment outcome over nine years. Journal of Studies on Alcohol and Drugs, 73(3), 459–468.22456251
769 Satre, D. D., Chi, F. W., Mertens, J. R., & Weisner, C. M. (2012). Effects of age and life transitions on alcohol and drug treatment outcome over nine years. Journal of Studies on Alcohol and Drugs, 73(3), 459–468.22456251
770 Satre, D. D., Chi, F. W., Mertens, J. R., & Weisner, C. M. (2012). Effects of age and life transitions on alcohol and drug treatment outcome over nine years. Journal of Studies on Alcohol and Drugs, 73(3), 459–468.22456251
771 Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-Step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3–4), 313–332.23731422
772 Timko, C. (2008). Outcomes of AA for special populations. In M. Galanter & L. A. Kaskutas (Eds.), Research on Alcoholics Anonymous and spirituality in addiction recovery (pp. 373–392). New York, NY: Springer.
773 Kelly, J. F., Stout, R. L., Magill, M., & Tonigan, J. S. (2011). The role of Alcoholics Anonymous in mobilizing adaptive social network changes: A prospective lagged mediational analysis. Drug and Alcohol Dependence, 114(2–3), 119–126.21035276
774 Moos, R., & Timko, C. (2008). Outcome research on 12-Step and other self-help programs. In M. Galanter & H. O. Kleber (Eds.), Textbook of substance abuse treatment (pp. 511–521). Washington, DC: American Psychiatric Press.
775 Moos, R., & Timko, C. (2008). Outcome research on 12-Step and other self-help programs. In M. Galanter & H. O. Kleber (Eds.), Textbook of substance abuse treatment (pp. 511–521). Washington, DC: American Psychiatric Press.
776 Satre, D. D., Mertens, J. R., Areán, P. A., & Weisner, C. (2004). Five-year alcohol and drug treatment outcomes of older adults versus middle-aged and younger adults in a managed care program. Addiction, 99(10), 1286–1297.15369567
777 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
778 Lemke, S., & Moos, R. H. (2003). Outcomes at 1 and 5 years for older patients with alcohol use disorders. Journal of Substance Abuse Treatment, 24(1), 43–50.12646329
779 Alcoholics Anonymous World Services, Inc. (2015). Reaching the older alcoholics: The “Invisible Epidemic.” Box 459, 61(4), 6–7.
780 Satre, D. D., Blow, F. C., Chi, F. W., & Weisner, C. (2007). Gender differences in seven-year alcohol and drug treatment outcomes among older adults. American Journal on Addictions, 16(3), 216–221.17612826
781 Timko, C. (2008). Outcomes of AA for special populations. In M. Galanter & L. A. Kaskutas (Eds.), Research on Alcoholics Anonymous and spirituality in addiction recovery (pp. 373–392). New York, NY: Springer.
782 Montes, K. S., & Tonigan, J. S. (2017). Does age moderate the effect of spirituality/religiousness in accounting for Alcoholics Anonymous benefit? Alcoholism Treatment Quarterly, 35(2), 96–112.28824222
783 Satre, D. D., Mertens, J. R., Areán, P. A., & Weisner, C. (2004). Five-year alcohol and drug treatment outcomes of older adults versus middle-aged and younger adults in a managed care program. Addiction, 99(10), 1286–1297.15369567
784 SMART Recovery. (2017). Five year strategic plan: Freedom from addiction. Mentor, OH: SMART Recovery. Retrieved from http://smartrecovery.org/wp-content/uploads/2017/11/2017_SMART_StrategicPlan_Final.pdf
785 Beck, A. K., Forbes, E., Baker, A. L., Kelly, P. J., Deane, F. P., Shakeshaft, A., … Kelly, J. F. (2017). Systematic review of SMART Recovery: Outcomes, process variables, and implications for research. Psychology of Addictive Behaviors, 31(1), 1–20.28165272
786 Valentine, P., White, W., & Taylor, P. (2007). The recovery community organization: Toward a definition and description (p. 1). Retrieved from www.williamwhitepa-pers.com/pr/2007DefiningRecoveryCommunityOrgani-zation.pdf
787 Substance Abuse and Mental Health Services Administration. (2011). Screening, brief intervention, and referral to treatment (SBIRT) in behavioral healthcare. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/sites/default/files/sbirtwhitepaper_0.pdf
788 Friedmann, P. D. (2013). Alcohol use in adults. New England Journal of Medicine, 368(17), 1655–1656.
789 Babor, T. F., & Higgins-Biddle, J. C. (2001). Brief intervention for hazardous and harmful drinking: A manual for use in primary care. Retrieved from https://apps.who.int/iris/handle/10665/67210
790 Fishleder, S., Schonfeld, L., Corvin, J., Tyler, S., & VandeWeerd, C. (2016). Drinking behavior among older adults in a planned retirement community: Results from the Villages survey. International Journal of Geriatric Psychiatry, 31(5), 536–543.26436200
791 Sacco, P., Burruss, K., Smith, C. A., Kuerbis, A., Harrington, D., Moore, A. A., & Resnick, B. (2015). Drinking behavior among older adults at a continuing care retirement community: Affective and motivational influences. Aging and Mental Health, 19(3), 279–289.25010351
792 Linehan, M. M. (1993). Cognitive-behavioral treatment of borderline personality disorder. New York, NY: Guilford Press.
793 Valentine, S. E., Bankoff, S. M., Poulin, R. M., Reidler, E. B., & Pantalone, D. W. (2015). The use of dialectical behavior therapy skills training as stand-alone treatment: A systematic review of the treatment outcome literature. Journal of Clinical Psychology, 71(1), 1–20.25042066
794 Chapman, A. L. (2006). Dialectical behavior therapy: Current indications and unique elements. Psychiatry, 3(9), 62–68.
795 Drossel, C., Fisher, J. E., & Mercer, V. (2011). A DBT skills training group for family caregivers of persons with dementia. Behavior Therapy, 42(1), 109–119.21292057
796 Aalto, M., Alho, H., Halme, J. T., & Seppä, K. (2011). The Alcohol Use Disorders Identification Test (AUDIT) and its derivatives in screening for heavy drinking among the elderly. International Journal of Geriatric Psychiatry, 26(9), 881–885.20661878
797 Barbor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). AUDIT: The Alcohol Use Disorders Identifcation Test: Guidelines for use in primary care (2nd ed., p. 17). Geneva, Switzerland: World Health Organization.
798 Barbor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). AUDIT: The Alcohol Use Disorders Identifcation Test: Guidelines for use in primary care (2nd ed., p. 31). Geneva, Switzerland: World Health Organization.
799 Aalto, M., Alho, H., Halme, J. T., & Seppä, K. (2011). The Alcohol Use Disorders Identification Test (AUDIT) and its derivatives in screening for heavy drinking among the elderly. International Journal of Geriatric Psychiatry, 26(9), 881–885.20661878
800 Blow, F. C., et al. (1998). Brief screening for alcohol problems in elderly populations using the Short Michigan Alcoholism Screening Test-Geriatric Version (SMAST-G). Hilton Head Island, SC: Research Society on Alcoholism Annual Scientific Meeting.
801 Smith, M., Robinson, L., & Segal, J. (2019). Coping with grief and loss: Understanding the grieving process and learning to heal. Retrieved from https://staging.helpguide.org/articles/grief/coping-with-grief-and-loss.htm
802 Substance Abuse and Mental Health Services Administration. (2017). A guide to preventing older adult alcohol and psychoactive medication misuse/abuse: Screening and brief interventions (p. 83). Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.ncoa.org/wp-content/uploads/SBIRT-Older-Adult-Manual-Final.pdf
803 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
804 Outlaw, F. H., Marquart, J. M., Roy, A., Luellen, J. K., Moran, M., Willis, A., & Doub, T. (2010). Treatment outcomes for older adults who abuse substances. Journal of Applied Gerontology, 31(1), 78–100.
805 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
806 Mowbray, O., & Quinn, A. (2015). A scoping review of treatments for older adults with substance use problems. Research on Social Work Practice, 26(1), 74–87.
807 Mowbray, O., & Quinn, A. (2015). A scoping review of treatments for older adults with substance use problems. Research on Social Work Practice, 26(1), 74–87.
808 Carew, A. M., & Comiskey, C. (2018). Treatment for opioid use and outcomes in older adults: A systematic literature review. Drug and Alcohol Dependence, 182, 48–57.29136566
809 Family Caregiver Alliance. (2019). Caregiver statistics: Demographics. Retrieved from www.caregiver.org/caregiver-statistics-demographics
810 Drugs.com. (2018). What are drug interactions? Retrieved August 27, 2018, from www.drugs.com/drug_interactions.html
811 World Health Organization. (2018). Management of substance abuse: Psychoactive substances. Retrieved from www.who.int/substance_abuse/terminology/psychoactive_substances/en/
812 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
813 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
814 U.S. Census Bureau. (2019, October 8). Older people projected to outnumber children for frst time in U.S. history [Revised press release]. Retrieved April 14, 2020, from www.census.gov/newsroom/press-releases/2018/cb18-41-population-projections.html
815 Cleary, M., Sayers, J., Bramble, M., Jackson, D., & Lopez, V. (2017). Overview of substance use and mental health among the “baby boomers” generation. Issues in Mental Health Nursing, 38(1), 61–65.27936334
816 Wu, L.-T., & Blazer, D. G. (2011). Illicit and nonmedical drug use among older adults: A review. Journal of Aging and Health, 23(3), 481–504.21084724
817 Han, B. H., Sherman, S., Mauro, P. M., Martins, S. S., Rotenberg, J., & Palamar, J. J. (2017). Demographic trends among older cannabis users in the United States, 2006–13. Addiction (Abingdon, England), 112(3), 516–525.
818 National Drug Intelligence Center. (2011). The economic impact of illicit drug use on American society. Retrieved from www.justice.gov/archive/ndic/pubs44/44731/44731p.pdf
819 Florence, C. S., Zhou, C., Luo, F., & Xu, L. (2016). The economic burden of prescription opioid overdose, abuse, and dependence in the United States, 2013. Medical Care, 54(10), 901–906.27623005
820 Buttorff, C., Rudder, T., & Bauman, M. (2017). Multiple chronic conditions in the United States. Santa Monica, CA: RAND Corporation.
821 Rich, P. B., & Adams, S. D. (2015). Health care: Economic impact of caring for geriatric patients. Surgical Clinics of North America, 95(1), 11–21.25459539
822 Sambamoorthi, U., Tan, X., & Deb, A. (2015). Multiple chronic conditions and healthcare costs among adults. Expert Review of Pharmacoeconomics and Outcomes Research, 15(5), 823–832.26400220
823 Alpert, P. T. (2014). Alcohol abuse in older adults: An invisible population. Home Health Care Management and Practice, 26(4), 269–272.
824 Benshoff, J. J., Harrawood, L. K., & Koch, D. S. (2003). Substance abuse and the elderly: Unique issues and concerns. Journal of Rehabilitation, 69(2), 43.
825 Alpert, P. T. (2014). Alcohol abuse in older adults: An invisible population. Home Health Care Management and Practice, 26(4), 269–272.
826 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
827 Mowbray, O., & Quinn, A. (2016). A scoping review of treatments for older adults with substance use problems. Research on Social Work Practice, 26(1), 74–87.
828 Moy, I., Crome, P., Crome, I., & Fisher, M. (2011). Systematic and narrative review of treatment for older people with substance problems. European Geriatric Medicine, 2(4), 212–236.
829 Bhatia, U., Nadkarni, A., Murthy, P., Rao, R., & Crome, I. (2015). Recent advances in treatment for older people with substance use problems: An updated systematic and narrative review. European Geriatric Medicine, 6(6), 580–586.
830 Satre, D. D. (2015). Alcohol and drug use problems among older adults. Clinical Psychology: Science and Practice, 22(3), 238–254.
831 National Center for Health Statistics. (2019). Health, United States, 2018. Retrieved from www.cdc.gov/nchs/data/hus/hus18.pdf
832 Milton, J. C., Hill-Smith, I., & Jackson, S. H. (2008). Prescribing for older people. BMJ, 336(7644), 606–609.18340075
833 2019 American Geriatrics Society Beers Criteria® Update Expert Panel. (2019). Updated AGS Beers Criteria® for potentially inappropriate medication use in older adults. Journal of the American Geriatrics Society, 67(4), 674–694.30693946
834 Milton, J. C., Hill-Smith, I., & Jackson, S. H. (2008). Prescribing for older people. BMJ, 336(7644), 606–609.18340075
835 Rochon, P. A. (2020). Drug prescribing for older adults. In J. Givens (Ed.), UpToDate. Retrieved from www.uptodate.com/contents/drug-prescribing-for-older-adults
836 Aira, M., Hartikainen, S., & Sulkava, R. (2008). Drinking alcohol for medicinal purposes by people aged over 75: A community-based interview study. Family Practice, 25(6), 44–59.
837 Levi-Minzi, M. A., Surratt, H. L., Kurtz, S. P., & Buttram, M. E. (2013). Under treatment of pain: A prescription for opioid misuse among the elderly? Pain Medicine, 14(11), 1719–1729.23841571
838 Christie, M. M., Bamber, D., Powell, C., Arrindell, T., & Pant, A. (2013). Older adult problem drinkers: Who presents for alcohol treatment? Aging and Mental Health, 17(1), 24–32.22757629
839 West, N. A., Severtson, S. G., Green, J. L., & Dart, R. C. (2015). Trends in abuse and misuse of prescription opioids among older adults. Drug and Alcohol Dependence, 149, 117–121.25678441
840 Institute of Medicine. (2011). Relieving pain in America: A blueprint for transforming prevention, care, education, and research. Washington, DC: The National Academies Press.
841 Wick, J. Y. (2013). The history of benzodiazepines. Consultant Pharmacist, 28(9), 538–548.
842 Tannenbaum, C., Paquette, A., Hilmer, S., Holroyd-Leduc, J., & Carnahan, R. (2012). A systematic review of amnestic and non-amnestic mild cognitive impairment induced by anticholinergic, antihistamine, GABAergic, and opioid drugs. Drugs and Aging, 29(8), 639–658.22812538
843 Wang, R., Chen, L., Fan, L., Gao, D., Liang, Z., He, J., … Gao, L. (2015). Incidence and effects of polypharmacy on clinical outcome among patients aged 80+: A five-year follow-up study. PLoS One, 10(11), e0142123.26554710
844 Alomar, M. J. (2014). Factors affecting the development of adverse drug reactions (Review article). Saudi Pharmaceutical Journal, 22(2), 83–94.24648818
845 Maher, R. L., Hanlon, J. T., & Hajjar, E. R. (2014). Clinical consequences of polypharmacy in elderly. Expert Opinion on Drug Safety, 13(1), 57–65.24073682
846 Park, T. W., Saitz, R., Ganoczy, D., Ilgen, M. A., & Bohnert, A. S. (2015). Benzodiazepine prescribing patterns and deaths from drug overdose among US veterans receiving opioid analgesics: Case-cohort study. BMJ, 350. doi:10.1136/bmj.h2698
847 Food and Drug Administration. (2016). FDA Drug Safety Communication: FDA warns about serious risks and death when combining opioid pain or cough medicines with benzodiazepines; Requires its strongest warning. Retrieved from www.fda.gov/Drugs/DrugSafety/ucm518473.htm
848 Food and Drug Administration. (2017). FDA Drug Safety Communication: FDA urges caution about withholding opioid addiction medications from patients taking benzodiazepines or CNS depressants: Careful medication management can reduce risks. Retrieved from www.fda.gov/drugs/drug-safety-and-availability/fda-drug-safety-communication-fda-urges-caution-about-withholding-opioid-addiction-medications
849 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
850 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
851 Chhatre, S., Cook, R., Mallik, E., & Jayadevappa, R. (2017). Trends in substance use admissions among older adults. BMC Health Services Research, 17(1), 584.28830504
852 Black, P., & Joseph, L. J. (2014). Still dazed and confused: Midlife marijuana use by the baby boom generation. Deviant Behavior, 35(10), 822–841.
853 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
854 Curran, H. V., Freeman, T. P., Mokrysz, C., Lewis, D. A., Morgan, C. J., & Parsons, L. H. (2016). Keep off the grass? Cannabis, cognition and addiction. National Reviews: Neuroscience, 17(5), 293–306.
855 Lev-Ran, S., Roerecke, M., Le Foll, B., George, T. P., McKenzie, K., & Rehm, J. (2014). The association between cannabis use and depression: A systematic review and meta-analysis of longitudinal studies. Psychological Medicine, 44(4), 797–810.23795762
856 Armentano, P. (2013). Cannabis and psychomotor performance: A rational review of the evidence and implications for public policy. Drug Testing and Analysis, 5(1), 52–56.22972702
857 Mechoulam, R., & Parker, L. A. (2013). The endocannabinoid system and the brain. Annual Review of Psychology, 64, 21–47.
858 ElSohly, M. A., Mehmedic, Z., Foster, S., Gon, C., Chandra, S., & Church, J. C. (2016). Changes in cannabis potency over the last 2 decades (1995–2014): Analysis of current data in the United States. Biological Psychiatry, 79(7), 613–619.26903403
859 Han, B. H., & Moore, A. A. (2018). Prevention and screening of unhealthy substance use by older adults. Clinics in Geriatric Medicine, 34(1), 117–129.29129212
860 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
861 Searby, A., Maude, P., & McGrath, I. (2015). Dual diagnosis in older adults: A review. Issues in Mental Health Nursing, 36(2), 104–111.25625710
862 Sacco, P., Unick, G. J., Zanjani, F., & Camlin, E. A. S. (2015). Hospital outcomes in major depression among older adults: Differences by alcohol comorbidity. Journal of Dual Diagnosis, 11(1), 83–92.25671685
863 Schulte, M. T., & Hser, Y.-I. (2014). Substance use and associated health conditions throughout the lifespan. Public Health Reviews, 35(2).
864 Han, B. H., & Moore, A. A. (2018). Prevention and screening of unhealthy substance use by older adults. Clinics in Geriatric Medicine, 34(1), 117–129.29129212
865 Han, B. H., & Moore, A. A. (2018). Prevention and screening of unhealthy substance use by older adults. Clinics in Geriatric Medicine, 34(1), 117–129.29129212
866 Han, B. H., & Moore, A. A. (2018). Prevention and screening of unhealthy substance use by older adults. Clinics in Geriatric Medicine, 34(1), 117–129.29129212
867 Agency for Healthcare Research and Quality. (2015). Health Literacy Universal Precautions Toolkit (2nd ed.). Retrieved from www.ahrq.gov/professionals/quality-patient-safety/quality-resources/tools/literacy-toolkit/healthlittoolkit2.html
868 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
869 Weiss, B. D., Brega, A. G., LeBlanc, W. G., Mabachi, N. M., Barnard, J., Albright, K., … West, D. R. (2016). Improving the effectiveness of medication review: Guidance from the Health Literacy Universal Precautions Toolkit. Journal of the American Board of Family Medicine, 29(1), 18–23.26769873
870 Han, B. H., & Moore, A. A. (2018). Prevention and screening of unhealthy substance use by older adults. Clinics in Geriatric Medicine, 34(1), 117–129.29129212
871 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
872 Han, B. H., & Moore, A. A. (2018). Prevention and screening of unhealthy substance use by older adults. Clinics in Geriatric Medicine, 34(1), 117–129.29129212
873 Barry, K. L., Blow, F. C., & Oslin, D. W. (2002). Substance abuse in older adults: Review and recommendations for education and practice in medical settings. Substance Abuse, 23(Suppl. 3), 105–131.
874 Kuerbis, A., Sacco, P., Blazer, D., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30, 629–654.25037298
875 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. Washington, DC: Department of Health and Human Services.
876 National Institute on Drug Abuse. (2018). Principles of drug addiction treatment: A research-based guide (3rd ed.). Bethesda, MD: National Institute on Drug Abuse. Retrieved from www.drugabuse.gov/publications/principles-drug-addiction-treatment-research-based-guide-third-edition/preface
877 Mee-Lee, D., Shulman, G. D., Fishman, M. J., Gastfriend, D. R., & Miller, M. M. (Eds.). (2013). Application to adult special populations: Older adults. In The ASAM criteria: Treatment criteria for addictive, substance-related, and co-occurring conditions (3rd ed., pp. 307–317). Carson City, NV: The Change Companies.
878 Mee-Lee, D., Shulman, G. D., Fishman, M. J., Gastfriend, D. R., & Miller, M. M. (Eds.). (2013). Level of care placement (3rd ed., pp. 174–306). In The ASAM criteria: Treatment criteria for addictive, substance-related, and co-occurring conditions (3rd ed., pp. 307–317). Carson City, NV: The Change Companies.
879 Satre, D. D. & Leibowitz, A. (2015). Brief alcohol and drug interventions and motivational interviewing. In P. Areán (Ed.), Treatment of late-life depression, anxiety, trauma and substance abuse (pp. 163–280). Washington, DC: American Psychological Association.
880 Substance Abuse and Mental Health Services Administration. (2017). A guide to preventing older adult alcohol and psychoactive medication misuse/abuse: Screening and brief interventions. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.ncoa.org/wp-content/uploads/SBIRT-Older-Adult-Manual-Final.pdf
881 Mercadante, S. (2015). Opioid metabolism and clinical aspects. European Journal of Pharmacology, 769, 71–78.26522929
882 Martin, C. M., & Forrester, C. S. (2013). Anticipating and managing opioid side effects in the elderly. Consultant Pharmacist, 28(3), 150–159.
883 Dowell, D., Haegerich, T. M., & Chou, R. (2016). CDC guideline for prescribing opioids for chronic pain: United States, 2016. MMWR Recommendations and Reports, 65(No. RR-1), 1–49.
884 Substance Abuse and Mental Health Services Administration. (2018). SAMHSA opioid overdose prevention toolkit. HHS Publication No. (SMA) 18–4742. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Opioid-Overdose-Prevention-Toolkit/SMA18-4742
885 Bommersbach, T. J., Lapid, M. A., Rumman, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
886 Substance Abuse and Mental Health Services Administration. (2020). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP20-02-01-006. Rockville, MD: Substance Abuse and Mental Health Services Administration.
887 Kahan, M., Srivastava, A., Ordean, A., & Cirone, S. (2011). Buprenorphine: New treatment of opioid addiction in primary care. Canadian Family Physician, 57(3), 281–289.21402963
888 Whelan, P. J., & Remski, K. (2012). Buprenorphine vs. methadone treatment: A review of evidence in both developed and developing worlds. Journal of Neurosciences in Rural Practice, 3(1), 45–50.22346191
889 Karp, J. F., Butters, M. A., Begley, A. E., Miller, M. D., Lenze, E. J., Blumberger, D. M., … Reynolds, C. F., III. (2014). Safety, tolerability, and clinical effect of low-dose buprenorphine for treatment-resistant depression in midlife and older adults. Journal of Clinical Psychiatry, 75(8), e785–e793.25191915
890 Le Roux, C., Tang, Y., & Drexler, K. (2016). Alcohol and opioid use disorder in older adults: Neglected and treatable illnesses. Current Psychiatry Reports, 18(9), 87.27488204
891 Dugosh, K., Abraham, A., Seymour, B., McLoyd, K., Chalk, M., & Festinger, D. (2016). A systematic review on the use of psychosocial interventions in conjunction with medications for the treatment of opioid addiction. Journal of Addiction Medicine, 10(2), 93–103.26808307
892 Makris, U. E., Abrams, R. C., Gurland, B., & Reid, M. C. (2014). Management of persistent pain in the older patient: A clinical review. JAMA, 312(8), 825–836.25157726
893 Makris, U. E., Abrams, R. C., Gurland, B., & Reid, M. C. (2014). Management of persistent pain in the older patient: A clinical review. JAMA, 312(8), 825–836.25157726
894 Keilman, L. (2015). Compendium of evidence-based nonpharmacologic interventions for pain in older adults. East Lansing, MI: Michigan State University, College of Nursing.
895 Bicket, M. C., & Mao, J. (2015). Chronic pain in older adults. Anesthesiology Clinics, 33(3), 577–590.26315639
896 Makris, U. E., Abrams, R. C., Gurland, B., & Reid, M. C. (2014). Management of persistent pain in the older patient: A clinical review. JAMA, 312(8), 825–836.25157726
897 Schroeck, J. L., Ford, J., Conway, E. L., Kurtzhalts, K. E., Gee, M. E., Vollmer, K. A., & Mergenhagen, K. A. (2016). Review of safety and efficacy of sleep medicines in older adults. Clinical Therapeutics, 38(11), 2340–2372.27751669
898 Hood, S. D., Norman, A., Hince, D. A., Melichar, J. K., & Hulse, G. K. (2014). Benzodiazepine dependence and its treatment. British Journal of Clinical Pharmacology, 77, 285–294.23126253
899 Gould, R. L., Coulson, M. C., Patel, N., Highton-Williamson, E., & Howard, R. J. (2014). Interventions for reducing benzodiazepine use in older people: Meta-analysis of randomised controlled trials. British Journal of Psychiatry, 204(2), 98–107.
900 Markota, M., Rummans, T., Bostwick, M., & Lapid, M. (2016). Benzodiazepine use in older adults: Dangers, management, and alternative therapies. Mayo Clinic Proceedings, 91(11), 1632–1639.27814838
901 Tannenbaum, C., Martin, P., Tamblyn, R., Benedetti, A., & Ahmed, S. (2014). Reduction of inappropriate benzodiazepine prescriptions among older adults through direct patient education: The EMPOWER cluster randomized trial. JAMA Internal Medicine, 174(6), 890–898.24733354
902 Paquin, A. M., Zimmerman, K., & Rudolph, J. L. (2014). Risk versus risk: A review of benzodiazepine reduction in older adults. Expert Opinion on Drug Safety, 13(7), 919–934.24905348
903 Tannenbaum, C. (2015). Inappropriate benzodiazepine use in elderly patients and its reduction. Journal of Psychiatry and Neuroscience, 40(3), E27–E28.25903036
904 Lovato, N., Lack, L., Wright, H., & Kennaway, D. J. (2014). Evaluation of a brief treatment program of cognitive behavior therapy for insomnia in older adults. Sleep, 37(1), 117–126.24470701
905 Rybarczyk, B., Lund, H. G., Garroway, A. M., & Mack, L. (2013). Cognitive behavioral therapy for insomnia in older adults: Background, evidence, and overview of treatment protocol. Clinical Gerontologist, 36(1), 70–93.
906 McMurry, S. M., Logsdon, R. G., Teri, L., & Vitiello, M. V. (2007). Evidence-based psychological treatments for insomnia in older adults. Psychology and Aging, 22(1), 18–27.17385979
907 Belanger, L., LeBlanc, M., & Morin, C. M. (2012). Cognitive behavioral therapy for insomnia in older adults. Cognitive and Behavioral Practice, 19(1), 101–115.
908 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
909 Bonnet, U., & Preuss, U. W. (2017). The cannabis withdrawal syndrome: Current insights. Substance Abuse and Rehabilitation, 8, 9–37.28490916
910 National Institute on Drug Abuse. (2019). Marijuana Research Report. www.drugabuse.gov/publications/research-reports/marijuana
911 Stern, T. A., Celano, C. M., Gross, A. F., Huffman, J. C., Freudenreich, O., Kontos, N., … Thompson, B. T. (2010). The assessment and management of agitation and delirium in the general hospital. Primary Care Companion to the Journal of Clinical Psychiatry, 12(1), PCC.09r00938.
912 Kim, J. H., & Lawrence, A. J. (2014). Drugs currently in Phase II clinical trials for cocaine addiction. Expert Opinion on Investigational Drugs, 23(8), 1105–1122.24773297
913 Haile, C. N., & Kosten, T. R. (2013). Pharmacotherapy for stimulant-related disorders. Current Psychiatry Reports, 15(11), 10.1007/s11920-013-0415-y.
914 Lee, N. K., & Rawson, R. A. (2008). A systematic review of cognitive and behavioural therapies for methamphetamine dependence. Drug and Alcohol Review, 27(3), 309–317.18368613
915 Jhanjee, S. (2014). Evidence-based psychosocial interventions in substance use. Indian Journal of Psychological Medicine, 36(2), 112–118.24860208
916 Jhanjee, S. (2014). Evidence-based psychosocial interventions in substance use. Indian Journal of Psychological Medicine, 36(2), 112–118.24860208
917 Bhatia, U., Nadkarni, A., Murthy, P., Rao, R., & Crome, I. (2015). Recent advances in treatment for older people with substance use problems: An updated systematic and narrative review. European Geriatric Medicine, 6, 580–586.
918 Kiosses, D. N., & Alexopoulos, G. S. (2014). Problem-solving therapy in the elderly. Current Treatment Options in Psychiatry, 1(1), 15–26.24729951
919 Zbikowski, S. M., Magnusson, B., Pockey, J. R., Tindle, H. A., & Weaver, K. E. (2012). A review of smoking cessation interventions for smokers aged 50 and over. Maturitas, 71, 131–141.22209349
920 Kropf, N. P., & Cummings, S. M. (2017). Evidence-based treatment with older adults: Theory, Practice, and Research. New York, NY: Oxford University Press.
921 Moy, I., Crome, P., Crome, I., & Fisher, M. (2011). Systematic and narrative review of treatment for older people with substance problems. European Geriatric Medicine, 2(4), 212–236.
922 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
923 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
924 Oslin, D. W., Slaymaker, V. J., Blow, F. C., Owen, P. L., & Colleran, C. (2005). Treatment outcomes for alcohol dependence among middle-aged and older adults. Addictive Behaviors, 30(7), 1431–1436.16022937
925 Kuerbis, A., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse, 7, 13–37.23471422
926 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS Publication No. (SMA) 03–3824. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
927 Kelly, J. F., & White, W. L. (2011). Addiction recovery management: Theory, research and practice. In J. F. White & W. L. White (Eds.), Current clinical psychiatry (pp. xi, 326). Totowa, NJ: Humana Press.
928 Kelly, J. F., & White, W. L. (2011). Addiction recovery management: Theory, research and practice. In J. F. White & W. L. White (Eds.). Current clinical psychiatry (pp. xi, 326). Totowa, NJ: Humana Press.
929 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
930 Oslin, D. W., Grantham, S., Coakley, E., Maxwell, J., Miles, K., Ware, J., Levkoff, S. (2006). PRISM-E: Comparison of integrated care and enhanced specialty referral in managing at-risk alcohol use. Psychiatric Services, 57(7), 954–958.16816279
931 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
932 McCrady, B. S. (2006). Family and other close relationships. In W. R. Miller & K. M. Carroll (Eds.), Rethinking substance abuse: What the science shows, and what we should do about it (pp. 166–181). New York, NY: Guilford Press.
933 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
934 Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-Step Interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3-4), 313–332.23731422
935 Donovan, D. M., Ingalsbe, M. H., Benbow, J., & Daley, D. C. (2013). 12-Step interventions and mutual support programs for substance use disorders: An overview. Social Work in Public Health, 28(3-4), 313–332.23731422
936 Beck, A. K., Forbes, E., Baker, A. L., Kelly, P. J., Deane, F. P., Shakeshaft, A., … Kelly, J. F. (2017). Systematic review of SMART Recovery: Outcomes, process variables, and implications for research. Psychology of Addictive Behaviors, 31(1), 1–20.28165272
937 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
938 Kelly, J. F., Greene, M. C., & Bergman, B. G. (2014). Do drug-dependent patients attending Alcoholics Anonymous rather than Narcotics Anonymous do as well? A prospective, lagged, matching analysis. Alcohol and Alcoholism, 49(6), 645–653.25294352
939 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
940 Kelly, J. F., Stout, R. L., Magill, M., & Tonigan, J. S. (2011). The role of Alcoholics Anonymous in mobilizing adaptive social network changes: A prospective lagged mediational analysis. Drug and Alcohol Dependence, 114(2-3), 119–126.21035276
941 Wolitzky-Taylor, K. B., Castriotta, N., Lenze, E. J., Stanley, M. A., & Craske, M. G. (2010). Anxiety disorders in older adults: A comprehensive review. Depression and Anxiety, 27(2), 190–211.20099273
942 Wolitzky-Taylor, K. B., Castriotta, N., Lenze, E. J., Stanley, M. A., & Craske, M. G. (2010). Anxiety disorders in older adults: A comprehensive review. Depression and Anxiety, 27(2), 190–211.20099273
943 Chernick, R., & Kuerbis, A. (2016). Social and familial contexts for drinking among older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 149–166). New York, NY: Springer.
944 Bogenschutz, M. P., Donovan, D. M., Mandler, R. N., Perl, H. I., Forcehimes, A. A., Crandall, C., … Douaihy, A. (2014). Brief intervention for drug users presenting in emergency departments (NIDA CTN Protocol 0047: SMART-ED). JAMA Internal Medicine, 174(11), 1736–1745.25179753
945 Lofwall, M. R., Schuster, A., & Strain, E. C. (2008). Changing profile of abused substances by older persons entering treatment. Journal of Nervous and Mental Disease, 196(12), 898–905.19077857
946 Yarnell, S. C. (2015). Cocaine abuse in later life: A case series and review of the literature. Primary Care Companion for CNS Disorders, 17(2), 10.4088/PCC.14r01727.
947 Yarnell, S. C. (2015). Cocaine abuse in later life: A case series and review of the literature. Primary Care Companion for CNS Disorders, 17(2), 10.4088/PCC.14r01727.
948 Mee-Lee, D., Shulman, G. D., Fishman, M. J., Gastfriend, D. R., & Miller, M. M. (Eds.). (2013). Application to adult special populations: Older adults. In The ASAM criteria: Treatment criteria for addictive, substance-related, and co-occurring conditions (3rd ed., pp. 307–317). Carson City, NV: The Change Companies.
949 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
950 Rooney, R. F. (2014). Preventing dementia: How lifestyle in midlife affects risk. Current Opinion in Psychiatry, 27(2), 149–157.24441418
951 Baumgart, M., Snyder, H. M., Carrillo, M. C., Fazio, S., Kim, H., & Johns, H. (2015). Summary of the evidence on modifiable risk factors for cognitive decline and dementia: A population-based perspective. Alzheimer's and Dementia, 11(6), 718–726.
952 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
953 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015-2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
954 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
955 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
956 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
957 Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/healthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
958 Family Caregiver Alliance. (2019). Caregiver statistics: Demographic. Retrieved from www.caregiver.org/caregiver-statistics-demographics
959 Drugs.com. (2018). What are drug interactions? Retrieved August 27, 2018, from www.drugs.com/druginteractions.html
960 World Health Organization. (2018). Lexicon of alcohol and drug terms published by the World Health Organization. Retrieved from www.who.int/substance_abuse/terminology/wholexicon/en/
961 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
962 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015-2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
963 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
964 Centers for Disease Control and Prevention. (2018). Alcohol and Public Health. Frequently Asked Questions. Retrieved from www.cdc.gov/alcohol/faqs.htm
965 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015-2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
966 World Health Organization. (2018). Management of substance abuse: Psychoactive substances. Retrieved August 27, 2018, from www.who.int/substance_abuse/terminology/psychoactive_substances/en/
967 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
968 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
969 Chhatre, S., Cook, R., Mallik, E., & Jayadevappa, R. (2017). Trends in substance use admissions among older adults. BMC Health Services Research, 17(1), 584.28830504
970 Alpert, P. (2014). Alcohol abuse in older adults: An invisible population. Home Health Care Management and Practice, 26(4), 269–272.
971 American Psychiatric Association. (2015). Position statement on substance use disorders in older adults. www.psychiatry.org/File%20Library/About-APA/Organization-Documents-Policies/Policies/Position-Substance-Use-Disorders-in-Older-Adults.pdf
972 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
973 Qato, D. M., Manzoor, B. S., & Lee, T. A. (2015). Drug-alcohol interactions in older U.S. adults. Journal of the American Geriatrics Society, 63(11), 2324–2331.26503899
974 Mattson, M., Lipari, R. N., Hays, C., & Van Horn, S. L. (2017). A day in the life of older adults: Substance use facts. The CBHSQ Report. Rockville, MD: Center for Behavioral Health Statistics and Quality, Substance Abuse and Mental Health Services Administration. Retrieved March 10, 2018, from www.samhsa.gov/data/sites/default/files/report2792/ShortReport-2792.html
975 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
976 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
977 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
978 National Institute on Alcohol Abuse and Alcoholism. (2016). Rethinking drinking. Bethesda, MD: National Institute on Alcohol Abuse and Alcoholism. Bethesda. MD: National Institute on Alcohol Abuse and Alcoholism.
979 Breslow, R. A., Castle, I. P., Chen, C. M., & Graubard, B. I. (2017). Trends in alcohol consumption among older Americans: National Health Interview Surveys, 1997 to 2014. Alcoholism, Clinical and Experimental Research, 41(5), 976–986.28340502
980 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
981 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
982 National Institute on Drug Abuse. (2018). Misuse of prescription drugs. Retrieved from www.drugabuse.gov/publications/research-reports/misuse-prescription-drugs
983 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
984 Blazer, D. G., & Wu, L. T. (2012). Patterns of tobacco use and tobacco-related psychiatric morbidity and substance use among middle-aged and older adults in the United States. Aging and Mental Health, 16(3), 296–304.22292514
985 American Geriatrics Society. (2019). Updated AGS Beers Criteria^®^ for potentially inappropriate medication use in older adults. Journal of the American Geriatrics Society, 67(4), 674–694.30693946
986 Markota, M., Rummans, T. A., Bostwick, J. M., & Lapid, M. I. (2016). Benzodiazepine use in older adults: Dangers, management, and alternative therapies. Mayo Clinic Proceedings, 91(11), 1632–1639.27814838
987 Choi, N. G., DiNitto, D. M., & Marti, C. N. (2016). Older marijuana users: Life stressors and perceived social support. Drug and Alcohol Dependence, 169, 56–63.27776245
988 Bolla, K. I., Brown, K., Eldreth, D., Tate, K., & Cadet, J. L. (2002). Dose-related neurocognitive effects of marijuana use. Neurology, 59(9), 1337–1343.12427880
989 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
990 Moore, A. A., Whiteman, E. J., & Ward, K. T. (2007). Risks of combined alcohol/medication use in older adults. American Journal of Geriatric Pharmacotherapy, 5(1), 64–74.17608249
991 Holton, A. E., Gallagher, P., Fahey, T., & Cousins, G. (2017). Concurrent use of alcohol interactive medications and alcohol in older adults: A systematic review of prevalence and associated adverse outcomes. BMC Geriatrics, 17(1), 148.28716004
992 Zanjani, F., Smith, R., Slavova, S., Charnigo, R., Schoenberg, N., … Clayton, R. (2016). Concurrent alcohol and medication poisoning hospital admissions among older rural and urban residents. American Journal of Drug and Alcohol Abuse, 42(4), 422–430.27184414
993 Clausen, T., Martinez, P., Towers, A., Greenfield, T., & Kowal, P. (2016). Alcohol consumption at any level increases risk of injury caused by others: Data from the Study on Global AGEing and Adult Health. Substance Abuse, 9(Suppl. 2), 125–132.27257385
994 Thompson, H. J., Dikmen, S., & Temkin, N. (2012). Prevalence of comorbidity and its association with traumatic brain injury and outcomes in older adults. Research in Gerontological Nursing, 5(1), 17–24.22165997
995 Grossbard, J., Malte, C. A., Lapham, G., Pagulayan, K., Turner, A. P., Rubinsky, A. D., … Hawkins, E. J. (2017). Prevalence of alcohol misuse and follow-up care in a national sample of OEF/OIF VA patients with and without TBI. Psychiatric Services, 68(1), 48–55.27476804
996 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2016). Nonsuicidal self-injury and suicide attempts among ED patients older than 50 years: Comparison of risk factors and ED visit outcomes. American Journal of Emergency Medicine, 34(6), 1016–1021.26976771
997 Blow, F. C., & Barry, K. L. (2012). Alcohol and substance misuse in older adults. Current Psychiatry Reports, 14(4), 310–319.22660897
998 Mayo Clinic. (2019). Alcohol: Does it affect blood pressure? Retrieved June 17, 2019, from www.mayoclinic.org/diseases-conditions/high-blood-pressure/expert-answers/blood-pressure/faq-20058254
999 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
1000 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
1001 Harada, C. N., Natelson Love, M. C., & Triebel, K. L. (2013). Normal cognitive aging. Clinics in Geriatric Medicine, 29(4), 737–752.24094294
1002 National Institute on Aging. (2017). How the aging brain affects thinking. Retrieved June 17, 2019, from www.nia.nih.gov/health/how-aging-brain-affects-thinking
1003 Harada, C. N., Natelson Love, M. C., & Triebel, K. L. (2013). Normal cognitive aging. Clinics in Geriatric Medicine, 29(4), 737–752.24094294
1004 Sudhinaraset, M., Wigglesworth, C., & Takeuchi, D. T. (2016). Social and cultural contexts of alcohol use: Influences in a social-ecological framework. Alcohol Research, 38(1), 35–45.27159810
1005 GBD 2016 Alcohol Collaborators. (2018). Alcohol use and burden for 195 countries and territories, 1990-2016: A systematic analysis for the Global Burden of Disease Study 2016. Lancet, 392(10152), 1015–1035.30146330
1006 Piazza-Gardner, A. K., Gaffud, T. J., & Barry, A. E. (2013). The impact of alcohol on Alzheimer's disease: A systematic review. Aging and Mental Health, 17(2), 133–146.23171229
1007 Downer, B., Zanjani, F., & Fardo, D. W. (2014). The relationship between midlife and late life alcohol consumption, APOE e4 and the decline in learning and memory among older adults. Alcohol and Alcoholism, 49(1), 17–22.24049153
1008 Kuzma, E., Llewellyn, D. J., Langa, K. M., Wallace, R. B., & Lang, I. A. (2014). History of alcohol use disorders and risk of severe cognitive impairment: A 19-year prospective cohort study. American Journal of Geriatric Psychiatry, 22(10), 1047–1054.
1009 González-Reimers, E., Santolaria-Fernández, F., Martín-González, M. C., Fernández-Rodríguez, C. M., & Quintero-Platt, G. (2014). Alcoholism: A systemic proinflammatory condition. World Journal of Gastroenterology, 20(40), 14660–14671.25356029
1010 Bjork, J. M., & Gilman, J. M. (2014). The effects of acute alcohol administration on the human brain: Insights from neuroimaging. Neuropharmacology, 84, 101–110.23978384
1011 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
1012 Qato, D. M., Manzoor, B. S., & Lee, T. A. (2015). Drug-alcohol interactions in older U.S. adults. Journal of the American Geriatrics Society, 63(11), 2324–2331.26503899
1013 Stavro, K., Pelletier, J., & Potvin, S. (2013). Widespread and sustained cognitive deficits in alcoholism: A meta-analysis. Addiction Biology, 18(2), 203–213.22264351
1014 Bates, M. E., Buckman, J. F., & Nguyen, T. T. (2013). A role for cognitive rehabilitation in increasing the effectiveness of treatment for alcohol use disorders. Neuropsychology Review, 23(1), 27–47.23412885
1015 de la Monte, S. M., & Kril, J. J. (2014). Human alcohol-related neuropathology. Acta Neuropathology, 127(1), 71–90.
1016 Kim, J. W., Lee, D. Y., Lee, B. C., Jung, M. H., Kim, H., Choi, Y. S., & Choi, I. G. (2012). Alcohol and cognition in the elderly: A review. Psychiatry Investigation, 9(1), 8–16.22396679
1017 Topiwala, A., Allan, C. L., Valkanova, V., Zsoldos, E., Filippini, N., Sexton, C., … Ebmeier, K. P. (2017). Moderate alcohol consumption as risk factor for adverse brain outcomes and cognitive decline: Longitudinal cohort study. BMJ, 357, j2353.28588063
1018 Huang, W.-J., Zhang, X., & Chen, W.-W. (2016). Association between alcohol and Alzheimer's disease. Experimental and Therapeutic Medicine, 12(3), 1247–1250.27588045
1019 Piazza-Gardner, A. K., Gaffud, T. J., & Barry, A. E. (2013). The impact of alcohol on Alzheimer's disease: A systematic review. Aging and Mental Health, 17(2), 133–146.23171229
1020 Downer, B., Zanjani, F., & Fardo, D. W. (2014). The relationship between midlife and late life alcohol consumption, APOE e4 and the decline in learning and memory among older adults. Alcohol and Alcoholism, 49(1), 17–22.24049153
1021 KuZma, E., Llewellyn, D. J., Langa, K. M., Wallace, R. B., & Lang, I. A. (2014). History of alcohol use disorders and risk of severe cognitive impairment: A 19-year prospective cohort study. American Journal of Geriatric Psychiatry, 22(10), 1047–1054.
1022 Xue, H., Sun, Q., Liu, L., Zhou, L., Liang, R., He, R., & Yu, H. (2017). Risk factors of transition from mild cognitive impairment to Alzheimer's disease and death: A cohort study. Comprehensive Psychiatry, 78, 91–97.28806610
1023 Nordstrom, P., Nordstrom, A., Eriksson, M., Wahlund, L. O., & Gustafson, Y. (2013). Risk factors in late adolescence for young-onset dementia in men: A nationwide cohort study. JAMA Internal Medicine, 173(17), 1612–1618.23939347
1024 Anttila, T., Helkala, E. L., Viitanen, M., Kareholt, I., Fratiglioni, L., Winblad, B., Kivipelto, M. (2004). Alcohol drinking in middle age and subsequent risk of mild cognitive impairment and dementia in old age: A prospective population-based study. BMJ, 329(7465), 539.15304383
1025 de Oliveira, F. F., Wajman, J. R., Bertolucci, P. H., Chen, E. S., & Smith, M. C. (2015). Correlations among cognitive and behavioural assessments in patients with dementia due to Alzheimer's disease. Clinical Neurology and Neurosurgery, 135, 27–33.26010393
1026 González-Reimers, E., Santolaria-Fernández, F., Martín-González, M. C., Fernández-Rodríguez, C. M., & Quintero-Platt, G. (2014). Alcoholism: A systemic proinflammatory condition. World Journal of Gastroenterology, 20(40), 14660–14671.25356029
1027 Bjork, J. M., & Gilman, J. M. (2014). The effects of acute alcohol administration on the human brain: Insights from neuroimaging. Neuropharmacology, 84, 101–110.23978384
1028 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research: Current Reviews, 38(1), 115–120.27159818
1029 Qato, D. M., Manzoor, B. S., & Lee, T. A. (2015). Drug-alcohol interactions in older U.S. adults. Journal of the American Geriatrics Society, 63(11), 2324–2331.26503899
1030 Panza, F., Capurso, C., D'Introno, A., Colacicco, A. M., Frisardi, V., Lorusso, M., … Solfrizzi, V. (2009). Alcohol drinking, cognitive functions in older age, predementia, and dementia syndromes. Journal of Alzheimer's Disease, 17(1), 7–31.
1031 GBD 2016 Alcohol Collaborators. (2018). Alcohol use and burden for 195 countries and territories, 1990-2016: A systematic analysis for the Global Burden of Disease Study 2016. Lancet, 392(10152), 1015–1035.30146330
1032 Hein, C., Forgues, A., Piau, A., Sommet, A., Vellas, B., & Nourhashemi, F. (2014). Impact of polypharmacy on occurrence of delirium in elderly emergency patients. Journal of the American Medical Directors Association, 15(11), e811–e855.
1033 Inouye, S. K., Robinson, T., Blaum, C., Busby-Whitehead, J., Boustani, M., Chalian, A., … Richter, H. (2015). Postoperative delirium in older adults: Best practice statement from the American Geriatrics Society. Journal of the American College of Surgeons, 220(2), 136–148.25535170
1034 Inouye, S. K., Westendorp, R. G., & Saczynski, J. S. (2014). Delirium in elderly people. Lancet, 383(9920), 911–922.23992774
1035 Costin, B. N., & Miles, M. F. (2014). Molecular and neurologic responses to chronic alcohol use. Handbook of Clinical Neurology, 125, 157–171.25307574
1036 Mainerova, B., Prasko, J., Latalova, K., Axmann, K., Cerna, M., … Bradacova, R. (2015). Alcohol withdrawal delirium: Diagnosis, course and treatment. Biomedical Papers of the Medical Faculty of the University Palacky, Olomouc, Czechoslovakia, 159(1), 44–52.24399242
1037 Schuckit, M. A. (2014). Recognition and management of withdrawal delirium (delirium tremens). New England Journal of Medicine, 371(22), 2109–2113.25427113
1038 Schuckit, M. A. (2014). Recognition and management of withdrawal delirium (delirium tremens). New England Journal of Medicine, 371(22), 2109–2113.25427113
1039 Sachdeva, A., Chandra, M., Choudhary, M., Dayal, P., & Anand, K. S. (2016). Alcohol-related dementia and neurocognitive impairment: A review study. International Journal of High-Risk Behaviors and Addiction, 5(3), e27976.27818965
1040 Cheng, C., Huang, C. L., Tsai, C. J., Chou, P. H., Lin, C. C., & Chang, C. K. (2017). Alcohol-related dementia: A systemic review of epidemiological studies. Psychosomatics, 58(4), 331–342.28501289
1041 Sachdeva, A., Chandra, M., Choudhary, M., Dayal, P., & Anand, K. S. (2016). Alcohol-related dementia and neurocognitive impairment: A review study. International Journal of High Risk Behaviors and Addiction, 5(3), e27976.27818965
1042 Sachdeva, A., Chandra, M., Choudhary, M., Dayal, P., & Anand, K. S. (2016). Alcohol-related dementia and neurocognitive impairment: A review study. International Journal of High Risk Behaviors and Addiction, 5(3), e27976.27818965
1043 Zahr, N. M., Kaufman, K. L., & Harper, C. G. (2011). Clinical and pathological features of alcohol-related brain damage. Nature Reviews: Neurology, 7, 284–294.21487421
1044 Galvin, R., Bråthen, G., Ivashynka, A., Hillbom, M., Tanasescu, R., & Leone, M. A. (2010). EFNS guidelines for diagnosis, therapy and prevention of Wernicke encephalopathy. European Journal of Neurology, 17(12), 1408–1418.20642790
1045 Galvin, R., Bråthen, G., Ivashynka, A., Hillbom, M., Tanasescu, R., & Leone, M. A. (2010). EFNS guidelines for diagnosis, therapy and prevention of Wernicke encephalopathy. European Journal of Neurology, 17(12), 1408–1418.20642790
1046 Gerridzen, I. J., Moerman-van den Brink, W. G., Depla, M. F., Verschuur, E. M., Veenhuizen, R. B., van der Wouden, J. C., … Joling, K. J. (2017). Prevalence and severity of behavioural symptoms in patients with Korsakoff syndrome and other alcohol-related cognitive disorders: A systematic review. International Journal of Geriatric Psychiatry, 32(3), 256–273.27918121
1047 Zhong, G., Wang, Y., Zhang, Y., & Zhao Y. (2015). Association between benzodiazepine use and dementia: A meta-analysis. PLoS One, 10(5), e0127836.26016483
1048 Billioti de Gage, S., Pariente, A., & Bégaud, B. (2015). Is there really a link between benzodiazepine use and the risk of dementia? Expert Opinions in Drug Safety, 14(5), 733–747.
1049 Zhong, G., Wang, Y., Zhang, Y., & Zhao Y. (2015). Association between benzodiazepine use and dementia: A meta-analysis. PLoS One, 10(5), e0127836.26016483
1050 2019 American Geriatrics Society Beers Criteria® Update Expert Panel. (2019). Updated AGS Beers Criteria® for potentially inappropriate medication use in older adults. Journal of the American Geriatrics Society, 67(4), 674–694.30693946
1051 2019 American Geriatrics Society Beers Criteria® Update Expert Panel. (2019). Updated AGS Beers Criteria® for potentially inappropriate medication use in older adults. Journal of the American Geriatrics Society, 67(4), 674–694.30693946
1052 Zhong, G., Wang, Y., Zhang, Y., Guo, J. J., & Zhao, Y. (2015). Smoking is associated with an increased risk of dementia: A meta-analysis of prospective cohort studies with investigation of potential effect modifiers. PLoS One, 10(3), e0118333.25763939
1053 Peters, R., Poulter, R., Warner, J., Beckett, N., Burch, L., & Bulpitt, C. (2008). Smoking, dementia and cognitive decline in the elderly: A systematic review. BMC Geriatrics, 8, 36.19105840
1054 Cataldo, J. K., Prochaska, J. J., & Glantz, S. A. (2010). Cigarette smoking is a risk factor for Alzheimer's disease: An analysis controlling for tobacco industry affiliation. Journal of Alzheimer's Disease, 19(2), 465–480.
1055 Anstey, K. J., von Sanden, C., Salim, A., & O'Kearney, R. (2007). Smoking as a risk factor for dementia and cognitive decline: A meta-analysis of prospective studies. American Journal of Epidemiology, 166(4), 367–378.17573335
1056 Beydoun, M. A., Beydoun, H. A., Gamaldo, A. A., Teel, A., Zonderman, A. B., & Wang, Y. (2014). Epidemiologic studies of modifiable factors associated with cognition and dementia: Systematic review and meta-analysis. BMC Public Health, 14, 643.24962204
1057 Wu, L. T., & Blazer, D. G. (2014). Substance use disorders and psychiatric comorbidity in mid and later life: A review. International Journal of Epidemiology, 43(2), 304–317.24163278
1058 Wu, L. T., & Blazer, D. G. (2014). Substance use disorders and psychiatric comorbidity in mid and later life: A review. International Journal of Epidemiology, 43(2), 304–317.24163278
1059 Mowbray, O., Washington, T., Purser, G., & O'Shields, J. (2017). Problem drinking and depression in older adults with multiple chronic health conditions. Journal of the American Geriatrics Society, 65(1), 146–152.27748504
1060 Shimada, H., Park, H., Makizako, H., Doi, T., Lee, S., & Suzuki, T. (2014). Depressive symptoms and cognitive performance in older adults. Journal of Psychiatric Research, 57, 149–156.25023083
1061 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
1062 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
1063 Searby, A., Maude, P., & McGrath, I. (2015). Dual diagnosis in older adults: A review. Issues in Mental Health Nursing, 36(2), 104–111.25625710
1064 Sacco, P., Unick, G. J., Zanjani, F., & Camlin, E. A. S. (2015). Hospital outcomes in major depression among older adults: Differences by alcohol comorbidity. Journal of Dual Diagnosis, 11(1), 83–92.25671685
1065 Bartels, S. J., Coakley, E., Oxman, T. E., Constantino, G., Oslin, D., Chen, H., Sanchez, H. (2002). Suicidal and death ideation in older primary care patients with depression, anxiety, and at-risk alcohol use. American Journal of Geriatric Psychiatry, 4, 417–427.
1066 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
1067 Searby, A., Maude, P., & McGrath, I. (2015). Dual diagnosis in older adults: A review. Issues in Mental Health Nursing, 36(2), 104–111.25625710
1068 Kuring, J. K., Mathias, J. L., & Ward, L. (2018). Prevalence of depression, anxiety and PTSD in people with dementia: A systematic review and meta-analysis. Neuropsychology Reviews, 28(4), 393–416.
1069 Mowbray, O., Washington, T., Purser, G., & O'Shields, J. (2017). Problem drinking and depression in older adults with multiple chronic health conditions. Journal of the American Geriatrics Society, 65(1), 146–152.27748504
1070 Hunt, S. A., Kay-Lambkin, F. J., Baker, A. L., & Michie, P. T. (2015). Systematic review of neurocognition in people with co-occurring alcohol misuse and depression. Journal of Affective Disorders, 179, 51–64.25845750
1071 Bennett, S., & Thomas, A. J. (2014). Depression and dementia: Cause, consequence or coincidence? Maturitas, 79(2), 184–190.24931304
1072 Ownby, R. L., Crocco, E., Acevedo, A., John, V., & Loewenstein, D. (2006). Depression and risk for Alzheimer's disease: Systematic review, meta-analysis, and metaregression analysis. Archives of General Psychiatry, 63, 530–538.16651510
1073 Diniz, B. S., Butters, M. A., Albert, S. M., Dew, M. A., & Reynolds, C. F. (2013). Late-life depression and risk of vascular dementia and Alzheimer's disease: Systematic review and meta-analysis of community-based cohort studies. British Journal of Psychiatry, 202(5), 329–335.
1074 Spira, A. P., Rebok, G. W., Stone, K. L., Kramer, J. H., & Yaffe, K. (2012). Depressive symptoms in oldest-old women: Risk of mild cognitive impairment and dementia. American Journal of Geriatric Psychiatry, 20(12), 1006–1015.
1075 da Silva, J., Gonçalves-Pereira, M., Xavier, M., & Mukaetova-Ladinska, E. B. (2013). Affective disorders and risk of developing dementia: Systematic review. British Journal of Psychiatry, 202(3), 177–186.
1076 Bower, E. S., Wetherell, J. L., Mon, T., & Lenze, E. J. (2015). Treating anxiety disorders in older adults: Current treatments and future directions. Harvard Review of Psychiatry, 23(5), 329–342.26332216
1077 Reynolds, K., Pietrzak, R. H., El-Gabalawy, R., Mackenzie, C. S., & Sareen, J. (2015). Prevalence of psychiatric disorders in U.S. older adults: Findings from a nationally representative survey. World Psychiatry, 14(1), 74–81.25655161
1078 Wolitzky-Taylor, K. B., Castriotta, N., Lenze, E. J., Stanley, M. A., & Craske, M. G. (2010). Anxiety disorders in older adults: A comprehensive review. Depression and Anxiety, 27(2), 190–211.20099273
1079 Reynolds, K., Pietrzak, R. H., El-Gabalawy, R., Mackenzie, C. S., & Sareen, J. (2015). Prevalence of psychiatric disorders in U.S. older adults: Findings from a nationally representative survey. World Psychiatry, 14(1), 74–81.25655161
1080 Lin, J. C., Karno, M. P., Grella, C. E., Ray, L. A., Liao, D. H., & Moore, A. A. (2014). Psychiatric correlates of alcohol and tobacco use disorders in U.S. adults aged 65 years and older: Results from the 2001-2002 National Epidemiologic Survey of Alcohol and Related Conditions. American Journal of Geriatric Psychiatry, 22(11), 1356–1363.
1081 Wu, L. T., & Blazer, D. G. (2014). Substance use disorders and psychiatric comorbidity in mid and later life: A review. International Journal of Epidemiology, 43(2), 304–317.24163278
1082 Mackenzie, C. S., El-Gabalawy, R., Chou, K. L., & Sareen, J. (2014). Prevalence and predictors of persistent versus remitting mood, anxiety, and substance disorders in a national sample of older adults. American Journal of Geriatric Psychiatry, 22(9), 854–865.
1083 Schutte, K., Lemke, S., Moos, R. H., & Brennan, P. L. (2015). Age-sensitive psychosocial treatment for older adults with substance abuse. In I. Crome, L.-T. Wu, R. T. Rao, & P. Crome (Eds.), Substance use and older people (pp. 314–339). West Sussex, UK: Wiley-Blackwell.
1084 Beaudreau, S. A., & O'Hara, R. (2008). Late-life anxiety and cognitive impairment: A review. American Journal of Geriatric Psychiatry, 16(10), 790–803.
1085 Beaudreau, S. A., & O'Hara, R. (2008). Late-life anxiety and cognitive impairment: A review. American Journal of Geriatric Psychiatry, 16(10), 790–803.
1086 Lin, J. C., Karno, M. P., Grella, C. E., Ray, L. A., Liao, D. H., & Moore, A. A. (2014). Psychiatric correlates of alcohol and tobacco use disorders in U.S. adults aged 65 years and older: Results from the 2001-2002 National Epidemiologic Survey of Alcohol and Related Conditions. American Journal of Geriatric Psychiatry, 22(11), 1356–1363.
1087 Kuring, J. K., Mathias, J. L., & Ward, L. (2018). Prevalence of depression, anxiety and PTSD in people with dementia: A systematic review and meta-analysis. Neuropsychology Reviews, 28(4), 393–416.
1088 Burton, C., Campbell, P., Jordan, K., Strauss, V., & Mallen, C. (2013). The association of anxiety and depression with future dementia diagnosis: A case-control study in primary care. Family Practice, 30(1), 25–30.22915794
1089 Burton, C., Campbell, P., Jordan, K., Strauss, V., & Mallen, C. (2013). The association of anxiety and depression with future dementia diagnosis: A case-control study in primary care. Family Practice, 30(1), 25–30.22915794
1090 Burton, C., Campbell, P., Jordan, K., Strauss, V., & Mallen, C. (2013). The association of anxiety and depression with future dementia diagnosis: A case-control study in primary care. Family Practice, 30(1), 25–30.22915794
1091 Gulpers, B., Ramakers, I., Hamel, R., Köhler, S., Oude Voshaar, R., & Verhey, F. (2016). Anxiety as a predictor for cognitive decline and dementia: A systematic review and meta-analysis. American Journal of Geriatric Psychiatry, 24(10), 823–842.
1092 Andreescu, C., & Varon, D. (2015). New research on anxiety disorders in the elderly and an update on evidence-based treatments. Current Psychiatry Reports, 17(7), 53.25980510
1093 Reynolds, K., Pietrzak, R. H., El-Gabalawy, R., Mackenzie, C. S., & Sareen, J. (2015). Prevalence of psychiatric disorders in U.S. older adults: Findings from a nationally representative survey. World Psychiatry, 74(1), 74–81.
1094 Pietrzak, R. H., Goldstein, R. B., Southwick, S. M. & Grant, B. F. (2012). Psychiatric comorbidity of full and partial posttraumatic stress disorder among older adults in the United States: Results from Wave 2 of the National Epidemiologic Survey on Alcohol and Related Conditions. American Journal of Geriatric Psychiatry, 20(5), 380–390.
1095 Kuring, J. K., Mathias, J. L. & Ward, L. (2018). Prevalence of depression, anxiety and PTSD in people with dementia: A systematic review and meta-analysis. Neuropsychological Reviews, 28(4), 393–416.
1096 Kang, B., Xu, H., & McConnell, E. S. (2019). Neurocognitive and psychiatric comorbidities of posttraumatic stress disorder among older veterans: A systematic review. International Journal of Geriatric Psychiatry, 34(4), 522–538.30588665
1097 Substance Abuse and Mental Health Services Administration. (2014). SAMHSA's concept of trauma and guidance for a trauma-informed approach. Retrieved from https://store.samhsa.gov/product/SAMHSA-s-Concept-of-Trauma-and-Guidance-for-a-Trauma-lnformed-Approach/SMA14-4884
1098 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4801. Retrieved from https://store.samhsa.gov/product/TIP-57-Trauma-lnformed-Care-in-Behavioral-Health-Services/SMA14-4816
1099 Hiskey, S., & McPherson, S. (2013). That's just life: Older adult constructs of trauma. Aging and Mental Health, 77(6), 689–696.
1100 Searby, Α., Maude, P., & McGrath, I. (2015). Dual diagnosis in older adults: A review. Issues in Mental Health Nursing, 36(2), 104–111.25625710
1101 Wu, L. T., & Blazer, D. G. (2014). Substance use disorders and psychiatric comorbidity in mid and later life: A review. International Journal of Epidemiology, 43(2), 304–317.24163278
1102 Lin, J. C., Karno, M. P., Grella, C. E., Ray, L. Α., Liao, D. H., & Moore, A. A. (2014). Psychiatric correlates of alcohol and tobacco use disorders in U.S. adults aged 65 years and older: Results from the 2001-2002 National Epidemiologic Survey of Alcohol and Related Conditions. American Journal of Geriatric Psychiatry, 22(11), 1356–1363.
1103 Balsamo, M., Cataldi, F., Carlucci, L„ & Fairfield, B. (2018). Assessment of anxiety in older adults: A review of self-report measures. Clinical Interventions in Aging, 13, 573–593.29670342
1104 Wuthrich, V. M., Johnco, C. & Knight, A. (2014). Comparison of the Penn State Worry Questionnaire (PSWQ) and abbreviated version (PSWQ-A) in a clinical and non-clinical population of older adults. Journal of Anxiety Disorders, 28(7), 657–663.25124502
1105 Pietrzak, R. H., Goldstein, R. B., Southwick, S. M. & Grant, B. F. (2012). Psychiatric comorbidity of full and partial posttraumatic stress disorder among older adults in the United States: Results from Wave 2 of the National Epidemiologic Survey on Alcohol and Related Conditions. American Journal of Geriatric Psychiatry, 20(5), 380–390.
1106 Satre, D. D., & Leibowitz, Α. (2015). Brief alcohol and drug interventions and motivational interviewing. In P. Areán (Ed.), Treatment of late-life depression, anxiety, trauma and substance abuse (pp. 163–180). Washington, DC: American Psychological Association.
1107 Satre, D. D., & Leibowitz, Α. (2015). Brief alcohol and drug interventions and motivational interviewing. In P. Areán (Ed.), Treatment of late-life depression, anxiety, trauma and substance abuse (pp. 163–180). Washington, DC: American Psychological Association.
1108 Oyebode, J. R. & Parveen, S. (2019). Psychosocial interventions for people with dementia: An overview and commentary on recent developments. Dementia (London), 78(1), 8–35.
1109 de Oliveira, A. M., Radanovic, M., de Mello, P. C., Buchain, P. C., Vizzotto, A. D., … Forlenza, O. V. (2015). Nonpharmacological interventionsto reduce behavioral and psychological symptoms of dementia: A systematic review. BioMed Research International, 218980.
1110 Bernabei, V., De Ronchi, D., La Ferla, T., Moretti, F., Tonelli, L., Ferrari, B. … Atti, A. R. (2013). Animal-assisted interventions for elderly patients affected by dementia or psychiatric disorders: A review. Journal of Psychiatric Research, 47(6), 762–773.23369337
1111 Rooney, R. F. (2014). Preventing dementia: How lifestyle in midlife affects risk. Current Opinion in Psychiatry, 27(2), 149–157.24441418
1112 Yaffe, K, & Hoang, T. (2013). Nonpharmacologic treatment and prevention strategies for dementia. Continuum (Minneapolis, Minnesota), 19(2 Dementia), 372–381.
1113 Cipriani, G., Lucetti, C., Danti, S., & Nuti, Α. (2015). Sleep disturbances and dementia. Psychogeriatrics, 75(1), 65–74.
1114 Lindauer, Α., Sexson, K„ & Harvath, T. A (2017). Medication management for people with dementia. American Journal of Nursing, 777(2), 60–64.
1115 AARP and National Alliance for Caregiving. (2020). Caregiving in the U.S. 2020. Retrieved from www.caregiving.org/caregiving-in-the-us-2020/
1116 National Association of Social Workers. (2010). NASW standards for social work practice with family caregivers of older adults. Retrieved from www.socialworkers.org/LinkClick.aspx?fileticket=aUwQL98exRM%3d&portalid=0
1117 Chiao, C. Y., Wu, H. S. & Hsiao, C. Y. (2015). Caregiver burden for informal caregivers of patients with dementia: A systematic review. International Nursing Review, 62(3), 340–350.26058542
1118 Moon, H„ & Dilworth-Anderson, P. (2015). Baby boomer caregiver and dementia caregiving: Findings from the National Study of Caregiving. Age and Ageing, 44(2), 300–306.25359299
1119 Dong, X., Chen, R„ & Simon, M.A. (2014). Elder abuse and dementia: A review of the research and health policy. Health Affairs (Millwood), 33(4), 642–649.
1120 Perkins, M., Howard, V. J., Wadley, V. G., Crowe, M., Safford, Μ. M., Haley, W. E. … Roth, D. L. (2013). Caregiving strain and all-cause mortality: Evidence from the REGARDS study. Journal of Gerontology, Series B, Psychological Sciences and Social Sciences, 68(4), 504–512.
1121 Kim, Y., Carver, C. S., Cannady, R. S. & Shaffer, Κ. M. (2013). Self-reported medical morbidity among informal caregivers of chronic illness: The case of cancer. Quality of Life Research, 22(6), 1265–1272.22907603
1122 Fonareva, I., & Oken, B. S. (2014). Physiological and functional consequences of caregiving for relatives with dementia. International Psychogeriatrics, 26(5), 725–747.24507463
1123 Martín-Carrasco, M., Ballesteros-Rodríguez, J., Domínguez-Panchón, Α. I., Muñoz-Hermoso, P., & González-Fraile, E. (2014). Interventions for caregivers of patients with dementia. Actas Españolas de Psiquiatría, 42(6), 300–314.25388772
1124 Brodaty, Η., & Donkin, M. (2009). Family caregivers of people with dementia. Dialogues in Clinical Neuroscience, 77(2), 217–228.
1125 Gilhooly, K. J., Gilhooly, M. L., Sullivan, M. P., Mclntyre, Α., Wilson, L., Harding, E. … Crutch, S. (2016). A meta-review of stress, coping and interventions in dementia and dementia caregiving. BMC Geriatrics, 16, 106.27193287
1126 Sattar, S. P., Padala, P. R., McArthur-Miller, D., Roccaforte, W. H., Wengel, S. P., & Burke, W. J. (2007). Impact of problem alcohol use on patient behavior and caregiver burden in a geriatric assessment clinic. Journal of Geriatric Psychiatry and Neurology, 20(2), 120–127.17548783
1127 García-Fernández, F. P., Arrabal-Orpez, M. J., Rodriguez-Torres Mdel, C., Gila-Selas, C., Carrascosa-García, I., & Laguna-Parras, J. M. (2014). Effect of hospital case-manager nurses on the level of dependence, satisfaction and caregiver burden in patients with complex chronic disease. Journal of Clinical Nursing, 23(19-20), 2814–2821.24479812
1128 Labrum, T. (2018). Caregiving for relatives with psychiatric disorders vs. co-occurring psychiatric and substance use disorders. Psychiatric Quarterly, 89(3), 631–644.29417307
1129 Yesavage, J. A. (n.d.). Geriatric Depression Scale. Retrieved from https://web.stanford.edu/~yesavage/GDS.html
1130 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 47(11), 15–21.
1131 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 47(11), 15–21.
1132 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 47(11), 15–21.
1133 Weathers, F. W., Litz, B. T., Keane, T. M., Palmieri, P. Α., Marx, B. P., & Schnurr, P. P. (2013). The PTSD Checklist for DSM-5 (PCL-5). Retrieved from https://www.ptsd.va.gov/professional/assessment/adult-sr/ptsd-checklist.asp
1134 Family Caregiver Alliance. (2019). Caregiver statistics: Demographics. Retrieved from www.caregiver.org/caregiver-statistics-demographics
1135 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
1136 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
1137 Satre, D. D., Chi, F. W., Mertens, J. R., & Weisner, C. M. (2012). Effects of age and life transitions on alcohol and drug treatment outcome over nine years. Journal of Studies on Alcohol and Drugs, 73(3), 459–468.22456251
1138 Nicholson, N. R. (2012). A review of social isolation: An important but underassessed condition in older adults. Journal of Primary Prevention, 33(2-3), 137–152.22766606
1139 Koenig, H. G. (2015). Religion, spirituality, and health: A review and update. Advances, 29(3), 19–26.26026153
1140 Zimmer, Z., Jagger, C., Chiu, C. T., Ofstedal, M. B., Rojo, F., & Saito, Y. (2016). Spirituality, religiosity, aging and health in global perspective: A review. SSM-Population Health, 2, 373–381.29349154
1141 Zimmer, Z., Jagger, C., Chiu, C. T., Ofstedal, M. B., Rojo, F., & Saito, Y. (2016). Spirituality, religiosity, aging and health in global perspective: A review. SSM-Population Health, 2, 373–381.29349154
1142 Koenig, H. G. (2012). Religion, spirituality, and health: The research and clinical implications. ISRN Psychiatry, 2012, 278730.23762764
1143 Zimmer, Z., Jagger, C., Chiu, C. T., Ofstedal, M. B., Rojo, F., & Saito, Y. (2016). Spirituality, religiosity, aging and health in global perspective: A review. SSM-Population Health, 2, 373–381.29349154
1144 Kim, S., Spilman, S. L., Liao, D. H., Sacco, P., & Moore, A. A. (2018). Social networks and alcohol use among older adults: A comparison with middle-aged adults. Aging and Mental Health, 22(4), 550–557.28006983
1145 Cohen-Mansfield, J., Hazan, H., Lerman, Y., & Shalom, V. (2016). Correlates and predictors of loneliness in older-adults: A review of quantitative results informed by qualitative insights. International Psychogeriatrics, 28(4), 557–576.26424033
1146 Gardiner, C., Geldenhuys, G., & Gott, M. (2018). Interventions to reduce social isolation and loneliness among older people: An integrative review. Health and Social Care in the Community, 26(2), 147–157.27413007
1147 Nicholson, N. R. (2012). A review of social isolation: An important but underassessed condition in older adults. Journal of Primary Prevention, 33(2-3), 137–152.22766606
1148 Mannes, Z. L., Burrell, L. E., Bryant, V. E., Dunne, E. M., Hearn, L. E., & Whitehead, N. E. (2016). Loneliness and substance use: The influence of gender among HIV+ Black/African American adults 50+. AIDS Care, 28(5), 598–602.26654243
1149 Rainer, J. P. (2013). Life after loss: Contemporary grief counseling and therapy. Eau Claire, WI: PESI Publishing & Media.
1150 Winokuer, H. R., & Harris, D. L. (2015). Principles and practice of grief counseling (2nd ed.). New York, NY: Springer.
1151 Nicholson, N. R. (2012). A review of social isolation: An important but underassessed condition in older adults. Journal of Primary Prevention, 33(2-3), 137–152.22766606
1152 Wethington, E., & Pillemer, K. (2014). Social isolation among older people. In R. J. Coplan & J. C. Bowker (Eds.), The handbook of solitude: Psychological perspectives on social isolation, social withdrawal, and being alone (pp. 242–259). Chichester, England: Wiley-Blackwell.
1153 Bhatti, A. B., & Haq, A. U. (2017). The pathophysiology of perceived social isolation: Effects on health and mortality. Cureus, 9(1), e994. doi:10.7759/cureus.994 28382237
1154 Cacioppo, J. T., Hawkley, L. C., Norman, G. J., & Berntson, G. G. (2011). Social isolation. Annals of the New York Academy of Sciences, 1231, 17–22.21651565
1155 Bhatti, A. B., & Haq, A. U. (2017). The pathophysiology of perceived social isolation: Effects on health and mortality. Cureus, 9(1), e994. doi:10.7759/cureus.994 28382237
1156 Cacioppo, J. T., Hawkley, L. C., Norman, G. J., & Berntson, G. G. (2011). Social isolation. Annals of the New York Academy of Sciences, 1231, 17–22.21651565
1157 Wethington, E., & Pillemer, K. (2014). Social isolation among older people. In R. J. Coplan & J. C. Bowker (Eds.), The handbook of solitude: Psychological perspectives on social isolation, social withdrawal, and being alone (pp. 242–259). Chichester, England: Wiley-Blackwell.
1158 Bhatti, A. B., & Haq, A. U. (2017). The pathophysiology of perceived social isolation: Effects on health and mortality. Cureus, 9(1), e994. doi:10.7759/cureus.994 28382237
1159 Nicholson, N. R. (2012). A review of social isolation: An important but underassessed condition in older adults. Journal of Primary Prevention, 33(2–3), 137–152.22766606
1160 Doukas, N. (2017). Older adults prescribed methadone for opiate replacement therapy: A literature review. Journal of Addiction and Preventive Medicine, 2(1), 1–6.
1161 Wethington, E., & Pillemer, K. (2014). Social isolation among older people. In R. J. Coplan & J. C. Bowker (Eds.), The handbook of solitude: Psychological perspectives on social isolation, social withdrawal, and being alone (pp. 242–259). Chichester, England: Wiley-Blackwell.
1162 Gouveia, O. M. R., Matos, A. D., & Schouten, M. J. (2016). Social networks and quality of life of elderly persons: A review and critical analysis of literature. Revista Brasileira de Geriatria e Gerontologia, 19, 1030–1040.
1163 Gardiner, C., Geldenhuys, G., & Gott, M. (2018). Interventions to reduce social isolation and loneliness among older people: An integrative review. Health and Social Care in the Community, 26(2), 147–157.27413007
1164 Gardiner, C., Geldenhuys, G., & Gott, M. (2018). Interventions to reduce social isolation and loneliness among older people: An integrative review. Health and Social Care in the Community, 26(2), 147–157.27413007
1165 Momtaz, Y. A., Haron, S. A., Ibrahim, R., & Hamid, T. A. (2014). Social embeddedness as a mechanism for linking social cohesion to well-being among older adults: Moderating effect of gender. Clinical Interventions in Aging, 9, 863–870.24904206
1166 Jackson, S. L. (2014). All elder abuse perpetrators are not alike: The heterogeneity of elder abuse perpetrators and implications for intervention. International Journal of Offender Therapy and Comparative Criminology, 60(3), 265–285.25326465
1167 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
1168 Reif, S., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., … Delphin-Rittmon, M. E. (2014). Peer recovery support for individuals with substance use disorders: Assessing the evidence. Psychiatric Services, 65(7), 853–861.24838535
1169 Stevens, E., Jason, L. A., Ram, D., & Light, J. (2015). Investigating social support and network relationships in substance use disorder recovery. Substance Abuse, 36(4), 396–399.25259558
1170 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
1171 Center for Substance Abuse Treatment. (2009). What are peer recovery support services? HHS Publication No. (SMA) 09-4454. Retrieved from https://store.samhsa.gov/product/What-Are-Peer-Recovery-Support-Services-/SMA09-4454
1172 Gardiner, C., Geldenhuys, G., & Gott, M. (2018). Interventions to reduce social isolation and loneliness among older people: An integrative review. Health and Social Care in the Community, 26(2), 147–157.27413007
1173 Leist, A. K. (2013). Social media use of older adults: A mini-review. Gerontology, 59(4), 378–384.23594915
1174 Anderson, M., & Perrin, A. (2017). Tech adoption climbs among older adults. Retrieved June 13, 2019, from http://assets.pewresearch.org/wp-content/uploads/sites/14/2017/05/16170850/PI_2017.05.17_Older-Americans-Tech_FINAL.pdf
1175 Kuerbis, A., Mulliken, A., Muench, F., Moore, A. A., & Gardner, D. (2017). Older adults and mobile technology: Factors that enhance and inhibit utilization in the context of behavioral health. Mental Health and Addiction Research, 2(2), 1–11.
1176 Fang, M. L., Canham, S. L., Battersby, L., Sixsmith, J., Wada, M., & Sixsmith, A. (2019). Exploring privilege in the digital divide: Implications for theory, policy, and practice. Gerontologist, 59(1), e1–e15.29750241
1177 Federal Communications Commission. (2018). 2018 broadband deployment report. Retrieved from www.fcc.gov/reports-research/reports/broadband-progress-reports/2018-broadband-deployment-report
1178 Chernick, R., & Kuerbis, A. (2016). Social and familial contexts for drinking among older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 149–166). New York, NY: Springer.
1179 Fishleder, S., Schonfeld, L., Corvin, J., Tyler, S., & VandeWeerd, C. (2016). Drinking behavior among older adults in a planned retirement community: Results from The Villages survey. International Journal of Geriatric Psychiatry, 31(5), 536–543.26436200
1180 Kobrin, M. (2019). Promoting wellness for better behavioral and physical health. Retrieved from https://mfpcc.samhsa.gov/ENewsArticles/Article12b2017.aspx
1181 McMahon, S., & Fleury, J. (2012). Wellness in older adults: A concept analysis. Nursing Forum, 47(1), 39–51.22309381
1182 Kobrin, M. (2019). Promoting wellness for better behavioral and physical health. Retrieved from https://mfpcc.samhsa.gov/ENewsArticles/Article12b2017.aspx
1183 Substance Abuse and Mental Health Services Administration. (2016). Learn the eight dimensions of wellness. Retrieved from https://store.samhsa.gov/product/Learn-the-Eight-Dimensions-of-Wellness-Poster-/SMA16-4953
1184 Gerontological Society of America. (2012). Communicating with older adults: An evidence-based review of what really works. Retrieved from www.changetogether.com/app/uploads/2016/03/GSA_Communicating-with-Older-Adults-high-Final.pdf
1185 Satre, D. D., & Leibowitz, A. (2015). Brief alcohol and drug interventions and motivational interviewing. In P. Areán (Ed.), Treatment of late-life depression, anxiety, trauma and substance abuse (pp. 163–180). Washington, DC: American Psychological Association.
1186 Cummings, S. M., Cooper, R. L., & Cassie, K. M. (2009). Motivational interviewing to affect behavioral change in older adults. Research on Social Work Practice, 19(2), 195–204.
1187 Purath, J., Keck, A., & Fitzgerald, C. E. (2014). Motivational interviewing for older adults in primary care: A systematic review. Geriatric Nursing, 35(3), 219–224.24656051
1188 Cherniack, E. P., & Cherniack, A. R. (2014). The benefit of pets and animal-assisted therapy to the health of older individuals. Current Gerontology and Geriatrics Research, 2014, 1–9.
1189 Harvard Women's Health Watch. (2015). The health benefits of tai chi. Retrieved from www.health.harvard.edu/staying-healthy/the-health-benefits-of-tai-chi
1190 Hackney, M. E. & Wolf, S. L. (2014). Impact of Tai Chi Chu'an practice on balance and mobility in older adults: An integrative review of 20 years of research. Journal of Geriatric Physical Therapy, 37(3), 127–135.24406709
1191 Irwin, M. R., Olmstead, R. & Motivala, S. J. (2008). Improving sleep quality in older adults with moderate sleep complaints: A randomized controlled trial of Tai Chi Chih. Sleep, 37(7), 1001–1008.
1192 Fountain-Zaragoza, S., & Prakash, R. S. (2017). Mindfulness training for healthy aging: Impact on attention, well-being, and inflammation. Frontiers in Aging Neuroscience, 9, 1–15.28174533
1193 Krause, Ν., & Hayward, R. D. (2014). Religious involvement, practical wisdom, and self-rated health. Journal of Aging and Health, 26(4), 540–558.24619064
1194 Kelly, J. F., Stout, R. L., Magill, M., Tonigan, J. S., & Pagano, Μ. E. (2011). Spirituality in recovery: A lagged mediational analysis of Alcoholics Anonymous' principal theoretical mechanism of behavior change. Alcoholism, Clinical and Experimental Research, 35(3), 454–463.21158876
1195 Zimmer, Z., Jagger, C., Chiu, C. T., Ofstedal, M. B., Rojo, F., & Saito, Y. (2016). Spirituality, religiosity, aging and health in global perspective: A review. SSM-Population Health, 2, 373–381.29349154
1196 Ponnuswami, I., Francis, Α., & Udhayakumar, P. (2012). Strengths-based approach to social work practice with older persons. Retrieved from www.academia.edu/3470933/Strengths-basedApproachtoSocialWorkPracticewithOlderPersons
1197 National Council on Aging. (2016). Fact sheet: Chronic disease self-management. Arlington, VA: National Council on Aging. Retrieved from www.ncoa.org/resources/fact-sheet-cdsmp
1198 Schulman-Green, D., Jaser, S. S., Park, C., & Whittemore, R. (2016). A metasynthesis of factors affecting self-management of chronic illness. Journal of Advanced Nursing, 72(7), 1469–1489.26781649
1199 National Council on Aging. (2016). Fact sheet: Chronic disease self-management. Arlington, VA: National Council on Aging. Retrieved from www.ncoa.org/resources/fact-sheet-cdsmp
1200 Erdem, E., & Korda, H. (2014). Self-management program participation by older adults with diabetes: Chronic Disease Self-Management Program and Diabetes Self-Management Program. Family and Community Health, 37(2), 134–146.24569159
1201 Satre, D. D., Mertens, J. R., Areán, P. Α., & Weisner, C. (2004). Five-year alcohol and drug treatment outcomes of older adults versus middle-aged and younger adults in a managed care program. Addiction, 99(10), 1286–1297.15369567
1202 Litt, M. D., Kadden, R. M., Kabela-Cormier, E., & Petry, N. M. (2009). Changing network support for drinking: Network Support Project 2-year follow-up. Journal of Consulting and Clinical Psychology, 77(2), 229–242.19309183
1203 Davidoff, J., Higgins, R., & Kipnis, S. (2004). Working with aging client populations: Preventing, identifying and treating alcohol, and substance abuse and supporting recovery [Presentation slides]. Retrieved June 1, 2019, from https://omh.ny.gov/omhweb/geriatric/resources.html
1204 Davidoff, J., Higgins, R„ & Kipnis, S. (2004). Working with aging client populations: Preventing, identifying and treating alcohol & substance abuse and supporting recovery [Presentation slides]. Retrieved June 1, 2019, from https://omh.ny.gov/ornhweb/geriatric/resources.html
1205 Schonfeld, L„ & MacFarland, N. S. (2015). Relapse prevention treatment for substance abuse disorders in older adults. In P. A. Areán (Ed.), Treatment of late-life depression, anxiety, trauma, and substance abuse (pp. 211–234). Washington, DC: American Psychological Association.
1206 Burzinski, C. Α., & Zgierska, A. (2014). Reducing relapse risk: Clinical tool. Retrieved from http://projects.hsl.wisc.edu/SERVICE/modules/35/M35CTReducingRelapseRisk.pdf
1207 Alim, T. N., Lawson, W. Β., Feder, Α., lacoviello, Β. M., Saxena, S., Bailey, C. R., … Neumeister, Α. (2012). Resilience to meet the challenge of addiction: Psychobiology and clinical considerations. Alcohol Research: Current Reviews, 34(4), 506–515.23584116
1208 Nilsson, H., Bülow, P. H. & Kazemi, A. (2015). Mindful sustainable aging: Advancing a comprehensive approach to the challenges and opportunities of old age. Europe's Journal of Psychology, 77(3), 494–508.
1209 American Psychological Association. (2014). Guidelines for psychological practice with older adults. American Psychologist, 69(1), 34–65.24446841
1210 Hildon, Z., Smith, G., Netuveli, G„ & Blane, D. (2008). Understanding adversity and resilience at older ages. Sociology of Health and Illness, 30(5), 726–740.18444953
1211 Walter, C. Α., & McCoyd, J. L. M. (2015). Grief and loss across the lifespan: A biopsychosocial perspective (2nd ed.). New York, NY: Springer.
1212 Slosser, A., McKibbin, C., Lee, A., Bourassa, K., & Carrico, C. (2015). Perceived health status and social network as predictors of resilience in rural older adults. Retrieved from www.uwyo.edu/wycoa/files/powerpoints/asgsa%20poster%202015.pdf
1213 American Psychological Association. (2018). Building your resilience. Retrieved from www.apa.org/helpcenter/road-resilience
1214 Lavretsky, H. (2014). Resilience and aging: Research and practice. Baltimore, MD: Johns Hopkins University Press.
1215 Bovend'Eerdt, T. J. H., Botell, R. E., & Wade, D. T. (2009). Writing SMART rehabilitation goals and achieving goal attainment scaling: A practical guide. Clinical Rehabilitation, 23(4), 352–361.19237435
1216 National Committee for Quality Assurance. (2016). Goals to care: How to keep the person in “person-centered.” Retrieved from www.ncqa.org/Portals/0/Programs/Goals%20to%20Care%20-%20Spotlight%20Report.pdf?ver=2016-02-23-113526-113
1217 Tracy, E., & Whittaker, J. (1990). The Social Network Map: Assessing social support in clinical practice. Families in Society, 71, 461–470.
1218 Tracy, E., & Whittaker, J. (1990). The Social Network Map: Assessing social support in clinical practice. Families in Society, 71, 461–470.
1219 Tracy, E., & Whittaker, J. (1990). The Social Network Map: Assessing social support in clinical practice. Families in Society, 71, 461–470.
1220 Tracy, E., & Whittaker, J. (1990). The Social Network Map: Assessing social support in clinical practice. Families in Society, 71, 461–470.
1221 Tracy, E., & Whittaker, J. (1990). The Social Network Map: Assessing social support in clinical practice. Families in Society, 71, 461–470.
1222 Lubben, J., & Gironda, M. (2004). Measuring social networks and assessing their benefits. In C. Phillipson, G. Allan, & D. Morgan (Eds.), Social networks and social exclusion: Sociological and policy perspectives (pp. 20–35). Aldershot, England: Ashgate.
1223 Lubben, J., Blozik, E., Gillmann, G., Iliffe, S., von Renteln Kruse, W., Beck, J. C., & Stuck, A. E. (2006). Performance of an abbreviated version of the Lubben Social Network Scale among three European community-dwelling older adult populations. Gerontologist, 46(4), 503–513.16921004
1224 Lubben, J., Blozik, E., Gillmann, G., Iliffe, S., von Renteln Kruse, W., Beck, J. C., & Stuck, A. E. (2006). Performance of an abbreviated version of the Lubben Social Network Scale among three European community-dwelling older adult populations. Gerontologist, 46(4), 503–513.16921004
1225 Gabrielson, M. L., & Holston, E. C. (2014). Broadening definitions of family for older lesbians: Modifying the Lubben Social Network Scale. Journal of Gerontological Social Work, 57(2–4), 198–217.24571296
1226 White, A. M., Philogene, G. S., Fine, L., & Sinha, S. (2009). Social support and self-reported health status of older adults in the United States. American Journal of Public Health, 99(10), 1872–1878.19696390
1227 Hwang, E. H., & Peralta-Catipon, T. (2016). Health Enhancement Lifestyle Profile (HELP) & HELP Screener: Older adult version; Guide for clinicians. Domínguez Hills, CA: California State University. Retrieved from www.csudh.edu/Assets/csudh-sites/ot/docs/3%20_Health%20Enhancement%20Lifestyle%20Profile%20(HELP)-Guide%20for%20Clinicians-2016.pdf
1228 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
1229 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
1230 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
1231 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
1232 Kok, R. M. (2014). Treatment of alcohol use disorders in the elderly: An overview of RCTs. International Psychogeriatrics, 26(11), 1767–1770.25188542
1233 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
1234 Schutte, K. K., Moos, R. H., & Brennan, P. L. (2006). Predictors of untreated remission from late-life drinking problems. Journal of Studies on Alcohol, 67(3), 354–362.16608144
1235 American Public Health Association & Education Development Center. (2008). Alcohol screening and brief intervention: A guide for public health practitioners. Washington, DC: National Highway Traffic Safety Administration, Department of Transportation.
1236 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
1237 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
1238 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
1239 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
1240 Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/healthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
1241 Family Caregiver Alliance. (2019). Caregiver statistics: Demographics. Retrieved from www.caregiver.org/caregiver-statistics-demographics
1242 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
1243 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
1244 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
1245 Centers for Disease Control and Prevention. (2018). Alcohol and Public Health. Frequently Asked Questions. Retrieved from www.cdc.gov/alcohol/faqs.htm
1246 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
1247 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
1248 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
1249 Centers for Disease Control and Prevention. (2018). Alcohol and Public Health. Frequently Asked Questions. Retrieved from www.cdc.gov/alcohol/faqs.htm
1250 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
1251 Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/ealthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
1252 Downer, B., & Boron, J. B. (2016). Alcohol and cognition. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 79–96). New York, NY: Springer.
1253 Downer, B., & Boron, J. B. (2016). Alcohol and cognition. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 79–96). New York, NY: Springer.
1254 National Institute on Alcohol Abuse and Alcoholism. (2015). Beyond hangovers: Understanding alcohol's impact on your health. NIH Publication No. 15–7604. Rockville, MD: National Institute on Alcohol Abuse and Alcoholism.
1255 GBD 2016 Collaborators. (2018). Alcohol use and burden for 195 countries and territories, 1990–2016: A systematic analysis for the Global Burden of Disease Study 2016. Lancet, 392(10152), 1015–1035.30146330
1256 Substance Abuse and Mental Health Services Administration. (2012). Older Americans Behavioral Health Issue Brief 2: Alcohol misuse and abuse prevention (p. 1). Retrieved from www.acl.gov/sites/default/files/programs/2016-11/Issue%20Brief%202%20Alcohol%20Misuse.pdf
1257 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
1258 Substance Abuse and Mental Health Services Administration. (2012). Older Americans Behavioral Health Issue Brief 2: Alcohol misuse and abuse prevention (p. 1). Retrieved from www.acl.gov/sites/default/files/programs/2016-11/Issue%20Brief%202%20Alcohol%20Misuse.pdf
1259 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
1260 Substance Abuse and Mental Health Services Administration. (2012). Older Americans Behavioral Health Issue Brief 2: Alcohol misuse and abuse prevention (p. 1). Retrieved from www.acl.gov/sites/default/files/programs/2016-11/Issue%20Brief%202%20Alcohol%20Misuse.pdf
1261 Leggett, A., Kavanagh, J., Zivin, K., Chiang, C., Kim, H. M., & Kales, H. C. (2015). The association between benzodiazepine use and depression outcomes in older veterans. Journal of Geriatric Psychiatry and Neurology, 28(4), 281–287.26269493
1262 Substance Abuse and Mental Health Services Administration. (2012). Older Americans Behavioral Health Issue Brief 2: Alcohol misuse and abuse prevention (p. 1). Retrieved from www.acl.gov/sites/default/files/programs/2016-11/Issue%20Brief%202%20Alcohol%20Misuse.pdf
1263 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
1264 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
1265 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2016). Alcohol, injury, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 97–115). New York, NY: Springer.
1266 Addiction Technology Transfer Center Network. (2001). A stomach enzyme deficit may place women at more risk from drinking alcohol. Retrieved from www.eurekalert.org/pubreleases/2001-04/ACER-Ased-1404101.php
1267 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
1268 Bommersbach, T. J., Lapid, M. I., Rummans, T. A., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
1269 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2016). Alcohol, injury, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 97–115). New York, NY: Springer.
1270 Letizia, M., & Reinbolz, M. (2005). Identifying and managing acute alcohol withdrawal in the elderly. Geriatric Nursing, 26(3), 176–183.15973346
1271 Saitz, R. (2013). Brief intervention for unhealthy alcohol use. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 41–48). New York, NY: Springer.
1272 Epstein, E. E., Fischer-Elber, K., & Al-Otaiba, Z. (2007). Women, aging, and alcohol use disorders. Journal of Women and Aging, 19(1–2), 31–48.17588878
1273 Substance Abuse and Mental Health Services Administration. (2009). Substance abuse treatment: Addressing the specific needs of women. Treatment Improvement Protocol (TIP) Series 51. HHS Publication No. (SMA) 15-4426. Retrieved from https://store.samhsa.gov/product/TIP-51-Substance-Abuse-Treatment-Addressing-the-Specific-Needs-of-Women/SMA15-4426
1274 Alcohol Pharmacology Education Partnership. (n.d.). Gender differences in alcohol metabolism. Retrieved from https://sites.duke.edu/apep/module-1-gender-matters/content/content-gender-differences-in-alcohol-metabolism
1275 Epstein, E. E., Fischer-Elber, K., & Al-Otaiba, Z. (2007). Women, aging, and alcohol use disorders. Journal of Women and Aging, 19(1–2), 31–48.17588878
1276 Blow, F., & Barry, K. (2002). Use and misuse of alcohol among older women. Alcohol Research and Health: The Journal of the National Institute on Alcohol Abuse and Alcoholism, 26(4), 308–315.12875042
1277 Substance Abuse and Mental Health Services Administration. (2009). Substance abuse treatment: Addressing the specific needs of women. Treatment Improvement Protocol (TIP) Series 51. HHS Publication No. (SMA) 15-4426. Retrieved from https://store.samhsa.gov/product/TIP-51-Substance-Abuse-Treatment-Addressing-the-Specific-Needs-of-Women/SMA15-4426
1278 Olfson, M., King, M., & Schoenbaum, M. (2015). Benzodiazepine use in the United States. JAMA Psychiatry, 72(2), 136–142.25517224
1279 Satre, D. D., Mertens, J. R., & Weisner, C. (2004). Gender differences in treatment outcomes for alcohol dependence among older adults. Journal of Studies on Alcohol, 65(5), 638–642.15536774
1280 Wettlaufer, A. (2018). Can a label help me drink in moderation? A review of the evidence on standard drink labelling. Substance Use and Misuse, 53(4), 585–595.28937874
1281 National Institute on Alcohol Abuse and Alcoholism. (n.d.). What's a “standard” drink? Retrieved June 14, 2019, from www.rethinkingdrinking.niaaa.nih.gov/How-much-is-too-much/What-counts-as-a-drink/Whats-A-Standard-Drink.aspx
1282 Kuerbis, A., Chernick, R., & Gardner, D. S. (2016). Alcohol use and comorbid psychiatric and subsyndromal disorders among older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 35–53). New York, NY: Springer.
1283 Satre, D. D. (2015). Alcohol and drug use problems among older adults. Clinical Psychology: Science and Practice, 22, 238–254.
1284 Haighton, C. (2016). Thinking behind alcohol consumption in old age: Psychological and sociological reasons for drinking in old age. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 3–16). New York, NY: Springer.
1285 Kuerbis, A., Treloar Padovano, H., Shao, S., Houser, J., Muench, F. J., & Morgenstern, J. (2018). Comparing daily drivers of problem drinking among older and younger adults: An electronic daily diary study using smartphones. Drug and Alcohol Dependence, 183, 240–246.29306171
1286 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS. Pub. No. (SMA) 03–3824. Rockville, MD: Center for Substance Abuse Prevention, Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
1287 Kelly, S., Olanrewaju, O., Cowan, A., Brayne, C., & Lafortune, L. (2018). Alcohol and older people: A systematic review of barriers, facilitators and context of drinking in older people and implications for intervention design. PLoS One, 13(1), e0191189.29370214
1288 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
1289 Satre, D. D. (2015). Alcohol and drug use problems among older adults. Clinical Psychology: Science and Practice, 22, 238–254.
1290 Chernick, R., & Kuerbis, A. (2016). Social and familial contexts for drinking among older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 149–166). New York, NY: Springer.
1291 Canham, S. L., & Mauro, P. M. (2016). Self-medication with alcohol: Aging issues. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 201–214). New York, NY: Springer.
1292 Canham, S. L., & Mauro, P. M. (2016). Self-medication with alcohol: Aging issues. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 201–214). New York, NY: Springer.
1293 Blow, F. C., Brockmann, L. M., & Barry, K. L. (2004). Role of alcohol in late-life suicide. Alcoholism, Clinical and Experimental Research, 28(Suppl. 1), 48S–56S.15166636
1294 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
1295 Canham, S. L., & Mauro, P. M. (2016). Self-medication with alcohol: Aging issues. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 201–214). New York, NY: Springer.
1296 Gilson, K.-M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
1297 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS. Pub. No. (SMA) 03–3824. Rockville, MD: Center for Substance Abuse Prevention, Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
1298 DiBartolo, M. C., & Jarosinski, J. M. (2017). Alcohol use disorder in older adults: Challenges in assessment and treatment. Issues in Mental Health Nursing, 38(1), 25–32.27936333
1299 Gilson, K.-M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
1300 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS. Pub. No. (SMA) 03–3824. Rockville, MD: Center for Substance Abuse Prevention, Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
1301 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
1302 DiBartolo, M. C., & Jarosinski, J. M. (2017). Alcohol use disorder in older adults: Challenges in assessment and treatment. Issues in Mental Health Nursing, 38(1), 25–32.27936333
1303 Gilson, K.-M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
1304 Gilson, K.-M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
1305 Substance Abuse and Mental Health Services Administration & Food and Drug Administration. (2004). As you age: A guide to aging, medicines, and alcohol. Retrieved from www.fda.gov/drugs/resources-you/you-agea-guide-aging-medicines-and-alcohol
1306 Gilson, K.-M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
1307 Gilson, K.-M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
1308 Gilson, K.-M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
1309 Gilson, K.-M., Bryant, C., & Judd, F. (2017). Understanding older problem drinkers: The role of drinking to cope. Addictive Behaviors, 64, 101–106.27597130
1310 Gordon, A. J., Gordon, J. M., & Broyles, L. M. (2013). Medical consequences of unhealthy alcohol. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 107–118). New York, NY: Springer.
1311 World Health Organization. (2018). Alcohol. Retrieved from www.who.int/news-room/fact-sheets/detail/alcohol
1312 Barry, K. L., & Blow, F. C. (2016). Drinking over the lifespan: Focus on older adults. Alcohol Research, 38(1), 115–120.27159818
1313 GBD 2016 Collaborators. (2018). Alcohol use and burden for 195 countries and territories, 1990–2016: A systematic analysis for the Global Burden of Disease Study 2016. Lancet, 392(10152), 1015–1035.30146330
1314 Rehm, J., Gmel, G. E., Sr., Gmel, G., Hasan, O. S. M., Imtiaz, S., Popova, S., … Shuper, P. A. (2017). The relationship between different dimensions of alcohol use and the burden of disease—An update. Addiction, 112, 968–1001.28220587
1315 NIH Osteoporosis and Related Bone Disease National Resource Center. (n.d.). What people recovering from alcoholism need to know about osteoporosis. Retrieved from www.bones.nih.gov/health-info/bone/osteoporosis/conditions-behaviors/alcoholism
1316 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS Publication No. (SMA) 03–3824. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
1317 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2016). Alcohol, injury, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 97–115). New York, NY: Springer.
1318 Rehm, J., Gmel, G. E., Sr., Gmel, G., Hasan, O. S. M., Imtiaz, S., Popova, S., … Shuper, P. A. (2017). The relationship between different dimensions of alcohol use and the burden of disease—An update. Addiction, 112, 968–1001.28220587
1319 National Institute on Aging. (2017). Facts about aging and alcohol. Retrieved from www.nia.nih.gov/health/facts-about-aging-and-alcohol
1320 National Institute on Alcohol Abuse and Alcoholism. (n.d.). HIV/AIDS. Retrieved from www.niaaa.nih.gov/alcohol-health/special-populations-co-occurring-disorders/hivaids
1321 AIDSinfo. (n.d.). HIV and older people. Retrieved from https://aidsinfo.nih.gov/understanding-hiv-aids/fact-sheets/25/80/hiv-and-older-people
1322 Ford, C. L., Godette, D. C., Mulatu, M. S., & Gaines, T. L. (2015). Recent HIV testing prevalence, determinants, and disparities among U.S. older adult respondents to the Behavioral Risk Factor Surveillance System. Sexually Transmitted Diseases, 42(8), 405–410.26165428
1323 Rehm, J., Gmel, G. E., Sr., Gmel, G., Hasan, O. S. M., Imtiaz, S., Popova, S., … Shuper, P. A. (2017). The relationship between different dimensions of alcohol use and the burden of disease—An update. Addiction, 112, 968–1001.28220587
1324 Berkeley Wellness. (2017). Alcohol's benefits: New questions. Retrieved from www.berkeleywellness.com/self-care/preventive-care/article/alcohols-health-benefits-new-questions
1325 Andréasson, S., Chikritzhs, T., Dangardt, F., Holder, H., Naimi, T., & Stockwell T. (2014). Evidence about health effects of “moderate” alcohol consumption: Reasons for skepticism and public health implications. In Alcohol and society 2014 (pp. 6–23). Stockholm, Sweden: IOGT-NTO and Swedish Society of Medicine.
1326 Molina, P. E., Gardner, J. D., Souza-Smith, F. M., & Whitaker, A. M. (2014). Alcohol abuse: Critical pathophysiological processes and contribution to disease burden. Physiology (Bethesda, Maryland), 29(3), 203–215.
1327 Caputo, F., Vignoli, T., Leggio, L., Addolorato, G., Zoli, G., & Bernardi, M. (2012). Alcohol use disorders in the elderly: A brief overview from epidemiology to treatment options. Experimental Gerontology, 47, 411–416.22575256
1328 DiBartolo, M. C., & Jarosinski, J. M. (2017). Alcohol use disorder in older adults: Challenges in assessment and treatment. Issues in Mental Health Nursing, 38(1), 25–32.27936333
1329 Gordon, A. J., Gordon, J. M., & Broyles, L. M. (2013). Medical consequences of unhealthy alcohol. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 107–118). New York, NY: Springer.
1330 Rehm, J., Gmel, G. E., Sr Gmel, G., Hasan, O. S. M., Imtiaz, S., Popova, S., … Shuper, P. A. (2017). The relationship between different dimensions of alcohol use and the burden of disease—An update. Addiction, 112, 968–1001.28220587
1331 Savage, C. L., Finnell, D. S., & Choflet, A. (2016). Cancer, alcohol, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 65–77). New York, NY: Springer.
1332 Simou, E., Britton, J., & Leonardi-Bee, J. (2018). Alcohol and the risk of pneumonia: A systematic review and meta-analysis. BMJ Open, 8(8), 1–10.
1333 Elmets, C. A., Leonardi, C. L., Davis, D. M. R., Gelfand, J. M., Lichten, J., Mehta, N. N., … Menter, A. (2019). Joint AAD-NPF guidelines of care for the management and treatment of psoriasis with awareness and attention to comorbidities. Journal of the American Academy of Dermatology, 80, 1073–1113.30772097
1334 Li, S., Cho, E., Drucker, A. M., Qureshi, A. A., & Li, W. Q. (2017). Alcohol intake and risk of rosacea in US women. Journal of the American Academy of Dermatology, 76(6), 1061–1067.28434611
1335 Topiwala, A., & Ebmeier, K. P. (2018). Effects of drinking on late-life brain and cognition. Evidence-Based Mental Health, 21(1), 12–15.29273599
1336 Qato, D. M., Manzoor, B. S., & Lee, T. A. (2015). Drug-alcohol interactions in older U.S. adults. Journal of the American Geriatrics Society, 63(11), 2324–2331.26503899
1337 Breslow, R. A., Dong, C., & White, A. (2015). Prevalence of alcohol-interactive prescription medication use among current drinkers: United States, 1999 to 2010. Alcoholism, Clinical and Experimental Research, 39(2), 371–379.25597432
1338 Breslow, R. A., Dong, C., & White, A. (2015). Prevalence of alcohol-interactive prescription medication use among current drinkers: United States, 1999 to 2010. Alcoholism, Clinical and Experimental Research, 39(2), 371–379.25597432
1339 National Institute on Alcohol Abuse and Alcoholism. (2014). Harmful interactions: Mixing alcohol with medicines. Retrieved from www.niaaa.nih.gov/publications/brochures-and-fact-sheets/harmful-interactions-mixing-alcohol-with-medicines
1340 Meier, P., & Seitz, H. K. (2008). Age, alcohol metabolism and liver disease. Current Opinion in Clinical Nutrition and Metabolic Care, 11, 21–26.18090653
1341 National Institute on Alcohol Abuse and Alcoholism. (2014). Harmful interactions: Mixing alcohol with medicines. Retrieved from www.niaaa.nih.gov/publications/brochures-and-fact-sheets/harmful-interactions-mixing-alcohol-with-medicines
1342 Slattum, P. W., & Hassan, O. E. (2016). Medications, alcohol, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 117–129). New York, NY: Springer.
1343 National Institute on Alcohol Abuse and Alcoholism. (2014). Harmful interactions: Mixing alcohol with medicines. Retrieved from www.niaaa.nih.gov/publications/brochures-and-fact-sheets/harmful-interactions-mixing-alcohol-with-medicines
1344 Slattum, P. W., & Hassan, O. E. (2016). Medications, alcohol, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 117–129). New York, NY: Springer.
1345 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2016). Alcohol, injury, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 97–115). New York, NY: Springer.
1346 Drugs.com. (n.d.). Cough syrup DM (dextromethorphan) and alcohol/food interactions. Retrieved from www.drugs.com/food-interactions/dextromethorphan,cough-syrup-dm.html
1347 Arora, S., Baraona, E., & Lieber, C. S. (2000). Alcohol levels are increased in social drinkers receiving ranitidine. American Journal of Gastroenterology, 95(1), 208–213.10638585
1348 Weaver, M. (2013). Choices for patients and clinicians: Ethics and legal issues. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 195–206). New York, NY: Springer.
1349 Paquin, A. M., Zimmerman, K., & Rudolph, J. L. (2014) Risk versus risk: A review of benzodiazepine reduction in older adults. Expert Opinion on Drug Safety, 13(7), 919–934.24905348
1350 Choi, N. G., DiNitto, D. M., Marti, C. N., & Choi, B. Y. (2016). Alcohol, injury, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 97–115). New York, NY: Springer.
1351 Harrington, Α. (2013). Psychiatric comorbidity. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 119–128). New York, NY: Springer.
1352 Paquin, A. M., Zimmerman, K. & Rudolph, J. L. (2014) Risk versus risk: A review of benzodiazepine reduction in older adults. Expert Opinion on Drug Safety, 13(7), 919–934.24905348
1353 Gould, R. L., Coulson, M. C., Patel, N., Highton-Williamson, E., & Howard, R. J. (2014). Interventions for reducing benzodiazepine use in older people: Meta-analysis of randomised controlled trials. British Journal of Psychiatry, 204(2), 98–107.
1354 Choi, N. G., DiNitto, D. M., Marti, C. N. & Choi, Β. Y. (2016). Alcohol, injury, and aging. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 97–115). New York, NY: Springer.
1355 Gudin, J. Α., Mogali, S., Jones, J. D. & Comer, S. D. (2013). Risks, management, and monitoring of combination opioid, benzodiazepines, and/or alcohol use. Postgraduate Medicine, 125(4), 115–130.
1356 Gunderson, E. W. & Alford, D. P. (2013). Managing pain in the context of unhealthy alcohol use. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 93–105). New York, NY: Springer.
1357 Taheri, Α., Dahri, K., Chan, P., Shaw, M., Aulakh, Α., & Tashakkor, A. (2014). Evaluation of a symptom-triggered protocol approach to the management of alcohol withdrawal syndrome in older adults. Journal of the American Geriatrics Society, 62(8), 1551–1555.24962514
1358 Bommersbach, T. J., Lapid, M. I., Rummans, Τ. Α., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
1359 Long, D., Long, B. & Koyfman, A. (2017). The emergency medicine treatment of severe alcohol withdrawal. American Journal of Emergency Medicine, 35, 1005–1011.28188055
1360 Blondell, R. D. & Azadfard, M. (2013). Hospital management. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 207–220). New York, NY: Springer.
1361 Blondell, R. D. & Azadfard, M. (2013). Hospital management. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 207–220). New York, NY: Springer.
1362 Dixit, D., Endicott, J., Burry, L., Ramos, L., Yeung, S. Y., Devabhakthuni, S„ … Bulloch, M. N. (2016). Management of acute alcohol withdrawal syndrome in critically ill patients. Pharmacotherapy, 36(7), 797–822.27196747
1363 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
1364 Bommersbach, T. J., Lapid, Μ. I., Rummans, Τ. Α., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
1365 Eberly, Μ. E., Lockwood, A. G., Lockwood, S., & Davis, K. W. (2016). Outcomes after implementation of an alcohol withdrawal protocol at a single institution. Hospital Pharmacy, 51(9), 752–758.27803505
1366 Letizia, M., & Reinbolz, M. (2005). Identifying and managing acute alcohol withdrawal in the elderly. Geriatric Nursing, 26(3), 176–183.15973346
1367 Blondell, R. D. & Azadfard, M. (2013). Hospital management. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 207–220). New York, NY: Springer.
1368 National Institute on Alcohol Abuse and Alcoholism, (n.d.). Planning for change. Retrieved June 1, 2019, from www.rethinkingdrinking.niaaa.nih.gov/Thinking-about-a-change/lts-up-to-you/Planning-For-Change.aspx
1369 Hunter, C. L., Goodie, J. L., Oordt, M. S. & Dobmeyer, A. C. (2017). Alcohol and prescription medication misuse. In C. L. Hunt, J. L. Goodie, M. S. Oordt, & A. C. Dobmeyer (Eds.), Integrated behavioral health in primary care: Step-by-step guidance for assessment and intervention (pp. 175–186). Washington, DC: American Psychological Association.
1370 Miller, W. R. & Muñoz, R. F. (2013). Controlling your drinking: Tools to make moderation work for you (2nd ed.). New York, NY: Guildford Press.
1371 National Institute on Alcohol Abuse and Alcoholism. (2016). Rethinking drinking. NIH Publication No. 15–3770. Rockville, MD: National Institute on Alcohol Abuse and Alcoholism.
1372 National Institute on Aging, (n.d.). Getting help for alcohol problems. Retrieved from www.nia.nih.gov/health/getting-help-alcohol-problems
1373 National Institute on Alcohol Abuse and Alcoholism, (n.d.). Drinking tracker cards. Retrieved June 1, 2019, from www.rethinkingdrinking.niaaa.nih.gov/tools/Interactive-worksheets-and-more/Track-what-you-drink/Drinking-Tracker-Cards.aspx
1374 National Institute on Aging, (n.d.). Getting help for alcohol problems. Retrieved from www.nia.nih.gov/health/getting-help-alcohol-problems
1375 Alcoholics Anonymous. (2016). The Twelve Steps of Alcoholics Anonymous. Retrieved from www.aa.org/assets/en_US/smf-121_en.pdf
1376 Alcoholics Anonymous. (2017). Serving all alcoholics: Making the A.A. message accessible. Retrieved from www.aa.org/assets/en_US/f-107_servingallalcoholics.pdf
1377 Addiction Recovery Guide. (n.d.). Mobile apps for addiction. Retrieved from www.addictionrecoveryguide.org/resources/mobileapps
1378 Jewell, T. (2020). The best alcohol addiction recovery apps of 2020. Retrieved from www.healthline.com/health/addiction/top-alcoholism-iphone-android-apps#nomo
1379 Jewell, T. (2020). The best alcohol addiction recovery apps of 2020. Retrieved from www.healthline.com/health/addiction/top-alcoholism-iphone-android-apps#nomo
1380 Castle, N., Smith, M. L., & Wolf, D. G. (2016). Long-term care and alcohol use. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 233–246). New York, NY: Springer.
1381 Han, B. H., & Moore, A. A. (2018). Prevention and screening of unhealthy substance use by older adults. Clinics in Geriatric Medicine, 34, 117–129.29129212
1382 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS. Pub. No. (SMA) 03–3824. Rockville, MD: Center for Substance Abuse Prevention, Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
1383 Moore, A. A., Kuerbis, A., Sacco, P., Chen, G. I., & Garcia, M. B. (2016). Screening and assessment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 169–180). New York, NY: Springer.
1384 Barry, K. L., & Blow, F. C. (2010). Screening, assessing and intervening for alcohol and medication misuse in older adults. In P. A. Lichtenberg (Ed.), Handbook of assessment in clinical gerontology (pp. 307–330). Burlington, MA: Elsevier.
1385 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Why do different people need different options? Retrieved from https://alcoholtreatment.niaaa.nih.gov/what-to-know/different-people-different-options
1386 Substance Abuse and Mental Health Services Administration, & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
1387 Moore, A. A., Kuerbis, A., Sacco, P., Chen, G. I., & Garcia, M. B. (2016). Screening and assessment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 169–180). New York, NY: Springer.
1388 Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
1389 Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
1390 Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
1391 Knopf, A. (2011, May 15). Some experts charge centers that avoid drug treatments with shunning science and ethics. Addiction Professional, 9(3).
1392 National Institute on Alcohol Abuse and Alcoholism. (2014). Treatment for alcohol problems: Finding and getting help. Retrieved from https://pubs.niaaa.nih.gov/publications/Treatment/treatment.htm#chapter04
1393 Moore, A. A., Kuerbis, A., Sacco, P., Chen, G. I., & Garcia, Maristela B. (2016). Screening and assessment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 169–180). New York, NY: Springer.
1394 Moore, A. A., Kuerbis, A., Sacco, P., Chen, G. I., & Garcia, M. B. (2016). Screening and assessment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 169–180). New York, NY: Springer.
1395 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–200). New York, NY: Springer.
1396 Dixit, D., Endicott, J., Burry, L., Ramos, L., Yeung, S. Y., Devabhakthuni, S„ … Bulloch, M. N. (2016). Management of acute alcohol withdrawal syndrome in critically ill patients. Pharmacotherapy, 36(7), 797–822.27196747
1397 Bommersbach, T. J., Lapid, M. I., Rummans, Τ. Α., & Morse, R. M. (2015). Geriatric alcohol use disorder: A review for primary care physicians. Mayo Clinic Proceedings, 90(5), 659–666.25939937
1398 McCarty, D., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., & Delphin-Rittmon, M. E. (2014). Substance abuse intensive outpatient programs: Assessing the evidence. Psychiatric Services (Washington, D.C), 65(6), 718–726.
1399 Rastegar, D. Α. (2013). Making effective referrals to specialty care. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 63–72). New York, NY: Springer.
1400 McCarty, D., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., & Delphin-Rittmon, Μ. E. (2014). Substance abuse intensive outpatient programs: Assessing the evidence. Psychiatric Services (Washington, D.C), 65(6), 718–726.
1401 McCarty, D., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., & Delphin-Rittmon, Μ. E. (2014). Substance abuse intensive outpatient programs: Assessing the evidence. Psychiatric Services (Washington, D.C), 65(6), 718–726.
1402 Rastegar, D. Α. (2013). Making effective referrals to specialty care. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 63–72). New York, NY: Springer.
1403 Mee-Lee, D., Shulman, G. D., Fishman, M. J., Gastfriend, D. R. & Miller, Μ. M. (Eds.). (2013). The ASAM Criteria: Treatment criteria for addictive, substance-related, and co-occurring conditions (3rd ed.). Carson City, NV: The Change Companies.
1404 Satre, D. D., Mertens, J., Areán, Ρ. Α., & Weisner, C. (2003). Contrasting outcomes of older versus middle-aged and younger adult chemical dependency patients in a managed care program. Journal of Studies on Alcohol, 64(4), 520–530.12921194
1405 Kuerbis, Α., & Sacco, P. (2013). A review of existing treatments for substance abuse among the elderly and recommendations for future directions. Substance Abuse: Research and Treatment, 7, 13–37.23471422
1406 MedLine Plus. (2017). Alcohol use disorder (AUD) treatment. Retrieved from https://medlineplus.gov/alcoholusedisorderaudtreatment.html
1407 Oslin, D. W. & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
1408 Petkus, A. J., & Wethereil, J. L. (2013). Acceptance and commitment therapy with older adults: Rationale and considerations. Cognitive and Behavioral Practice, 20, 47–56.26997859
1409 O'Farrell, T. J., & Clements, K. (2012). Review of outcome research on marital and family therapy in treatment for alcoholism. Journal of Marital and Family Therapy, 38(1), 122–144.22283384
1410 McHugh, R. K., Hearon, Β. Α., & Otto, M. W. (2010). Cognitive behavioral therapy for substance use disorders. Psychiatric Clinics of North America, 33(3), 511–525.20599130
1411 Kuerbis, Α., Sacco, P., Blazer, D. G. & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
1412 Rastegar, D. Α. (2013). Making effective referrals to specialty care. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 63–72). New York, NY: Springer.
1413 Substance Abuse and Mental Health Services Administration. (2013). Family therapy can help. HHS Publication No. (SMA) 13-4784. Retrieved from https://store.samhsa.gov/product/Farnily-Therapy-Can-Help-For-People-in-Recovery-From-Mental-lllness-or-Addiction/SMA15-4784
1414 Chawla, N., Collin, S., Bowen, S., Hsu, S., Grow, J., Douglass, Α., & Marlatt, G. A. (2010). The Mindfulness-Based Relapse Prevention Adherence and Competence Scale: Development, interrater reliability, and validity. Psychotherapy Research, 20(4), 388–397.20204916
1415 Miller, W. R. & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guildford Press.
1416 Amodeo, M„ & López, L. M. (2013). Making effective referrals to Alcoholics Anonymous and other 12-Step programs. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 73–83). New York, NY: Springer.
1417 Doyle, T. J., Peter D., Friedmann, P. D. & Zywiak, W. H. (2013). Management of patients with alcohol dependence in recovery: Options for maintenance and anticipating and managing relapse in primary care. In R. Saitz (Ed.), Addressing unhealthy alcohol use in primary care (pp. 85–92). New York, NY: Springer.
1418 National Institute on Alcohol Abuse and Alcoholism, (n.d.). Social support to stop drinking. Retrieved June 1, 2019, from www.rethinkingdrinking.niaaa.nih.gov/hinking-about-a-change/Support-for-quitting/Social-Support.aspx
1419 Substance Abuse and Mental Health Services Administration. (2013). Family therapy can help. HHS Publication No. (SMA) 13–4784. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/Family-Therapy-Can-Help-For-People-in-Recovery-From-Mental-Illness-or-Addiction/SMA15-4784
1420 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Tips to try. Retrieved June 14, 2019, from www.rethinkingdrinking.niaaa.nih.gov/Thinking-about-a-change/Strategies-for-cutting-down/Tips-To-Try.aspx
1421 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
1422 NAADAC, The Association for Addiction Professionals. (2014). Understanding the role of peer recovery coaches in the addiction profession. Retrieved from www.naadac.org/assets/2416/2014-05-01understanding_role_peer_recovery_coaches_webinarslides.pdf
1423 National Institute on Aging. (n.d.). Getting help for alcohol problems. Retrieved from www.nia.nih.gov/health/getting-help-alcohol-problems
1424 Hazelden Betty Ford Foundation. (2015, September 1). How do you talk to older adults who may be addicted? Retrieved from www.hazeldenbettyford.org/articles/how-to-talk-to-an-older-person-who-has-a-problem-with-alcohol-or-medications
1425 SeniorNavigator. (n.d.). Alcoholism and the older adult. Retrieved from https://seniornavigator.org/article/12411/alcoholism-and-older-adult%20%20
1426 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS Publication No. (SMA) 03-3824. Retrieved from https://store.samhsa.gov/product/Get-Connected-Linking-Older-Adults-with-Resources-on-Medication-Alcohol-and-Mental-Health-2019-Edition/SMA03-3824
1427 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
1428 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
1429 National Academies of Sciences, Engineering, and Medicine. (2016). Families caring for an aging America. Washington, DC: National Academies Press.
1430 Hazelden Betty Ford Foundation. (2015, September 1). How do you talk to older adults who may be addicted? Retrieved from www.hazeldenbettyford.org/articles/how-to-talk-to-an-older-person-who-has-a-problem-with-alcohol-or-medications
1431 Hazelden Betty Ford Foundation. (2019). How to talk about addiction: When a friend has a drinking or drug problem. Retrieved from www.hazeldenbettyford.org/articles/what-can-i-say-to-get-you-to-stop
1432 MedLine Plus. (2017). Helping a loved one with a drinking problem. Retrieved from https://medlineplus.gov/ency/patientinstructions/000815.htm
1433 Oslin, D. W., & Zanjani, F. (2016). Treatment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 181–199). New York, NY: Springer.
1434 HealthyAging.org (n.d.). Tools & Tips: Caregiver Self Assessment Questionnaire. Retrieved from www.healthinaging.org/tools-and-tips/caregiver-self-assessment-questionnaire
1435 MedLine Plus. (2017). Helping a loved one with a drinking problem. Retrieved from https://medlineplus.gov/ency/patientinstructions/000815.htm
1436 Hazelden Betty Ford Foundation. (2019). How to talk about addiction: When a friend has a drinking or drug problem. Retrieved from www.hazeldenbettyford.org/articles/what-can-i-say-to-get-you-to-stop
1437 Hazelden Betty Ford Foundation. (2019). How to talk about addiction: When a friend has a drinking or drug problem. Retrieved from www.hazeldenbettyford.org/articles/what-can-i-say-to-get-you-to-stop
1438 Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
1439 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
1440 Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/healthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
1441 U.S. Department of Health and Human Services & U.S. Department of Agriculture. (2015). 2015–2020 Dietary Guidelines for Americans (8th ed.). Retrieved from https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines
1442 National Institute on Alcohol Abuse and Alcoholism. (2017). Cocktail content calculator. Retrieved June 14, 2019, from www.rethinkingdrinking.niaaa.nih.gov/Tools/Calculators/cocktail-calculator.aspx
1443 Substance Abuse and Mental Health Services Administration. (2012). Older Americans Behavioral Health Issue Brief 2: Alcohol misuse and abuse prevention (p. 1). Retrieved from www.acl.gov/sites/default/files/programs/2016-11/Issue%20Brief%202%20Alcohol%20Misuse.pdf
1444 National Institute on Alcohol Abuse and Alcoholism. (n.d.). What's a “standard” drink? Retrieved from www.rethinkingdrinking.niaaa.nih.gov/How-much-is-too-much/What-counts-as-a-drink/Whats-A-Standard-Drink.aspx
1445 Blow, F. C., et al. (1998). Brief screening for alcohol problems in elderly populations using the Short Michigan Alcoholism Screening Test-Geriatric Version (SMAST-G). Hilton Head Island, SC: Research Society on Alcoholism Annual Scientific Meeting.
1446 American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing.
1447 Moore, A. A., Kuerbis, A., Sacco, P., Chen, G. I., & Garcia, M. B. (2016). Screening and assessment of unhealthy alcohol use in older adults. In A. Kuerbis, A. A. Moore, P. Sacco, & F. Zanjani (Eds.), Alcohol and aging: Clinical and public health perspectives (pp. 169–180). New York, NY: Springer.
1448 Barry, K. L., Blow, F. C., & Oslin, D. W. (2002). Substance abuse in older adults: Review and recommendations for education and practice in medical settings. Substance Abuse, 23(3 Suppl.), 105–131.
1449 Kuerbis, A., Sacco, P., Blazer, D. G., & Moore, A. A. (2014). Substance abuse among older adults. Clinics in Geriatric Medicine, 30(3), 629–654.25037298
1450 Barnes, A. J., Moore, A. A., Xu, H., Ang, A., Tallen, L., Mirkin, M., & Ettner, S. L. (2010). Prevalence and correlates of at-risk drinking among older adults: The Project SHARE study. Journal of General Internal Medicine, 25(8), 840–846.20396975
1451 Aalto, M., Alho, H., Halme, J. T., & Seppä, K. (2011). The Alcohol Use Disorders Identification Test (AUDIT) and its derivatives in screening for heavy drinking among the elderly. International Journal of Geriatric Psychiatry, 26(9), 881–885.20661878
1452 Barbor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). AUDIT: The Alcohol Use Disorders Identifcation Test: Guidelines for use in primary care (2nd ed., p. 17). Geneva, Switzerland: World Health Organization.
1453 Barbor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). AUDIT: The Alcohol Use Disorders Identifcation Test: Guidelines for use in primary care (2nd ed., p. 31). Geneva, Switzerland: World Health Organization.
1454 Aalto, M., Alho, H., Halme, J. T., & Seppä, K. (2011). The Alcohol Use Disorders Identification Test (AUDIT) and its derivatives in screening for heavy drinking among the elderly. International Journal of Geriatric Psychiatry, 26(9), 881–885.20661878
1455 Bush, K., Kivlahan, D. R., McDonell, M. B., Fihn, S. D., & Bradley, K. A. (1998). The AUDIT alcohol consumption questions (AUDIT-C): An effective brief screening test for problem drinking. Archives of Internal Medicine, 158, 1789–1795.9738608
1456 U.S. Department of Veterans Affairs. (n.d.). AUDIT-C Frequently Asked Questions. Retrieved from www.queri.research.va.gov/tools/alcohol-misuse/alcohol-faqs.cfm#top
1457 Purcell, B. (2003). Senior Alcohol Misuse Indicator. Toronto, Canada: Centre for Addiction and Mental Health, University of Toronto.
1458 Adamson, S. J., Kay-Lambkin, F. J., Baker, A. L., Lewin, T. J., Thornton, L., Kelly, B. J., & Sellman, J. D. (2010). An improved brief measure of cannabis misuse: The Cannabis Use Disorders Identification Test-Revised (CUDIT-R). Drug and Alcohol Dependence, 110, 137–143.20347232
1459 Adamson, S. J., Kay-Lambkin, F. J., Baker, A. L., Lewin, T. J., Thornton, L., Kelly, B. J., & Sellman, J. D. (2010). An improved brief measure of cannabis misuse: The Cannabis Use Disorders Identification Test-Revised (CUDIT-R). Drug and Alcohol Dependence, 110, 137–143.20347232
1460 Brown, R. L., & Rounds, L. A. (1995). Conjoint screening questionnaires for alcohol and other drug abuse: Criterion validity in a primary care practice. Wisconsin Medical Journal, 94(3), 135–140.7778330
1461 Substance Abuse and Mental Health Services Administration. (2011). Screening, brief intervention and referral to treatment (SBIRT) in behavioral healthcare. Retrieved from www.samhsa.gov/sites/default/files/sbirtwhitepaper0.pdf
1462 Friedmann, P. D. (2013). Alcohol use in adults. New England Journal of Medicine, 368(17), 1655–1656.
1463 Babor, T. F., & Higgins-Biddle, J. C. (2001). Brief intervention for hazardous and harmful drinking: A manual for use in primary care. Retrieved from https://apps.who.int/iris/handle/10665/67210
1464 Substance Abuse and Mental Health Services Administration. (2017). A guide to preventing older adult alcohol and psychoactive medication misuse/abuse: Screening and brief interventions (p. 87). Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from www.ncoa.org/wp-content/uploads/SBIRT-Older-Adult-Manual-Final.pdf
1465 VasMiadis, H. M., Chudzinski, V., Gontijo-Guerra, S., & Préville, M. (2015). The 10-item Kessler Psychological Distress Scale (K10) and the 7-item Generalized Anxiety Disorder Scale (GAD-7): Screening instruments for a population of older adults. Gerontologist, 55(Suppl. 2), 87.
1466 Spitzer, R. L., Kroenke, K., Williams, J. B. W. & Löwe, Β. Α. (2006). Brief measure for assessing generalized anxiety disorder: The GAD-7. Archives of Internal Medicine, 766(10), 1092–1097.
1467 Segal, D. L., June, Α., Payne, M., Coolidge, F. L. & Yochim, B. (2010). Development and initial validation of a self-report assessment tool for anxiety among older adults: The Geriatric Anxiety Scale. Journal of Anxiety Disorders, 24, 709–714.20558032
1468 Mueller, A. E., Segal, D. L., Gavett, B., Marty, Μ. Α., Yochim, B., June, Α., & Coolidge, F. L. (2015). Geriatric Anxiety Scale: Item response theory analysis, differential item functioning, and creation of a ten-item short form (GAS-10). International Psychogeriatrics, 27(7), 1099–1111.24576589
1469 Segal, D. L., June, Α., Payne, M., Coolidge, F. L. & Yochim, B. (2010). Development and initial validation of a self-report assessment tool for anxiety among older adults: The Geriatric Anxiety Scale. Journal of Anxiety Disorders, 24, 709–714.20558032
1470 Meyer, T., Miller, M., Metzger, R. & Borkovec, T. D. (1990). Development and validation of the Penn State Worry Scale. Behaviour Research and Therapy, 28, 487–495.2076086
1471 Therrien, Z., & Hunsley, J. (2012). Assessment of anxiety in older adults: A systematic review of commonly used measures. Aging and Mental Health, 76(1), 1–16.
1472 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 47(11), 15–21.
1473 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 47(11), 15–21.
1474 Brown, E. L., Raue, P. J., & Halpert, K. (2015). Evidence-based practice guideline: Depression detection in older adults with dementia. Journal of Gerontological Nursing, 47(11), 15–21.
1475 Yesavage, J. A. (n.d.). Geriatric Depression Scale. Retrieved from https://web.stanford.edu/~yesavage/GDS.html
1476 Phelan, E., Williams, B., Meeker, K., Bonn, K., Frederick, J., Logerfo, J., & Snowden, M. (2010). A study of the diagnostic accuracy of the PHQ-9 in primary care elderly. BMC Family Practice, 11, 63.20807445
1477 Richardson, T. M., He, H., Podgorski, C., Tu, X., & Conwell, Y. (2010). Screening for depression in aging services clients. American Journal of Geriatric Psychiatry, 78(12), 1116–1123.
1478 Richardson, T. M., He, H., Podgorski, C., Tu, X., & Conwell, Y. (2010). Screening for depression in aging services clients. American Journal of Geriatric Psychiatry, 78(12), 1116–1123.
1479 Kroenke, K., Spitzer, R. L. & Williams, J. B. (2001). The PHQ-9: Validity of a brief depression severity measure. Journal of General Internal Medicine, 76(9), 606–613.
1480 Kroene, K„ & Spitzer, R. L. (2002). The PHQ-9: A new depression diagnostic and severity measure. Psychiatric Annals, 32, 509–521.
1481 Richardson, T. M., He, H., Podgorski, C., Tu, X., & Conwell, Y. (2010). Screening for depression in aging services clients. American Journal of Geriatric Psychiatry, 78(12), 1116–1123.
1482 Hudson, S. Α., Beckford, L. Α., Jackson, S. D., & Philpot, M. P. (2008). Validation of a screening instrument for post-traumatic stress disorder in a clinical sample of older adults. Aging and Mental Health, 72(5), 670–673.
1483 Weathers, F. W., Litz, B. T., Herman, J. Α., Huska, J. Α., & Keane, T. M. (1993). The PTSD Checklist (PCL): Reliability, validity and diagnostic utility. Paper presented at the 9th Annual Conference of the International Society of Traumatic Stress Studies. San Antonio, Texas.
1484 Pietrzak, R. H., Van Ness, P. H., Fried, T. R., Galea, S. & Norris, F. (2012). Diagnostic utility and factor structure of the PTSD Checklist in older adults. International Psychogeriatrics, 24(10), 1684–1696.22647669
1485 Yeager, D. E. & Magruder, Κ. M. (2014). PTSD checklist scoring rules for elderly Veterans Affairs outpatients. American Journal of Geriatric Psychiatry, 22(6), 545–550.
1486 Weathers, F. W., Litz, B. T., Keane, T. M., Palmieri, P. Α., Marx, B. P., & Schnurr, P. P. (2013). The PTSD Checklist for DSM-5 (PCL-5). Retrieved from https://www.ptsd.va.gov/professional/assessment/adult-sr/ptsd-checklist.asp
1487 Prins, Α., Bovin, M. J., Smolenski, D. J., Marx, B. P., Kimerling, R., Jenkins-Guarnieri, M. Α., … Tiet, Q. Q. (2016). The Primary Care PTSD Screen for DSM-5 (PC-PTSD-5): Development and evaluation within a veteran primary care sample. Journal of General Internal Medicine, 37(10), 1206–1211.
1488 Prins, Α., Bovin, M. J., Kimerling, R., Kaloupek, D. G., Marx, B. P., Pless Kaiser, Α., & Schnurr, P. P. (2015). The Primary Care PTSD Screen for DSM-5 (PC-PTSD-5). Retrieved from www.ptsd.va.gov/professional/assessment/screens/pc-ptsd.asp
1489 Yaffe, M. J., & Tazkarji, B. (2012). Understanding elder abuse in family practice. Canadian Family Physician, 58(12), 1336–1340.23242889
1490 Booker, S. Q., & Herr, K. A. (2016). Assessment and measurement of pain in adults in later life. Clinics in Geriatric Medicine, 32(4), 677–692.27741963
1491 Booker, S. Q., & Herr, K. A. (2016). Assessment and measurement of pain in adults in later life. Clinics in Geriatric Medicine, 32(4), 677–692.27741963
1492 Ware, L. J., Herr, K. A., Booker, S. S., Dotson, K., Key, J., Poindexter, N., … Packard, A. (2015). Psychometric evaluation of the revised Iowa Pain Thermometer (IPT-R) in a sample of diverse cognitively intact and impaired older adults: A pilot study. Pain Management Nursing, 16(4), 475–482.26256217
1493 Booker, S. Q., & Herr, K. A. (2016). Assessment and measurement of pain in adults in later life. Clinics in Geriatric Medicine, 32(4), 677–692.27741963
1494 Katz, S., Ford, A. B., Moskowitz, R. W., Jackson, B. A., & Jaffe, M. W. (1963). Studies of illness in the aged: The Index of ADL; a standardized measure of biological and psychosocial function. JAMA, 185(12), 914–919.14044222
1495 Hartigan, I. (2007). A comparative review of the Katz ADL and the Barthel Index in assessing the activities of daily living of older people. International Journal of Older People Nursing, 2(3), 204–212.20925877
1496 Katz, S., Down, T. D., Cash, H. R., & Grotz, R. C. (1970). Progress in the development of the Index of ADL. Gerontologist, 10, 20–30.5420677
1497 Mahoney, F., & Barthel, D. (1965). Functional evaluation: The Barthel Index. Maryland State Medical Journal, 14, 61–65.
1498 Hartigan, I. (2007). A comparative review of the Katz ADL and the Barthel Index in assessing the activities of daily living of older people. International Journal of Older People Nursing, 2(3), 204–212.20925877
1499 NINDS Common Data Elements. (n.d.). Report Viewer [for Barthel Index]. Retrieved from www.commondataelements.ninds.nih.gov/report-viewer/23804/www.mapi-trust.org
1500 Pfeffer, R. I., Kurosaki, T. T., Harrah, C. H., Chance, J. M., & Filos, S. (1982). Measurement of functional activities in older adults in the community. Journal of Gerontology, 37(3), 323–329.7069156
1501 Tracy, E., & Whittaker, J. (1990). The Social Network Map: Assessing social support in clinical practice. Families in Society, 71, 461–470.
1502 Tracy, E., & Whittaker, J. (1990). The Social Network Map: Assessing social support in clinical practice. Families in Society, 71, 461–470.
1503 Tracy, E., & Whittaker, J. (1990). The Social Network Map: Assessing social support in clinical practice. Families in Society, 71, 461–470.
1504 National Committee for Quality Assurance. (2016). Goals to care: How to keep the person in “person-centered.” Retrieved from www.ncqa.org/Portals/0/Programs/Goals%20to%20Care%20-%20Spotlight%20Report.pdf?ver=2016-02-23-113526-113
1505 Haight, B. K., and Haight, B. S. (2007). The handbook of structured life review. Baltimore, MD: Health Professions Press.
1506 Smith, M., Robinson, L., & Segal, J. (2019). Coping with grief and loss: Understanding the grieving process and learning to heal. Retrieved from https://staging.helpguide.org/articles/grief/coping-with-grief-and-loss.htm
1507 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking tracker cards. Retrieved June 14, 2019, from www.rethinkingdrinking.niaaa.nih.gov/tools/Interactive-worksheets-and-more/Track-what-you-drink/Drinking-Tracker-Cards.aspx
1508 Hunter, C. L., Goodie, J. L., Oordt, M. S., & Dobmeyer, A. C. (2017). Alcohol and prescription medication misuse. In C. L. Hunt, J. L. Goodie, M. S. Oordt, & A. C. Dobmeyer (Eds.), Integrated behavioral health in primary care: Step-by-step guidance for assessment and intervention (pp. 175–186). Washington, DC: American Psychological Association.
1509 National Institute on Alcohol Abuse and Alcoholism. (n.d.). Planning for change. Retrieved June 14, 2019, from www.rethinkingdrinking.niaaa.nih.gov/Thinking-about-a-change/Its-up-to-you/Planning-For-Change.aspx