# ENDNOTES

1 Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services. Maternal, Infant, and Child Health. https://www.healthypeople.gov/2020/topics-objectives/topic/maternal-infant-and-child-health. Published 2020. Accessed July 6, 2020.

2 Thompson J. Fetal Nutrition and Adult Hypertension, Diabetes, Obesity, and Coronary Artery Disease. Neonatal network : NN. 2007;26:235–240.17710957

3 World Health Organization. The Importance of a Life Course Approach to Health: Chronic Disease Risk from Preconception Through Adolescence and Adulthood. https://www.who.int/life-course/publications/life-course-approach-to-health.pdf?ua=1. Accessed July 6, 2020.

4 World Health Organization. Trends in maternal mortality 2000 to 2017: estimated by WHO, UNICEF, UNFPA, World Bank Group and the United Nations Population Division. 2019.

5 Hoyert DL, Miniño AM. Maternal Mortality in the United States: Changes in Coding, Publication, and Data Release, 2018. Natl Vital Stat Rep. 2020;69(2):1–18.

6 World Health Organization. Maternal mortality ratio (per 100 000 live births). https://www.who.int/healthinfo/statistics/indmaternalmortality/en/. Published 2014. Accessed July 5, 2020.

7 Centers for Disease Control and Prevention. Pregnancy Mortality Surveillance System. https://www.cdc.gov/reproductivehealth/maternal-mortality/pregnancy-mortality-surveillance-system.html. Published 2020. Accessed July 6, 2020.

8 Petersen EE, Davis NL, Goodman D, . Vital Signs: Pregnancy-Related Deaths, United States, 2011–2015, and Strategies for Prevention, 13 States, 2013–2017. MMWR Morb Mortal Wkly Rep. 2019;68(18):423–429.31071074

9 Centers for Disease Control and Prevention. Pregnancy-Related Deaths. https://www.cdc.gov/vitalsigns/maternal-deaths/index.html Published 2019. Accessed July 23, 2020.

10 Davis NL, Smoots A.N., Goodman D. Pregnancy-Related Deaths: Data from 14 U.S. Maternal Mortality Review Committees, 2008–2017. Centers for Disease Control and Prevention. https://www.cdc.gov/reproductivehealth/maternal-mortality/erase-mm/MMR-Data-Brief_2019-h.pdf. Published 2019. Accessed July 6, 2020.

11 Berg CJ, Callaghan WM, Syverson C, Henderson Z. Pregnancy-related mortality in the United States, 1998 to 2005. Obstet Gynecol. 2010;116(6):1302–1309. .21099595

12 Creanga AA, Syverson C, Seed K, Callaghan WM. Pregnancy-Related Mortality in the United States, 2011–2013. Obstet Gynecol. 2017;130(2):366–373 28697109

13 Centers for Disease Control and Prevention. Severe Maternal Morbidity in the United States. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/severematernalmorbidity.html. Accessed July 6, 2020.

14 Centers for Disease Control and Prevention. How Does CDC Identify Severe Maternal Morbidity? Reproductive Health Web site. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/smm/severe-morbidity-ICD.htm. Published 2019. Accessed July 9, 2020.

15 Main EK, Abreo A, McNulty J, . Measuring severe maternal morbidity: validation of potential measures. American Journal of Obstetrics and Gynecology. 2016;214(5):643.e641–643.e610.26582168

16 Himes KP, Bodnar LM. Validation of criteria to identify severe maternal morbidity. Paediatr Perinat Epidemiol. 2020;34(4):408–415.31951038

17 Martin JA HB, Osterman MJK, Driscoll AK. Births: Final data for 2018. Hyattsville, MD,2019.

18 Indian Health Services. Maternal Mortality and Morbidity in Indian Country. https://www.ihs.gov/sites/dccs/themes/responsive2017/display_objects/documents/IHSmaternalmortalityfsfinal.pdf. Accessed July 5, 2020.

19 Personal communication with Drs. Dave Goodman and Emily Petersen in CDC’s Division of Reproductive Health on In: May 13 2020.

20 Petersen EE, Davis NL, Goodman D, . Racial/Ethnic Disparities in Pregnancy-Related Deaths - United States, 2007–2016. MMWR Morb Mortal Wkly Rep. 2019;68(35):762–765 31487273

21 Howell EA, Egorova N, Balbierz A, Zeitlin J, Hebert PL. Black-white differences in severe maternal morbidity and site of care. American journal of obstetrics and gynecology. 2016;214(1):122.e121–122.e1227.26283457

22 Office of Disease Prevention and Health Promotion. Social Determinants of Health. https://www.healthypeople.gov/2020/topics-objectives/topic/social-determinants-of-health. Published 2020. Accessed July 4, 2020.

23 Howell EA. Reducing Disparities in Severe Maternal Morbidity and Mortality. Clin Obstet Gynecol. 2018;61(2):387–399.29346121

24 Azeez O, Kulkarni A, Kuklina EV, Kim SY, Cox S. Hypertension and Diabetes in Non-Pregnant Women of Reproductive Age in the United States. Prev Chronic Dis. 2019;16:E146–E146.31651378

25 Centers for Disease Control and Prevention. Vital Signs: Overdoses of Prescription Opioid Pain Relievers and Other Drugs Among Women- United States, 1990–2010. MMWR Morb Mortal Wkly Rep. 2013;65:537–542

26 Mitra M, Clements KM, Zhang J, Smith LD. Disparities in Adverse Preconception Risk Factors Between Women with and Without Disabilities. Matern Child Health J. 2016;20(3):507–515.26518009

27 Clements KM, Mitra M, Zhang J, Iezzoni LI. Pregnancy Characteristics and Outcomes among Women at Risk for Disability from Health Conditions Identified in Medical Claims. Women’s Health Issues. 2016;26(5):504–510.27477954

28 Brown HK, Cobigo V, Lunsky Y, Vigod SN. Maternal and offspring outcomes in women with intellectual and developmental disabilities: a population-based cohort study. BJOG. 2017;124(5):757–765.27222439

29 Ostchega Y, Fryar CD, Nwankwo T, Nguyen DT. Hypertension Prevalence Among Adults Aged 18 and Over: United States, 2017–2018. NCHS Data Brief. 2020(364):1–8.

30 ACOG Practice Bulletin No. 203 Summary: Chronic Hypertension in Pregnancy. Obstet Gynecol. 2019;133(1):215–219.30575669

31 Seely EW, Ecker J. Clinical practice. Chronic hypertension in pregnancy. N Engl J Med. 2011;365(5):439–446.21812673

32 Whelton PK, Carey RM, Aronow WS, . 2017 ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/NMA/PCNA Guideline for the Prevention, Detection, Evaluation, and Management of High Blood Pressure in Adults: A Report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Hypertension. 2018;71(6):e13–e115.29133356

33 Gestational Hypertension and Preeclampsia: ACOG Practice Bulletin, Number 222. Obstetrics & Gynecology. 2020;135(6).

34 Honigberg MC, Natarajan P. Women’s Cardiovascular Health After Hypertensive Pregnancy: The Long View From Labor and Delivery Becomes Clearer. J Am Coll Cardiol. 2020;75(18):2335–2337.32381165

35 Garovic VD, White WM, Vaughan L, . Incidence and Long-Term Outcomes of Hypertensive Disorders of Pregnancy. J Am Coll Cardiol. 2020;75(18):2323–2334.32381164

36 Honigberg MC, Zekavat SM, Aragam K, . Long-Term Cardiovascular Risk in Women With Hypertension During Pregnancy. J Am Coll Cardiol. 2019;74(22):2743–2754.31727424

37 Lo CCW, Lo ACQ, Leow SH, . Future Cardiovascular Disease Risk for Women With Gestational Hypertension: A Systematic Review and Meta-Analysis. J Am Heart Assoc. 2020:e013991.32578465

38 Haas DM, Parker CB, Marsh DJ, . Association of Adverse Pregnancy Outcomes With Hypertension 2 to 7 Years Postpartum. J Am Heart Assoc. 2019;8(19):e013092.31564189

39 Centers for Disease Control and Prevention. Put the Brakes on Diabetes Complications. Diabetes Web site. https://www.cdc.gov/diabetes/library/features/prevent-complications.html. Published 2019. Accessed July 6, 2020.

40 Centers for Disease Control and Prevention. Type 1 or Type 2 Diabetes and Pregnancy. https://www.cdc.gov/pregnancy/diabetes-types.html. Published 2020. Accessed July 6, 2020.

41 Centers for Disease Control and Prevention. Type 1 or Type 2 Diabetes and Pregnancy. https://www.cdc.gov/pregnancy/diabetes-types.html. Published 2020. Accessed July 6, 2020

42 Kim SY, Sharma AJ, Callaghan WM. Gestational diabetes and childhood obesity: what is the link? Curr Opin Obstet Gynecol. 2012;24(6):376–381.23000698

43 Singh AS, Mulder C, Twisk JW, van Mechelen W, Chinapaw MJ. Tracking of childhood overweight into adulthood: a systematic review of the literature. Obes Rev. 2008;9(5):474–488.18331423

44 Clinical Guidelines on the Identification, Evaluation, and Treatment of Overweight and Obesity in Adults--The Evidence Report. National Institutes of Health. Obes Res. 1998;6 Suppl 2:51s–209s.9813653

45 Centers for Disease Control and Prevention. The Health Effects of Overweight and Obesity. https://www.cdc.gov/healthyweight/effects/index.html. Published 2020. Accessed July 6, 2020.

46 Ogden CL, Carroll MD, Lawman HG, . Trends in Obesity Prevalence Among Children and Adolescents in the United States, 1988–1994 Through 2013–2014. JAMA. 2016;315(21):2292–2299.27272581

47 Hales CM CM, Fryar CD, Ogden CL. Prevalence of obesity among adults and youth: United States 2015–2016. NCHS Data Brief. 2017;no 288.

48 Deputy NP, Dub B, Sharma AJ. Prevalence and Trends in Prepregnancy Normal Weight - 48 States, New York City, and District of Columbia, 2011–2015. MMWR Morb Mortal Wkly Rep. 2018;66(51–52):1402–1407.29300720

49 Chu SY, Callaghan WM, Kim SY, . Maternal Obesity and Risk of Gestational Diabetes Mellitus. Diabetes Care. 2007;30(8):2070.17416786

50 Bodnar LM, Ness RB, Markovic N, Roberts JM. The risk of preeclampsia rises with increasing prepregnancy body mass index. Ann Epidemiol. 2005;15(7):475–482.16029839

51 Practice Bulletin No 156: Obesity in Pregnancy. Obstetrics & Gynecology. 2015;126(6).

52 Stang J, Huffman LG. Position of the Academy of Nutrition and Dietetics: Obesity, Reproduction, and Pregnancy Outcomes. Journal of the Academy of Nutrition and Dietetics. 2016;116(4):677–691.27017177

53 Institute of Medicine, National Research Council Committee to Reexamine, Institue of Medicine Pregnancy Weight Guidelines. The National Academies Collection: Reports funded by National Institutes of Health. In: Weight Gain During Pregnancy: Reexamining the Guidelines. Washington (DC): National Academies Press (US); 2009.

54 Luke B, Hediger ML, Nugent C, . Body mass index--specific weight gains associated with optimal birth weights in twin pregnancies. J Reprod Med. 2003;48(4):217–224.12746982

55 Centers for Disease Control and Prevention. Weight Gain During Pregnancy. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pregnancy-weight-gain.htm. Published 2019. Accessed July 31, 2020.

56 Kourtis AP, Read JS, Jamieson DJ. Pregnancy and infection. The New England Journal of Medicine. 2014;370(23):2211–2218.24897084

57 Centers for Disease Control and Prevention. Immunization Schedules. https://www.cdc.gov/vaccines/schedules/hcp/imz/adult.html. Published 2020. Accessed July 6, 2020.

58 Ellington S, Strid P, Tong VT, . Characteristics of Women of Reproductive Age with Laboratory-Confirmed SARS-CoV-2 Infection by Pregnancy Status-United States, January 22–June 7, 2020. MMWR Morb Mortal Wkly Rep 2020.

59 Substance Abuse and Mental Health Services Administration. Results from the 2018 National Survey on Drug Use and Health: Detailed Tables, Prevalence Estimates, Standard Errots, P Values and Sample Sizes. https://www.samhsa.gov/data/sites/default/files/cbhsq-reports/NSDUHDetailedTabs2018R2/NSDUHDetailedTabs2018.pdf. Published 2019. Accessed July 4, 2020.

60 Centers for Disease Control and Prevention. Smoking During Pregnancy. https://www.cdc.gov/tobacco/basic_information/health_effects/pregnancy/index.html Published 2020. Accessed July 6, 2020.

61 Centers for Disease Control and Prevention. Substance Use During Pregnancy. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/substance-abuse/substance-abuse-during-pregnancy.html. Published 2019. Accessed July 3, 2020.

62 Centers for Disease Control and Prevention. Fetal Alcohol Spectrum Disorders. https://www.cdc.gov/ncbddd/fasd/alcohol-use.html. Published 2020. Accessed July 6, 2020.

63 Substance Abuse and Mental Health Services Administration. Mental Health and Substance Use Disorders. https://www.samhsa.gov/find-help/disorders. Published 2019. Accessed July 4, 2020.

64 Committee opinion no. 633: Alcohol abuse and other substance use disorders: ethical issues in obstetric and gynecologic practice. Obstet Gynecol. 2015;125(6):1529–1537.26000541

65 Haight SC, Ko JY, Tong VT, Bohm MK, Callaghan WM. Opioid Use Disorder Documented at Delivery Hospitalization - United States, 1999–2014. MMWR Morb Mortal Wkly Rep. 2018;67(31):845–849.30091969

66 U.S. Department of Health and Human Services, Office of the Surgeon General. Facing Addiction in America: The Surgeon General’s Report on Alcohol, Drugs, and Health. https://addiction.surgeongeneral.gov/sites/default/files/surgeon-generals-report.pdf. Published 2016. Accessed July 6, 2020.

67 Committee Opinion No. 711: Opioid Use and Opioid Use Disorder in Pregnancy. Obstetrics & Gynecology. 2017;130(2).

68 Substance Abuse and Mental Health Services Administration. National Survey on Drug Use and Health [Data Set]. https://www.samhsa.gov/data/sites/default/files/cbhsq-reports/NSDUHDetailedTabs2017/NSDUHDetailedTabs2017.pdf. Published 2017. Accessed July 6, 2020.

69 Haight SC, Byatt N, Moore Simas TA, Robbins CL, Ko JY. Recorded Diagnoses of Depression During Delivery Hospitalizations in the United States, 2000–2015. Obstet Gynecol. 2019;133(6):1216–1223..31135737

70 Bauman BL KJ, Cox S, . Postpartum Depressive Symptoms and Provider Discussions about Perinatal Depression- United States. MMWR Morb Mortal Wkly Rep 2018;2020(79):575–581.

71 Slomian J, Honvo G, Emonts P, Reginster JY, Bruyère O. Consequences of maternal postpartum depression: A systematic review of maternal and infant outcomes. Womens Health (Lond). 2019;15:1745506519844044.31035856

72 The National Intimate Partner and Sexual Violence Survey. 2015 Data Brief- Updated Release https://www.cdc.gov/violenceprevention/pdf/2015data-brief508.pdf. Published 2018. Accessed July 23, 2020.

73 Breiding MJ, Basile KC, Smith SG, Black MC, Mahendra RR. Intimate Partner Violence Surveillance: Uniform Definitions and Recommended Data Elements. National Center for Injury Prevention and Control, Centers for Disease Control and Prevention. 2015;2.0.

74 Cheng D, Horon IL. Intimate-Partner Homicide Among Pregnant and Postpartum Women. Obstetrics & Gynecology. 2010;115(6).

75 O’Reilly R, Peters K. Opportunistic domestic violence screening for pregnant and post-partum women by community based health care providers. BMC Women’s Health. 2018;18(1):128..30041637

76 Alhusen JL, Ray E, Sharps P, Bullock L. Intimate partner violence during pregnancy: maternal and neonatal outcomes. J Womens Health (Larchmt). 2015;24(1):100–106.25265285

77 Koch AR, Rosenberg D, Geller SE. Higher Risk of Homicide Among Pregnant and Postpartum Females Aged 10–29 Years in Illinois, 2002–2011. Obstet Gynecol. 2016;128(3):440–446.27500340

78 Wallace ME, Crear-Perry J, Mehta PK, Theall KP. Homicide During Pregnancy and the Postpartum Period in Louisiana, 2016–2017. JAMA Pediatrics. 2020;174(4):387–388.32011644

79 Womens Preventive Services Initiative. Recommendations for Well-Women Care. https://www.womenspreventivehealth.org/wellwomanchart. Published 2020. Accessed July 4, 2020.

80 Centers for Disease Control and Prevention. Recommendations to improve preconception health and health care- United States: a report of the CDC/ATSDR Preconception Care Work Group and the Select Panel on Preconception Care. MMWR 2006;55.

81 Centers for Disease Control and Prevention. Providing Quality Family Planning Services: Recommendations of the CDC and the U.S. Office of Population Affairs. MMWR. 2014;63.

82 Breast cancer and breastfeeding: collaborative reanalysis of individual data from 47 epidemiological studies in 30 countries, including 50302 women with breast cancer and 96973 women without the disease. Lancet. 2002;360(9328):187–195.12133652

83 U.S. Department of Health and Human Services, National Institute of Health, National Cancer Institute. How Quitting Helps Women’s Health. https://women.smokefree.gov/quit-smoking-women/what-women-should-know/how-quitting-helps-women. Accessed July 6, 2020.

84 U.S. Department of Health and Human Services. Physical Activity Guidelines for Americans. In. 2 ed. Washington, DC, 2018.

85 American College of Obstetricians and Gynecologists. Routine Tests During Pregnancy. Frequently Asked Questions: Pregnancy Web site. https://www.acog.org/patient-resources/faqs/pregnancy/routine-tests-during-pregnancy. Published 2020. Accessed July 6, 2020.

86 American College of Obstetricians and Gynecologists. Guidelines for Perinatal Care, Eighth Edition Book. https://www.acog.org/store/products/clinical-resources/guidelines-for-perinatal-care. Published 2017. Accessed July 6, 2020.

87 Yan J. The Effects of Prenatal Care Utilization on Maternal Health and Health Behaviors. Health Econ. 2017;26(8):1001–1018.27374163

88 Feltner C, Weber RP, Stuebe A, Grodensky CA, Orr C, Viswanathan M. AHRQ Comparative Effectiveness Reviews. In: Breastfeeding Programs and Policies, Breastfeeding Uptake, and Maternal Health Outcomes in Developed Countries. Rockville (MD): Agency for Healthcare Research and Quality (US); 2018.

89 Centers for Disease Control and Prevention. Breastfeeding Rates. National Immunization Survey (NIS) Web site. https://www.cdc.gov/breastfeeding/data/nis_data/index.htm. Published 2019. Accessed July 6, 2020.

90 National Prevention Council. National Prevention Strategy. Washington, DC 2011.

91 U.S. Department of Health and Human Services, President’s Council on Sports Fitness and Nutrition. Dietary Guidelines for Americans https://www.hhs.gov/fitness/eat-healthy/dietary-guidelines-for-americans/index.html. Published 2017. Accessed July 5, 2020.

92 Watson NF, Badr MS, Belenky G, . Recommended Amount of Sleep for a Healthy Adult: A Joint Consensus Statement of the American Academy of Sleep Medicine and Sleep Research Society. Sleep. 2015;38(6):843–844.26039963

93 Hirshkowitz M, Whiton K, Albert SM, . National Sleep Foundation’s sleep time duration recommendations: methodology and results summary. Sleep Health. 2015;1(1):40–43.29073412

94 Office on Women’s Health. Oral Health. https://www.womenshealth.gov/a-z-topics/oral-health. Published 2019. Accessed July 6, 2020.

95 American Dental Association. Oral health during pregnancy. JADA 2011(5).

96 U.S. Department of Health and Human Services. Smoking Cessation. A Report of the Surgeon General. Atlanta, GA: U.S. Department of Health and Human Services,;2020.

97 U.S. Department of Health and Human Services. U.S. Surgeon General’s Advisory: Marijuana And the Developing Brain. https://www.hhs.gov/surgeongeneral/reports-and-publications/addiction-and-substance-misuse/advisory-on-marijuana-use-and-developing-brain/index.html. Published 2019. Accessed July 5, 2020.

98 Centers for Disease Control and Prevention. A 2005 Message to Women from the U.S. Surgeon General. 2005.

99 U.S. Preventive Services Taskforce. Folic Acid for the Prevention of Neural Tube Defects: Preventive Medication https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/folic-acid-for-the-prevention-of-neural-tube-defects-preventive-medication. Published 2017. Accessed July 5, 2020.

100 World Health Organization. WHO Recommendations on health promotion interventions for maternal and newborn health. Geneva, Switzerland 2015.

101 Mosca L, Benjamin EJ, Berra K, . Effectiveness-based guidelines for the prevention of cardiovascular disease in women--2011 update: a guideline from the american heart association. Circulation. 2011;123(11):1243–1262.21325087

102 American Diabetes Association. Standards of Medical Care in Diabetes—2014. Diabetes Care. 2014;37(Supplement 1):S14.24357209

103 American Heart Association. Know Your Heart Numbers. https://www.heart.org/en/health-topics/diabetes/prevention--treatment-of-diabetes/know-your-health-numbers. Published 2015. Accessed July 6, 2020..

104 American Diabetes Association. Diabetes. https://www.diabetes.org/diabetes. Published 2020. Accessed July 6, 2020.

105 Agency for Healthcare Research and Quality (AHRQ). Be More Involved in Your Health Care. Tips & Tools Web site. https://www.ahrq.gov/patients-consumers/patient-involvement/ask-your-doctor/tips-and-tools/beinvolved.html. Published 2011. Accessed July 6, 2020.

106 The Joint Commisson. Speak Up Campaigns https://www.jointcommission.org/en/resources/for-consumers/speak-up-campaigns/. Accessed July 7, 2020.

107 Centers for Disease Control and Prevention. HEAR HER Campaign. Reproductive Health, Web site. https://www.cdc.gov/hearher/about-the-campaign/index.html. Published 2020. Accessed August 19, 2020.

108 American College of Obstetricians and Gynecologists. Postpartum Depression. https://www.acog.org/Patients/FAQs/Postpartum-Depression. Published 2019. Accessed July 5, 2020.

109 ACOG Committee Opinion No. 736: Optimizing Postpartum Care. Obstet Gynecol. 2018;131(5):e140–e150.29683911

110 Schwartz PM, Kelly C, Cheadle A, Pulver A, Solomon L. The Kaiser Permanente Community Health Initiative: A Decade of Implementing and Evaluating Community Change. Am J Prev Med. 2018;54(5 Suppl 2):S105–s109.29680107

111 Main EK, Markow C, Gould J. Addressing Maternal Mortality And Morbidity In California Through Public-Private Partnerships. Health Aff (Millwood). 2018;37(9):1484–1493.30179538

112 Main EK, Cape V, Abreo A, . Reduction of severe maternal morbidity from hemorrhage using a state perinatal quality collaborative. Am J Obstet Gynecol. 2017;216(3):298.e291–298.e211.28153661

113 Association of State and Territorial Health Officials. Fact Sheet: Perinatal Regionalization. 2014.

114 Lasswell S, Barfield W, Rochat R, Blackmon L. Perinatal Regionalization for Very Low-Birth-Weight and Very Preterm Infants: A Meta-analysis. JAMA. 2010;304:992–1000.20810377

115 Centers for Disease Control and Prevention. Perinatal Quality Collaboratives. https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pqc.htm. Published 2020. Accessed July 6, 2020.

116 de Beaumount Foundation. Building Skills for a More Strategic Public Health Workforce: A Call to Action. https://www.debeaumont.org/wp-content/uploads/2019/04/Building-Skills-for-a-More-Strategic-Public-Health-Workforce.pdf. Published 2019. Accessed July 23, 2020.

117 Centers for Disease Control and Prevention. Enhancing Reviews and Surveillance to Eliminate Maternal Mortality (ERASE MM). Reproductive Health Web site. https://www.cdc.gov/reproductivehealth/maternal-mortality/erase-mm/index.html. Published 2020. Accessed July 6, 2020..

118 D’Angelo DV, Cernich A, Harrison L, . Disability and Pregnancy: A Cross-Federal Agency Collaboration to Collect Population-Based Data About Experiences Around the Time of Pregnancy. J Womens Health (Larchmt). 2020;29(3):291–296.32186964

119 U.S. Department of Health and Human Services. The Surgeon General’s Call to Action to Support Breastfeeding. Washington, DC: Offie of the Surgeon General;2011.

120 Office of Disease Prevention and Health Promotion. Using Law and Policy to Promote Breastfeeding in the United States. Maternal, Infant, and Child Health Web site. https://www.healthypeople.gov/2020/law-and-health-policy/topic/maternal-infant-child-health. Published 2020. Accessed July 7, 2020.

121 Kilpatrick SJ, Menard MK, Zahn CM, Callaghan WM. Obstetric Care Consensus #9: Levels of Maternal Care: (Replaces Obstetric Care Consensus Number 2, February 2015). Am J Obstet Gynecol. 2019;221(6):B19–b30.31351999

122 Human Resources and Services Association. Home Visiting. Programs & Initiatves Web site. https://mchb.hrsa.gov/maternal-child-health-initiatives/home-visiting-overview. Published 2020. Accessed July 23, 2020.

123 Harder+Company Community Research. Best Babies Zone Evaluation Outcomes. http://bestbabieszone.gutensite.net/Evaluation Accessed July 6, 2020.

124 Centers for Medicare & Medicaid Services. Improving Access to Maternal Health Care in Rural Communities Issue Brief Web site. https://www.cms.gov/About-CMS/Agency-Information/OMH/equity-initiatives/rural-health/09032019-Maternal-Health-Care-in-Rural-Communities.pdf. Published 2020. Accessed July 6, 2020.

125 National Academies of Sciences E, Medicine. Birth Settings in America: Outcomes, Quality, Access, and Choice. Washington, DC: The National Academies Press; 2020.

126 Community Preventive Services Task Force. Your online guide of what works to promote healthy communities https://www.thecommunityguide.org/. Accessed July 6, 2020.

127 Rossen LM WL, Hoyert DL, Anderson RN, Uddin SFG,. The impact of the pregnancy checkbox and misclassification on maternal mortality trends in the United States, 1999–2017. National Center for Health Statistics. 2020;Vital Health Statistics(44).

128 Donna Hoyert SFU, Arialdi M. Minimo. Evaluation of the Pregnancy Status Checkbox on the Identification of Maternal Deaths. National Virtal Statistics Reports. 2020;69.

129 Arias E, Schauman WS, Eschbach K, Sorlie PD, Backlund E. The validity of race and Hispanic origin reporting on death certificates in the United States. Vital Health Stat 2. 2008(148):1–23.

130 Review to Action. Learn. https://reviewtoaction.org/learn/definitions. Accessed July 6, 2020.

131 Primary Care Physicians’ Role In Coordinating Medical And Health-Related Social Needs In Eleven Countries. Health Affairs. 2020;39(1):115–123.31821045

132 World Health Organization. The World Health Report 2008-primary Health Care (Now More Than Ever). https://www.who.int/whr/2008/overview/en/index2.html. Published 2008. Accessed July 6, 2020.

133 U.S. Preventive Services Task Force. Recommendations. https://www.uspreventiveservicestaskforce.org/uspstf/topic_search_results?topic_status=P. Accessed July 4, 2020.

134 American Academy of Pediatrics. Bright Futures: Prevention and health promotion for infants, children, adolescents, and their families. https://brightfutures.aap.org/Pages/default.aspx. Accessed July 4, 2020.

135 U.S. Department of Health and Human Services, Office of Minority Health. The National CLAS Standards. https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=2&lvlid=53. Accessed July 6, 2020.

136 Brown HL, Warner JJ, Gianos E, . Promoting Risk Identification and Reduction of Cardiovascular Disease in Women Through Collaboration With Obstetricians and Gynecologists: A Presidential Advisory From the American Heart Association and the American College of Obstetricians and Gynecologists. Circulation. 2018;137(24):e843–e852.29748185

137 World Health Organization. Counseling for Maternal and Newborn Health Care: A Handbook for Building Skills. Geneva: World Health Organization,; 2013.

138 WHO Reproductive Health Library. WHO recommendation on effective communication between maternity care providers and women in labour. https://extranet.who.int/rhl/topics/preconception-pregnancy-childbirth-and-postpartum-care/care-during-childbirth/who-recommendation-effective-communication-between-maternity-care-providers-and-women-labour. Published 2018. Accessed July 6, 2020.

139 Werner D, Young NK, Dennis K, Amatetti S. Family-Centered Treatment for Women With Substance Use Disorders-History, Key Elements, and Challenges. 2007.

140 Cox JL, Holden JM, Sagovsky R. Detection of postnatal depression. Development of the 10-item Edinburgh Postnatal Depression Scale. Br J Psychiatry. 1987;150:782–786.3651732

141 Tobias DK, Stuart JJ, Li S, . Association of history of gestational diabetes with long term cardiovascular disease risk in a large prospective cohort of US women. JAMA Internal Medicine. 2017(12):1735–1742.29049820

142 Agency for Healthcare Research and Quality (AHRQ), U.S. Department of Health and Human Services. Toolkit for Improving Perinatal Safety. Healthcare-Associated Infections Program Web site. https://www.ahrq.gov/hai/tools/perinatal-care/index.html. Published 2017. Accessed July 7, 2020.

143 Agency for Healthcare Research and Quality (AHRQ), U.S. Department of Health and Human Services. TeamSTEPPS. https://www.ahrq.gov/teamstepps/index.html. Accessed July 7, 2020.

144 Hung P, Henning-Smith CE, Casey MM, Kozhimannil KB. Access To Obstetric Services In Rural Counties Still Declining, With 9 Percent Losing Services, 2004–14. Health Aff (Millwood). 2017;36(9):1663–1671.28874496

145 Kozhimannil KB, Hung P, Henning-Smith C, Casey MM, Prasad S. Association Between Loss of Hospital-Based Obstetric Services and Birth Outcomes in Rural Counties in the United States. JAMA. 2018;319(12):1239–1247.29522161

146 Centers for Disease Control and Prevention. CDC Levels of Care Assessment Tool (CDC LOCATe). https://www.cdc.gov/reproductivehealth/maternalinfanthealth/cdc-locate/index.html#tool. Published 2019. Accessed July 7, 2020.

147 Council on Patient Safety in Women’s Health Care. Alliance on Innovation on Maternal Health Program. https://safehealthcareforeverywoman.org/aim-program/. Published 2020. Accessed July 6, 2020.

148 Ten Hoope-Bender P, de Bernis L, Campbell J, . Improvement of maternal and newborn health through midwifery. Lancet. 2014;384(9949):1226–1235.24965818

149 World Health Organization. Promoting sexual and reproductive health for persons with disabilities. WHO/UNFOA Guidance Note. https://www.who.int/reproductivehealth/publications/general/9789241598682/ Published 2009. Accessed July 6, 2020.

150 Association of Women’s Health Obstetric and Neonatal Nurses. POST-BIRTH Warning Signs Education Program. https://awhonn.org/education/hospital-products/post-birth-warning-signs-education-program/. Accessed July 7, 2020.

151 Baby-Friendly USA. About Us. https://www.babyfriendlyusa.org/about/. Published 2012–2020. Accessed July 5, 2020.

152 ACOG Committee Opinion No. 731: Group Prenatal Care. Obstet Gynecol. 2018;131(3):e104–e108.29470344

153 U.S. Department of Agriculture Food and Nutrition Service. Coordination Strategies Handbook- A Guide for WIC and Primary Care Professionals https://www.fns.usda.gov/wic/coordination-strategies-handbook. Accessed July 4, 2020.

154 Human Resources and Services Association. Home Visiting. Programs & Initiatives Web site. https://mchb.hrsa.gov/maternal-child-health-initiatives/home-visiting-overview. Published 2020. Accessed July 23, 2020.

155 U.S. Department of Health and Human Services. Role of Community Health Workers. https://www.nhlbi.nih.gov/health/educational/healthdisp/role-of-community-health-workers.html. Accessed July 6, 2020.

156 National Center for Health Statistics. Health Insurance and Access to Care. https://www.cdc.gov/nchs/data/factsheets/factsheet_hiac.pdf. Published 2017. Accessed July 4, 2020.

157 BCBS ProgressHealth. Making Childbirth Safer for Women in the U.S. https://www.bcbsprogresshealth.com/community/123/making-childbirth-safer-for-women-in-the-u-s. Accessed July 6, 2020.

158 Centers for Medicare & Medicaid Services. CMS Healthy Equity Awards https://www.bcbsprogresshealth.com/community/123/making-childbirth-safer-for-women-in-the-u-s. Published 2020. Accessed July 5, 2020.

159 U.S. Department of Labor. Family and Medical Leave Act (FMLA). https://www.dol.gov/agencies/whd/fmla. Accessed July 5, 2020.

160 U.S. Department of Labor. Family and Medical Leave (FMLA). Leave Benefits Web site. https://www.dol.gov/general/topic/benefits-leave/fmla Accessed July 7, 2020.

161 National Partnership for Women & Families. A Look at the U.S. Department of Labor’s 2012 Family and Medical Leave Act Employee and Worksite Survey. https://www.nationalpartnership.org/our-work/resources/economic-justice/fmla/dol-fmla-survey-key-findings-2012.pdf. Published 2013. Accessed July 5, 2020.

162 National Defense Authorization Act In. H.R.2500. 116th Congress ed2020.

163 U.S. Department of Labor. Wages and the Fair Labor Standards Act. https://www.dol.gov/agencies/whd/flsa Published 2020. Accessed July 5, 2020.

164 U.S. Department of Labor. Section 7(r) of the Fair Labor Standards Act-Break Time for Nursing Mothers Provision. https://www.dol.gov/agencies/whd/nursing-mothers/law Accessed July 6, 2020.

165 American College of Obstetricians and Gynecologists. Paid Parental Leave. https://www.acog.org/clinical-information/policy-and-position-statements/statements-of-policy/2019/paid-parental-leave Published 2019. Accessed July 4, 2020.

166 The Council of Economic Advisors. The Economics of Paid and Unpaid Leave. 2014.

167 Centers for Disease Control and Prevention. Workplace Health Model. https://www.cdc.gov/workplacehealthpromotion/model/index.html. Published 2016. Accessed July 5, 2020.

168 Arijit Nandi DJ, Michelle C. Dimitris, Jeremy A. Labrecque, Erin C. Strumpf, Jay S. Kauman, Ilona Vincent, Efe Atabay, Sam Harper, Alison Earle, S. Jody Haymann,. The Impact of Parental and Medical Leave Policies on Socioeconomic and Health Outcomes in OECD Countries: A Systemic Review of the Empirical Literature The Milbank Quarterly: A Multidisciplinary Journal of Population Health and Health Policy. 2018;96:434–471.

169 Centers for Disease Control and Prevention. Blood Pressure Interventions: Programs. https://www.cdc.gov/workplacehealthpromotion/health-strategies/blood-pressure/interventions/programs.html. Accessed July 5, 2020.

170 Health Resources and Services Administration. Remote Pregnancy Monitoring. https://mchbgrandchallenges.hrsa.gov/challenges/remote-pregnancy-monitoring. Accessed July 6, 2020.

171 Centers for Medicare & Medicaid Services. Maternal Opioid Misuse (MOM) Model. Innovation Models Web site. https://innovation.cms.gov/innovation-models/maternal-opioid-misuse-model. Published 2020. Accessed July 9, 2020.

172 Chakhtoura N, Chinn JJ, Grantz KL, . Importance of research in reducing maternal morbidity and mortality rates. Am J Obstet Gynecol. 2019;221(3):179–182.31492377

173 Dahlke JD, Mendez-Figueroa H, Maggio L, . Prevention and management of postpartum hemorrhage: a comparison of 4 national guidelines. Am J Obstet Gynecol. 2015;213(1):76.e71–76.e10.25731692

174 Bibbins-Domingo K, Grossman DC, Curry SJ, . Screening for Preeclampsia: US Preventive Services Task Force Recommendation Statement. JAMA. 2017;317(16):1661–1667.28444286

175 Grodzinsky A, Florio K, Spertus JA, . Maternal Mortality in the United States and the HOPE Registry. Curr Treat Options Cardiovasc Med. 2019;21(9):42.31342274

176 Hilfiker-Kleiner D, Haghikia A, Nonhoff J, Bauersachs J. Peripartum cardiomyopathy: current management and future perspectives. Eur Heart J. 2015;36(18):1090–1097..25636745

177 U.S. Department of Health and Human Services. PregSource. https://pregsource.nih.gov/. Published 2020. Accessed July 5, 2020.

178 Centers for Disease Control and Prevention. PRAMS. https://www.cdc.gov/prams/index.htm. Published 2020. Accessed July 6, 2020.

179 Centers for Disease Control and Prevention. National Health and Nutrition Examination Survey. https://www.cdc.gov/nchs/nhanes/index.htm. Published 2020. Accessed July 4, 2020.

180 Centers for Medicare & Medicaid Services. Transformed Medicaid Statistical Information System (T-MSIS) Analytic Files (TAF). https://www.medicaid.gov/medicaid/data-systems/macbis/medicaid-chip-research-files/transformed-medicaid-statistical-information-system-t-msis-analytic-files-taf/index.html. Accessed July 6, 2020.

181 U.S. Department of Health and Human Services. Healthy Women, Healthy Pregnancies, Healthy Futures: The U.S. Department of Health and Human Services’ Action Plan to Improve Maternal Health in America In:2020.

182 National Institute of Health. Task Force on Research Specific to Pregnant and Lactating Women (PRGLAC). https://www.nichd.nih.gov/about/advisory/PRGLAC. Published 2020. Accessed July 5, 2020.

183 World Health Organization. Maternal and perinatal health. https://www.who.int/maternal_child_adolescent/topics/maternal/maternal_perinatal/en/. Published 2013. Accessed July 6, 2020.

184 Office on Women’s Health, U.S. Department of Health and Human Services. Preconception Health. https://www.womenshealth.gov/pregnancy/you-get-pregnant/preconception-health. Accessed July 24, 2020.

185 Obstetric Care Consensus No. 9: Levels of Maternal Care: Correction. Obstet Gynecol. 2019;134(4):883.

186 Streeter RA, Snyder JE, Kepley H, Stahl AL, Li T, Washko MM. The geographic alignment of primary care Health Professional Shortage Areas with markers for social determinants of health. PLOS ONE. 2020;15(4):e0231443.32330143

187 St Pierre A, Zaharatos J, Goodman D, Callaghan WM. Challenges and Opportunities in Identifying, Reviewing, and Preventing Maternal Deaths. Obstet Gynecol. 2018;131(1):138–142.29215526

188 Zaharatos J, St Pierre A, Cornell A, Pasalic E, Goodman D. Building U.S. Capacity to Review and Prevent Maternal Deaths. J Womens Health 2018;27(1):1–5.