# 6 GLOSSARY OF TERMS

MATERNAL DEATH: The death of a woman while pregnant or within 42 days of termination of pregnancy, irrespective of the duration and site of the pregnancy, from any cause related to or aggravated by the pregnancy or its management but not from accidental or incidental causes.^6^
PERINATAL: The period from 22 completed weeks of gestation through seven days after birth.^183^
PERINATAL QUALITY COLLABORATIVE (PQC): state or multi-state networks working to improve maternal and infant health by advancing evidence-informed clinical practices and processes using quality improvement principles.
POSTPARTUM: The period immediately after the birth of a child and up to 12 months after delivery.^110^
PRECONCEPTION HEALTH: The health of a woman before becoming pregnant.^184^
PREGNANCY-ASSOCIATED DEATH: The death of a woman while pregnant or within one year of termination of pregnancy, regardless of cause.^131^
PREGNANCY-RELATED DEATH: The death of a woman while pregnant or within 1 year of the end of a pregnancy –regardless of the outcome, duration or site of the pregnancy–from any cause related to or aggravated by the pregnancy or its management, but not from accidental or incidental causes.^7^
PRENATAL PERIOD: The period from conception to birth.
REPRODUCTIVE PERIOD: The period from first menarche to last menstruation when a woman can become pregnant and give birth.
RISK-APPROPRIATE CARE: A strategy developed to improve health outcomes for pregnant women and infants that ensures those at high risk of complications receive care at a birth facility that is best prepared to meet their health needs.^185^
SEVERE MATERNAL MORBIDITY: Unintended outcomes of the process of labor and delivery that result in significant short-term or long-term consequences to a woman’s health.^13^
SOCIAL DETERMINANTS OF HEALTH: Conditions in the environments in which people are born, live, learn, work, play, worship, and age that affect a wide range of health, functioning, and quality-of-life outcomes and risks.^22^
UNDERSERVED AREAS: Medically underserved areas and Health Professional Shortage Areas exist in all states in urban and rural areas, and identify geographic areas and populations with a lack of, and barriers to, access to health professionals and medical care services.^186^