# FOREWORD FROM THE SURGEON GENERAL, U.S. DEPARTMENT OF HEALTH AND HUMAN SERVICES

As a husband, father, son, and the Nation’s Doctor, I am deeply committed to improving the health and well-being of America’s mothers and mothers-to-be. The death of a woman from pregnancy-related causes is one of the greatest tragedies that can befall a family and a community. Sadly, this catastrophe happens about 700 times each year in the U.S. -- far more frequently than in countries of similar population size and income. Severe complications of pregnancy number in the tens of thousands, and pregnancy-related events can put women at increased risk of certain medical conditions for the rest of their lives.

Further, we cannot truly address maternal health-- especially maternal morbidity and mortality-- without acknowledging the disparate outcomes many women of color face. For example, black and American Indian/Alaska Native women die from pregnancy-related causes at two to three times that of their white, Asian Pacific Islander, and Hispanic counterparts.

These outcomes are not just unacceptable. They are largely avoidable. In fact, the Centers for Disease Control and Prevention (CDC) estimates that two out of three pregnancy-related deaths are considered preventable. Simply put, we can – and must – do more for our moms.

Looking around the country, we have seen that adoption of best practices in the home, community, clinic, and hospital, leads to better outcomes for women and babies. I am issuing this Call to Action to equip each of you with specific actions that will help ensure every woman is provided the best chance to see her child take their first steps, graduate from high school, and even have a baby of their own.

It is also an inescapable fact that this Surgeon General’s Call to Action will be released during unprecedented times. The novel coronavirus and the disease it causes (COVID-19) have changed all of our lives and touched every household in America. It has brought to light many of the factors, such as housing, transportation, and workplace policies, that make some Americans more vulnerable to health threats. COVID-19 has also shed light on how many Americans, including women of reproductive age, have hypertension, diabetes, unhealthy body weight, and other chronic conditions. We have discovered that such health burdens not only increase risks during pregnancy, but may also increase susceptibility to and severity of COVID-19. That’s why it is more pressing than ever that we address these determinants of health—both societal and medical—as they impact the lives and livelihoods of women, and in turn, our nation’s future.

The health of our nation depends on the health of our mothers. That is why I applaud the fact that both the Department of Health and Human Services Action Plan to Improve Maternal Health in America and this Call to Action have adopted a life-course approach, promoting and building health across the age spectrum through individual, community, and healthcare actions. By investing early and over time in all three levels of action, we can become a nation of healthy mothers—and over the long term, a healthier nation.

I ask that you join me in this mission. Read this document. Share it with your friends and colleagues. Then take the actions that are a good fit for you and your organization or community. Every single one of us has a unique role to play. By working together we can support moms, save lives, and set the foundation for a healthier nation.

- Jerome M. Adams, MD, MPH
  Vice Admiral, U.S. Public Health Service
  Surgeon General
  U.S. Department of Health and Human Services