# FOREWORD FROM THE SECRETARY, U.S. DEPARTMENT OF HEALTH AND HUMAN SERVICES

The United States has one of the most technologically advanced healthcare systems in the world, yet we have a maternal mortality rate that is higher than comparable countries. Racial and ethnic, geographic, and age disparities are especially concerning: Pregnancy-related mortality for Black and American Indian and Alaska Native women is two to three times higher than for white, Hispanic, and Asian/Pacific Islander women.^a^ The share of rural counties with hospital obstetric services decreased significantly in the past decade, and women over 35 years are one and a half times more likely to experience complications during pregnancy.

a CDC Morbidity and Mortality Weekly Report. Racial/Ethnic Disparities in Pregnancy-Related Deaths — United States, 2007–2016, https://www.cdc.gov/mmwr/volumes/68/wr/pdfs/mm6835a3-H.pdf.

The disparities go well beyond tragic, unnecessary deaths. Each year, thousands of women experience severe maternal morbidity—unexpected outcomes of labor and delivery that result in significant short- or long-term consequences to their health. These health outcomes create lasting burdens that make it more challenging for mothers to live healthy, flourishing lives. Such disparities and outcomes are unacceptable.

The Trump Administration, including through leadership by the Surgeon General, has made it a priority to tackle health issues that disproportionately impact Americans of color—such as kidney care, HIV/AIDS, hypertension, and sickle cell disease—and we must do the same for maternal health. We are committed to reducing disparities and improving outcomes for our nation’s mothers, and we can accomplish even more if Congress acts on the maternal health proposals contained in President Trump’s Fiscal Year 2021 Budget.

We have an opportunity for action. Research indicates that as much as two-thirds of pregnancy-related deaths are preventable. Key factors that may contribute to high maternal mortality and morbidity include variation in clinical practice patterns, access to care, and data limitations that inhibit surveillance and research.

Implementing evidence-based measures to reduce maternal mortality has been shown to cut mortality by as much as half.^b^ The Department of Health and Human Services is releasing an Action Plan that lays out a path forward to deliver such results.

b Main, E. K., Markow, C., & Gould, J. (2018). Addressing maternal mortality and morbidity in California through public-private partnerships. Health Affairs, 37(9), 1484–1493.30179538

But we cannot accomplish our goals from Washington. Every American has an important role. This Surgeon General’s Call to Action outlines the critical roles that each of us can play to reduce the unacceptably high rates of maternal mortality and morbidity in the United States. Success will require the coordinated efforts of states, healthcare professionals, health care and birthing facilities, women and families, payors, employers, innovators, and researchers, working in collaboration with federal partners.

Calls to Action by the United States Surgeon General are a rare step, reserved for the most serious public health crises facing all Americans. Maternal morbidity and mortality is a crisis, and has been for far too long.

Taking action together, we can help all women set a course for health before, during, and after pregnancy, ensuring healthy futures for both our mothers and children.

- Alex M. Azar II
  Secretary of Health and Human Services