# 5 CONCLUSION AND LONG-TERM VISION

The health and well-being of our nation’s women and their families is paramount to the overall health of the U.S. population and future generations. When considering strategies and actions to improve maternal health, it is important to address health across the life course -- starting with young girls and adolescents and extending through childbearing age and beyond, while engaging a variety of stakeholders, including women and families, states, tribes, and local communities, healthcare professionals, health systems, hospitals, and birthing facilities, payors, employers, innovators, and researchers. Everyone can contribute by creating environments that support the health and well-being of women, promoting healthy pregnancies, preventing the development of risk factors in the first place, and ensuring access to high-quality healthcare before, during, and after pregnancy.

The conditions in which women are born, grow, live, work, and age greatly influence their health status, health risks, and outcomes. These social determinants also contribute to racial and ethnic disparities in maternal health outcomes that are persistent and are critical to address if we are to make progress on improving maternal health and reducing maternal mortality and morbidity in the United States. Everyone can work together to better understand these disparities and to identify and implement prevention strategies to achieve health equity.

As the strategies and actions in this Call to Action make clear, each of us has a critical role to play in improving maternal health and reversing the unacceptable rates of maternal mortality and severe maternal morbidity in the United States. This will provide the best opportunity for all women to have a safe passage through pregnancy and set a sustained course for their health and the health of future generations.