# 3 RISKS TO MATERNAL HEALTH

Many health conditions that are present prior to pregnancy may worsen or cause complications during pregnancy. These conditions can potentially lead to death or other adverse outcomes for the mother and/or baby. High blood pressure (hypertension), diabetes, unhealthy weight, and infectious diseases, warrant special attention in the context of pregnancy. Other important risk factors, such as substance use and substance use disorders, mental health conditions, and intimate partner violence (IPV) can also contribute to adverse outcomes.

Some groups of women are more likely to have these conditions than others. For example, Native Hawaiian or Pacific Islander, AI/AN, and black women have higher rates of pre-pregnancy overweight and obesity than non-Hispanic white women.^17^ Compared to white women, AI/AN women are more than twice as likely to have a diagnosis of diabetes prior to pregnancy.^17^ Black women ages 20–44 years have a prevalence of hypertension more than twice that of other racial and ethnic groups.^24^ White women have the highest rates of prescription opioid overdoses as compared to other ethnic groups.^25^

Reproductive-aged women with disabilities (such as difficulty with vision, hearing, mobility, cognition, self-care, or independent living) are more likely to have risks to healthy pregnancies compared to women without disabilities, including high blood pressure, cardiovascular conditions, diabetes, weight concerns, and mental health concerns, and are also at higher risk for poor birth outcomes.^26,27,28^

## HIGH BLOOD PRESSURE (HYPERTENSION)

In 2017–2018, approximately 13 percent of women aged 18–39 years had chronic hypertension.^29^ Chronic hypertension has increased among pregnant women over time, largely due to increasing rates of obesity and increased maternal age.^30^ Women with hypertension are at higher risk for pregnancy complications such as superimposed preeclampsia, placental abruption (premature separation of the placenta from the uterus associated with abnormal bleeding), kidney failure, and cesarean delivery.^31^ Complications for the infant can also occur, including premature birth and fetal growth restriction.^31^ National guidelines now recommend that individuals self-monitor their blood pressure outside the clinical setting and work closely with their healthcare teams and others to achieve optimal control of their hypertension.^32^

PREECLAMPSIA

A condition marked by high blood pressure during pregnancy and potential of damage to other organs, such as the kidneys (e.g., protein in the urine), liver, and brain

Gestational hypertension (high blood pressure that first occurs after 20 weeks of pregnancy) and preeclampsia are hypertensive disorders that occur specifically during pregnancy.^33^ Women with these conditions are at higher risk of future cardiovascular disease.^34,35,36,37,38^

## DIABETES

Diabetes is a disease that occurs when blood glucose, also called blood sugar, is too high. In 2011–2016, approximately 3 percent of women aged 20–44 years were diagnosed with diabetes and for more than half of these women their diabetes was not under control.^24^ Over time, diabetes can lead to serious problems, such as heart disease and stroke, as well as damage to the eyes, kidneys, and nerves.^39^

Women with diabetes prior to pregnancy are at higher risk for pregnancy complications, such as preeclampsia, cesarean section, miscarriage or stillbirth, preterm birth, birth defects, and macrosomia (larger than average infant).^40^

Gestational diabetes is a type of diabetes that occurs during pregnancy. In 2018, approximately 7 percent of women who gave birth in the U.S. had gestational diabetes.^17^ Women with gestational diabetes are also at increased risk of complications during pregnancy and delivery, including preeclampsia, cesarean section, fetal macrosomia, shoulder dystocia (baby’s shoulders become stuck in maternal pelvis during delivery), and prematurity.^41^

Approximately half of women who have gestational diabetes will develop type 2 diabetes later in life.^41^ Infants born to women with gestational diabetes are at higher risk of developing overweight and obesity in childhood.^42^ Children who are overweight or obese are more likely to be overweight in adulthood.^43^

GESTATIONAL DIABETES

A type of diabetes that is first seen in a pregnant woman who did not have diabetes before she was pregnant

## UNHEALTHY WEIGHT

Body mass index (BMI) is a screening tool that is used to define weight categories and is based on a person’s height and weight. Weight categories include: underweight (<18.5 kg/m^2^), normal weight (18.5–24.9 kg/m^2^), overweight (25– 29.9 kg/m^2^) and obese (≥30 kg/m^2^).^44^

The U.S. is currently experiencing a decades-long obesity epidemic. Obesity is associated with many diseases and other health conditions, such as heart disease, type 2 diabetes, high blood pressure, stroke, sleep apnea, and mental illness.^45^ Over the past two decades, the prevalence of obesity has increased in the U.S., especially for adolescent girls and women.^46^ In 2015–2016, the prevalence of obesity was 20.9 percent among adolescent girls aged 12–19 years, 36.5 percent among women aged 20–39 years, and 44.7 percent among those aged 40–59 years.^47^

There has also been an increase in the proportion of women who enter pregnancy either overweight or obese.^48^ From 2011 to 2015, there was an 8 percent increase in the prevalence of pre-pregnancy obesity.^48^ Obesity can increase the risk of pregnancy-related conditions, including gestational diabetes^49^ and preeclampsia.^50^ Pregnant women with obesity are also at increased risk of cesarean delivery^51^ and adverse infant outcomes, including preterm birth, stillbirth, macrosomia, and birth defects.^52^

The amount of weight gained during pregnancy is important for the health and well-being of women and their infants. Recommendations for healthy weight gain during pregnancy are based on pre-pregnancy BMI and vary from 11 to 40 pounds (for singleton pregnancies) to 25–62 pounds (for twin pregnancies).^53,54,55^

## INFECTIOUS DISEASES

Infectious diseases can complicate pregnancies and place a woman and her infant at risk for adverse events.^56^ These can include viral infections (e.g., influenza, viral hepatitis, rubella, human immunodeficiency virus or HIV) as well as bacterial infections (e.g., tuberculosis, listeriosis, urinary tract infections, gonorrhea, syphilis, chlamydia and other sexually transmitted infections). Prenatal care includes screening and/or testing for many infectious diseases. Routine immunizations^57^ are important for protecting against infectious diseases.

COVID-19 is an emerging viral disease that has impacted millions of individuals across the world. Recent evidence suggests that among reproductive-aged women (aged 15–44 years) with COVID-19, pregnant women are more likely to be hospitalized, admitted into an intensive care unit, and to receive mechanical ventilation as compared to non-pregnant women.^58^ Information is still emerging about the impact of COVID-19 on maternal and infant health outcomes.

## SUBSTANCE USE AND SUBSTANCE USE DISORDERS

In the 2018 National Survey on Drug Use and Health, approximately 12 percent of pregnant women reported using tobacco products in the previous month.^59^ During the same time period, nearly 10 percent of pregnant women reported using alcohol and approximately 5 percent reported drug use (marijuana, opioids, cocaine, and others) in the past month.^59^ These substances can harm a mother and her infant. Complications during pregnancy, which vary by substance used, may include ectopic (outside the uterus) pregnancy, miscarriage, or stillbirth; other complications that may affect the baby include Sudden Infant Death Syndrome (SIDS), fetal alcohol spectrum disorders, neonatal abstinence syndrome (group of symptoms affecting babies exposed to drugs, commonly opioids while in the uterus), birth defects, premature birth, or low birth weight.^60,61,62^

Substance use disorders occur when the repeated use of alcohol and/or drugs causes significant impairment, including health problems, disability, and failure to meet major responsibilities at work, school, or home.^63^ Substance use disorders are often underdiagnosed among women, occur regardless of sociodemographic characteristics, and result in high costs for individuals, families, and society.^64^ During 1999–2014, national rates of opioid use disorder at delivery more than quadrupled, increasing from 1.5 to 6.5 per 1,000 delivery hospitalizations.^65^

Substance use disorders can be identified and effectively treated prior to a woman becoming pregnant as well as during pregnancy.^64^ Non-medication treatments, such as cognitive behavioral therapy and motivational enhancement therapy as well as contingency management, which provides rewards or incentives for treatment participation, are commonly used in the treatment of substance use disorders.^66^ For some substance use disorders, such as opioid use disorder,^67^ medications are the primary treatment.

## MENTAL HEALTH

Each year more than 20 percent of U.S. women experience a mental, behavioral, or emotional disorder, such as depression or anxiety.^68^ Mental health conditions are also common complications during pregnancy^69^ and in the postpartum period^70^ and may contribute to poor maternal outcomes. Data from 14 state MMRCs between 2008 and 2017 showed that almost 10 percent of pregnancy-related deaths were due (in whole or in part) to mental health conditions.^10^ These conditions serve as underlying factors in injury or death due to overdose or suicide. Mental health conditions in the postpartum period, such as postpartum depression, are associated with poorer maternal and infant bonding, decreased breastfeeding initiation, and delayed infant development.^71^

## INTIMATE PARTNER VIOLENCE

More than one in three U.S. women report having experienced IPV during their lifetime.^72^ This includes physical violence, sexual violence, stalking, and psychological aggression by a current or former intimate partner.^73^ IPV often begins or escalates during the pregnancy and postpartum periods, making women and their infants especially vulnerable during this time.^74,75^ IPV is also associated with an increased risk of adverse maternal and neonatal outcomes, including homicide, suicide, depression, low birth weight, and preterm birth.^76,77^ In some U.S. states, homicide during pregnancy and the postpartum period surpasses any single obstetric or other cause of death for this population.^74,78^