# APPENDIX C ACKNOWLEDGMENTS

The Surgeon General’s Call to Action to Improve Maternal Health was prepared under the direction of the Office of the Surgeon General, and supported by the Office on Women’s Health, and published by the U.S. Department of Health and Human Services. Representatives from the Health Resources and Services Administration, the Indian Health Service and the Centers for Medicare & Medicaid Services, which are part of the U.S. Department of Health and Human Services, collaborated and sought input on the current state of maternal mortality and morbidity and to identify priority actions and directions for concerted national efforts to improve maternal and infant health. The group also reviewed recommendations and priorities delineated at various meetings, including five HHS-led round table discussions which occurred in August and September 2019, and included members of professional organizations, payors, clinicians, advocacy groups, and hospitals and health systems.

## SENIOR LEADERSHIP

- VADM Jerome M. Adams, M.D., MPH
  U.S. Surgeon General
- ADM Brett P. Giroir, M.D.
  Assistant Secretary for Health
- Diane Foley, M.D.
  Acting Principal Deputy Assistant Secretary for Health
- RADM Sylvia Trent-Adams, PhD, RN *
  * These individuals are no longer in Federal service at the time of publication.
  Principal Deputy Assistant Secretary for Health

## FEDERAL WRITING GROUP

- Sharon P. McKiernan, M.D. ^†^
  † Dr. McKiernan is currently employed by the Defense Health Agency (DHA).
  Indian Health Service (IHS)
- Catherine J. Vladutiu, PhD, MPH
  Maternal and Child Health Bureau
  Health Resources and Services Administration (HRSA)

## CONTRIBUTORS

### CENTERS FOR DISEASE CONTROL AND PREVENTION

- RADM Wanda Barfield, M.D., MPH
  Division of Reproductive Health
  National Center for Chronic Disease Prevention and Health Promotion
- Amy Branum, MSPH, PhD
  National Center for Health Statistics
- Elizabeth Cassidy, MPH
  Division of Reproductive Health
  National Center for Chronic Disease Prevention and Health Promotion
- Shanna Cox, MSPH
  Division of Reproductive Health
  National Center for Chronic Disease Prevention and Health Promotion
- Sarah Foster, MPH
  Division of Reproductive Health
  National Center for Chronic Disease Prevention and Health Promotion
- Dave Goodman, MS, PhD
  Division of Reproductive Health
  National Center for Chronic Disease Prevention and Health Promotion
- Toby Merkt, MPH
  Division of Reproductive Health
  National Center for Chronic Disease Prevention and Health Promotion
- Lauren Rossen, PhD
  National Center for Health Statistics
- Julie Zaharatos, MPH
  Division of Reproductive Health
  National Center for Chronic Disease Prevention and Health Promotion

### CENTERS FOR MEDICARE & MEDICAID SERVICES

- Devon Trolley, MHA *
  Office of the Administrator
- Tiffany Wiggins, M.D., MPH
  Center for Medicare and Medicaid Innovation

### HEALTH RESOURCES AND SERVICES ADMINISTRATION

- Laura Kavanagh, MPP
  Maternal and Child Health Bureau
- Michael D. Warren, M.D. MPH, FAAP
  Maternal and Child Health Bureau

### INDIAN HEALTH SERVICE

- Jean E. Howe, MD, MPH
- RADM Timothy L. Ricks, DMD, MAP FICD
- RADM Michael Toedt, M.D.

### OFFICE OF THE SECRETARY

- RADM Felicia Collins, M.D., MPH
  Office of Minority Health
- Sandra Howard, BA
  Office of Minority Health
- Mandar Bodas, PhD, MHA
  Office of the Assistant Secretary for Planning and Evaluation
- Andre Chappel, PhD
  Office of the Assistant Secretary for Planning and Evaluation
- Dorothy Fink, M.D.
  Office on Women’s Health
- LCDR Courtney E. Gustin, DrPH, CNM, RN
  Office on Women’s Health

### OFFICE OF THE SURGEON GENERAL

- Erica Palladino, MPH
- Janet S. Wright, MD, FACC