# APPENDIX B GOVERNMENT PROGRAMS AND RESOURCES

## ADMINISTRATION FOR COMMUNITY LIVING (ACL)

- Center for Human Dignity and Health Access for Individuals with Disabilities: https://acl.gov/grants/human-dignity-and-civilrights-people-disabilities
- ACL Fact Sheet: Accessible Medical Diagnostic Equipment: https://acl.gov/sites/default/files/Aging%20and%20Disability%20in%20America/MDE%20Fact%20Sheet%20Final.docx
- ACL NIDILRR-funded National Research Center for Parents with Disabilities, Parents Empowering Parents and investigators: https://heller.brandeis.edu/parentswith-Disabilities
- Parenting with a Disability - The Looking Glass: https://lookingglass.org/nationalservices/national-center
- Association of Maternal and Child Health Programs Toolbox on Women’s Health and Disability: http://www.amchp.org/programsandtopics/womens-health/Focus%20Areas/WomensHealthDisability/Pages/default.aspx
- National Council on Disability “Rocking the Cradle: Ensuring the Rights of Parents with Disabilities”: https://www.ncd.gov/publications/2012/Sep272012

## AGENCY FOR HEALTHCARE RESEARCH AND QUALITY (AHRQ)

- Evidence-based Practice Center (EPC) Program: https://www.ahrq.gov/research/findings/evidence-based-reports/index.html
- The Healthcare Cost and Utilization Project (HCUP): https://www.hcup-us.ahrq.gov/
- The National Healthcare Quality and Disparities Report: https://nhqrnet.ahrq.gov/inhqrdr/ or https://www.ahrq.gov/research/findings/nhqrdr/index.html
- Safety Program for Perinatal Care (SPPC) toolkit: https://www.ahrq.gov/hai/tools/perinatal-care/index.html

## CENTERS FOR MEDICARE & MEDICAID SERVICES (CMS)

- Rural Maternal Health: https://www.cms.gov/About-CMS/Agency-Information/OMH/equity-initiatives/rural-health/rural-maternal-health
- Strong Start for Mothers and Newborns Initiative: https://innovation.cms.gov/innovation-models/strong-start
- Maternal Opioid Misuse (MOM) Model: https://innovation.cms.gov/initiatives/maternal-opioid-misuse-model/
- Integrated Care for Kids (InCK) Model: https://innovation.cms.gov/innovation-models/integrated-care-for-kids-model
- Maternal & Infant Health Initiative: https://www.medicaid.gov/medicaid/quality-of-care/improvement-initiatives/maternal-and-infant-health/index.html
- Medicaid Adult and Child Core Measure Sets:
  - Adult Core Set : https://www.medicaid.gov/medicaid/quality-of-care/downloads/performance-measurement/2020-adult-core-set.pdf
  - Child Core Measure Set: https://www.medicaid.gov/medicaid/quality-of-care/performance-measurement/adult-and-child-health-care-quality-measures/childrens-health-care-quality-measures/index.html
  - Maternity Core Set: https://www.medicaid.gov/medicaid/quality-of-care/downloads/performance-measurement/2020-maternity-core-set.pdf
- Medicaid and CHIP Scorecard: https://www.medicaid.gov/state-overviews/scorecard/index.html
- Medicaid Maternal Depression Screening: https://www.medicaid.gov/sites/default/files/Federal-Policy-Guidance/Downloads/cib051116.pdf

## CENTERS FOR DISEASE CONTROL AND PREVENTION (CDC)

- Hear Her Campaign: https://www.cdc.gov/hearher/index.html
- Pregnancy-related Mortality Surveillance System: https://www.cdc.gov/reproductivehealth/maternal-mortality/pregnancy-mortality-surveillance-system.htm
- National Center for Health Statistics Maternal Mortality Data and Resources: https://www.cdc.gov/nchs/maternal-mortality/index.htm
- Enhancing Reviews and Surveillance to Eliminate Maternal Mortality (ERASE MM): https://www.cdc.gov/erase-mm
- Perinatal Quality Collaboratives: https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pqc.htm
- CDC Levels of Care Assessment Tool (CDC LOCATe): https://www.cdc.gov/reproductivehealth/maternalinfanthealth/cdc-locate/index.html
- Million Hearts: https://millionhearts.hhs.gov/index.html
- Addressing Opioid Use Disorder to Improve Maternal and Infant Health: https://www.cdc.gov/reproductivehealth/maternalinfanthealth/substance-abuse/opioid-use-disorder-pregnancy/addressing-opioid-use-maternal-infant-htm
- Depression Among Women: https://www.cdc.gov/reproductivehealth/depression/index.htm
- US Medical Eligibility Criteria (US MEC) for Contraceptive Use, 2016: https://www.cdc.gov/reproductivehealth/contraception/mmwr/mec/summary.html
- US Selected Practice Recommendations (US SPR) for Contraceptive Use, 2016: https://www.cdc.gov/reproductivehealth/contraception/mmwr/spr/summary.html
- Treating for Two: Medicine and Pregnancy: https://www.cdc.gov/pregnancy/meds/treatingfortwo/index.html
- https://www.cdc.gov/hiv/group/gender/pregnantwomen/opt-out.html
- Sexually Transmitted Diseases Treatment Guidelines, 2015
- 2018 Sexually Transmitted Disease Surveillance Report

## HEALTH RESOURCES AND SERVICES ADMINISTRATION (HRSA)

- Remote Pregnancy Monitoring Challenge: https://mchbgrandchallenges.hrsa.gov/challenges/remote-pregnancy-monitoring
- Alliance for Innovation on Maternal Health (AIM): https://safehealthcareforeverywoman.org
- Infant Mortality Collaborative Improvement and Innovation Network (CoIIN): https://mchb.hrsa.gov/maternal-child-health-initiatives/collaborative-improvement-innovation-networks-coiins
- Preconception Collaborative Improvement and Innovation Network: https://beforeandbeyond.org/pchimcoiin/
- Screening and Treatment for Maternal Depression and Related Behavioral Disorders: https://mchb.hrsa.gov/maternal-child-health-initiatives/mental-behavioral-health/mdrbd
- Women’s Preventive Services Guidelines: https://www.womenspreventivehealth.org/wellwomanchart/
- Healthy Start Initiative: Eliminating Disparities in Perinatal Health: https://mchb.hrsa.gov/maternal-child-health-initiatives/healthy-start
- The Maternal, Infant, and Early Childhood Home Visiting Program: https://mchb.hrsa.gov/home-visiting
- Rural Maternity and Obstetrics Managements (RMOMS) Program:
  https://www.hrsa.gov/grants/find-funding/hrsa-19-094
  https://www.hhs.gov/about/news/2019/09/10/hhs-awards-9-million-new-models-obstetrics-care-rural-communities.html
- Supporting Maternal Health Innovation Programs – the Maternal Health Learning and Innovation Center: https://impact.fpg.unc.edu/what-we-do/maternal-health-learning-and-innovation-center
- State Maternal Health Innovation Programs: https://mchb.hrsa.gov/maternal-child-health-initiatives/fy20-state-maternal-health-innovation-awards
- Maternal and Child Health Research Networks: https://mchb.hrsa.gov/research/projects-networks.asp

## INDIAN HEALTH SERVICE (IHS)

- Breastfeeding Toolkit (referenced on Health Education Resources page): https://www.ihs.gov/healthed/resources/breastfeedingtoolkit/
- Tobacco Use/Statistics among Pregnant Women: https://www.ihs.gov/hpdp/tobaccoprevention/
- Healthy Weight Model/Across the Lifespan: https://www.ihs.gov/healthyweight/hwmodel/
- Healthy Weight for Life/Actions for Providers (discusses pre-conception/prenatal care, breastfeeding/infant feeding education and support): https://www.ihs.gov/healthyweight/providers/
- Baby Friendly Hospital Initiative/Promoting Breastfeeding: http://www.ihs.gov/babyfriendly/
- Hepatitis C and Pregnancy: https://www.ihs.gov/dccs/hcv/
- HIV: Clinical Information Guidelines (links to pediatric HIV infection/perinatal guidelines): https://www.ihs.gov/hivaids/clinicalinfo/guidelines/
- HIV Testing/IHS Guidelines/resources to CDC recommendation for breastfeeding:
  https://www.ihs.gov/hivaids/clinicalinfo/hivtesting/
  https://www.ihs.gov/hivaids/treatment/
- Opioid Use/Substance Abuse/Maternal Health/Child Health:
  https://www.ihs.gov/opioids/maternalchild/
  https://www.ihs.gov/opioids/childhealth/
  https://www.ihs.gov/asap/providers/maternaladdiction/ (linked on MCH page)
- Women’s Health – Maternal and Child Health page linking MCH topics: https://www.ihs.gov/womenshealth/maternalchildhealth/
- Diabetes Standards of Care & Clinical Practices: Preconception, Pregnancy, Postpartum: https://www.ihs.gov/diabetes/clinician-resources/soc/preconception-pregnancy-postpartum-diabetes1/

## NATIONAL INSTITUTES OF HEALTH (NIH)

- PregSource®: https://pregsource.nih.gov/
- HHS Task Force on Research Specific to Pregnant Women and Lactating Women (PRGLAC): https://www.nichd.nih.gov/about/advisory/PRGLAC
- The National Cancer Institute’s Smokefree Women website (free information and tools to help women quit smoking): https://women.smokefree.gov/

## OFFICE OF THE ASSISTANT SECRETARY FOR HEALTH (OASH)

- Office of Infectious Disease and HIV/AIDS Policy
  - Healthmap Vaccine Finder: https://vaccinefinder.org
- Office of Population Affairs: www.hhs.gov/opa/reproductive-health/index.html
- Office on Women’s Health
  - Pregnancy: https://www.womenshealth.gov/pregnancy
  - Breastfeeding: https://www.womenshealth.gov/breastfeeding
  - Mental health: https://www.womenshealth.gov/patient-materials/health-topic/mental-health

## OFFICE OF MINORITY HEALTH (OMH)

- National Standards for Culturally and Linguistically Appropriate Services: https://thinkculturalhealth.hhs.gov/clas

## SUBSTANCE ABUSE AND MENTAL HEALTH SERVICES ADMINISTRATION (SAMHSA)

- Marijuana Use and Pregnancy: https://attcnetwork.org/centers/network-coordinating-office/product/marijuana-use-and-pregnancy
- The Stigma is Real: Pregnant and Parenting Women with Substance Use Disorders: https://attcnetwork.org/centers/mountain-plains-attc/product/stigma-real-pregnant-and-parenting-women-substance-use
- Healing Two Generations: Care for Pregnant/Parenting Women with OUD/SUD (Webinar): https://attcnetwork.org/centers/northwest-attc/product/healing-two-generations-care-pregnantparenting-women-oudsud-webinar
- Healthy Pregnancy Healthy Baby Fact Sheet: https://store.samhsa.gov/product/Healthy-Pregnancy-Healthy-Baby-Fact-Sheets/SMA18-5071
- Opioid Use Disorder and Pregnancy: https://store.samhsa.gov/product/Opioid-Use-Disorder-and-Pregnancy/SMA18-5071FS1
- Treating Babies Who Were Exposed to Opioids Before Birth: https://store.samhsa.gov/product/Treating-Babies-Who-Were-Exposed-to-Opioids-Before-Birth/SMA18-5071FS3
- Good Care for You and Your Baby While Receiving Opioid Use Disorder Treatment: https://store.samhsa.gov/product/Good-Care-for-You-and-Your-Baby-While-Receiving-Opioid-Use-Disorder-Treatment/SMA18-5071FS4
- Clinical Guidance for Treating Pregnant and Parenting Women With Opioid Use Disorder and Their Infants: https://store.samhsa.gov/product/Clinical-Guidance-for-Treating-Pregnant-and-Parenting-Women-With-Opioid-Use-Disorder-and-Their-Infants/SMA18-5054
- A Collaborative Approach to the Treatment of Pregnant Women with Opioid Use Disorders https://store.samhsa.gov/product/A-Collaborative-Approach-to-the-Treatment-of-Pregnant-Women-with-Opioid-Use-Disorders/SMA16-4978