# APPENDIX A MEASURING MATERNAL DEATHS AND PREGNANCY-RELATED DEATHS

## NATIONAL VITAL STATISTICS SYSTEM

The Centers for Disease Control and Prevention’s (CDC’s) National Vital Statistics System (NVSS) measures maternal deaths using the WHO definition for maternal mortality.^5^ NVSS reports the maternal mortality rate (MMR) as the number of maternal deaths per 100,000 live births. This measure of maternal mortality is used to compare the U.S. to other countries that use the same measure.

## PREGNANCY MORTALITY SURVEILLANCE SYSTEM

A related but different measure is the pregnancy-related mortality ratio (PRMR), reported by the CDC Pregnancy Mortality Surveillance System (PMSS) as the number of pregnancy-related deaths per 100,000 live births. This measure includes all deaths that occur within one year of pregnancy from a cause related to the pregnancy or its management. The PMSS and NVSS measures also differ in other ways, including how the data are collected and how the cause of death is determined to be related to pregnancy or not.

The PMSS provides greater detail on the causes and circumstances surrounding a pregnancy-related death than what is found using vital records alone. PMSS receives death certificates linked with live birth or fetal death certificates, and additional data when available (e.g., autopsy reports, hospital discharge records, and media reports). All of the information obtained is summarized, and medically trained epidemiologists determine the cause and time of death related to the pregnancy. This allows for a thorough exploration and description of the causes and timing of death, which is critical for tailoring programs and interventions to reduce pregnancy-related deaths.

## MATERNAL MORTALITY REVIEW COMMITTEES

Beginning in the 1930s, maternal mortality review committees (MMRCs) were formed to examine pregnancy-related deaths for insights to help prevent future events.^187^ Today, MMRCs represent a critical tool in helping understand the factors driving maternal mortality and what we can do to prevent future deaths. The President’s 2021 Budget invests $24 million in the CDC to expand MMRCs to all 50 states to ensure every pregnancy-related death is examined. As limitations with death certificate data alone have been identified, and concerns about maternal mortality increased, there has been an increased emphasis on the importance of multi-disciplinary MMRCs to look at data sources beyond vital records, including medical records, social service records, autopsy reports, and other clinical and nonclinical data sources. They may also conduct interviews to develop a comprehensive understanding of the events surrounding the death.

These detailed reviews of deaths establish temporal and causal relationships to pregnancy. Committees evaluate contributing factors, assess preventability (whether there was at least some chance of averting the death by one or more reasonable changes to patient, family, healthcare provider, facility, systems, or community factors), and make recommendations for preventive action.^188^ These insights can inform quality improvement efforts throughout pregnancy and the year after delivery.

The Maternal Mortality Review Information Application (MMRIA) is a data system developed by the CDC as a key tool for MMRCs. MMRIA supports essential MMRC functions such as data abstraction, case narrative development, documentation of committee decisions, and analysis. This data system supports MMRCs in producing relevant and comparable data to inform policy, process, clinical care, and public health. MMRIA also supports efforts to aggregate MMRC findings across states to enable multi-state reporting.^189^

## SYSTEMS OF MATERNAL MORTALITY SURVEILLANCE IN THE UNITED STATES

Data Source | National Vital Statistics System | Pregnancy Mortality Surveillance System | Maternal Mortality Review Committees
Source of Classification | International Classification of Diseases (ICD), 10th Revision codes | Medical epidemiologists, utilizing Pregnancy Mortality Surveillance System codes | Multi-disciplinary committees
Strengths | Strongest source of historical data, dating back to 1900; Reliable basis for international comparison; Relies on readily available data from death certificates | Clinically relevant national measure of burden of maternal deaths; 30-year history | Allows for the most accurate identification and comprehensive review of deaths; Allows specific recommendations for development of local, state, and national prevention strategies that are informed by local context of deaths
Challenges | Constrained by the limited codes in the ICD; Does not capture sufficient detail to inform prevention strategies; Changes in ICD coding may affect comparisons over time | Limited to information primarily derived from death and birth certificates; Does not capture detailed; information on contributors to deaths | Resource-intensive; Reliant on data from multiple sources, including medical records, social records, autopsy reports, and informant interviews; Requires review by multiple stakeholders; Currently, MMRCs do not exist in each state, inhibiting use of this data for national surveillance

Table adapted from: St. Pierre A, Zaharatos J, Goodman D, Callaghan WM. Challenges and opportunities in identifying, reviewing, and preventing maternal deaths. Obstet Gynecol, 2018 Jan; 131(1): 138–142.29215526