# 7 ABBREVIATIONS

ACOG: American College of Obstetricians and Gynecologists
AHRQ: Agency for Healthcare Research and Quality
AIM: Alliance for Innovation on Maternal Health
AI/AN: American Indian/Alaska Native
BMI: Body mass index
CDC: Centers for Disease Control and Prevention
CHIP: Children’s Health Insurance Program
CMS: Centers for Medicare & Medicaid Services
EHR: Electronic Health Record
FDA: Food and Drug Administration
FLSA: Fair Labor Standards Act
FMLA: Family and Medical Leave Act
HCUP: Healthcare Cost and Utilization Project
HHS: U.S. Department of Health and Human Services
HRSA: Health Resources and Services Administration
IHS: Indian Health Service
IPV: Intimate Partner Violence
LOCATe: Levels of Care Assessment Tool (CDC)
MCHB: Maternal and Child Health Bureau
MMRC: Maternal Mortality Review Committee
MMRIA: Maternal Mortality Review Information Application
NDAA: National Defense Authorization Act
NHANES: National Health and Nutrition Examination Survey
NIH: National Institutes of Health
OASH: Office of the Assistant Secretary for Health
OECD: Organisation for Economic Co-operation and Development
OWH: Office on Women’s Health
PQC: Perinatal Quality Collaborative
PRAMS: Pregnancy Risk Assessment Monitoring System
SMFM: Society for Maternal-Fetal Medicine
SMM: Severe maternal morbidity
T-MSIS: Transformed Medicaid Statistical Information System
USPSTF: U.S. Preventive Services Task Force
WHO: World Health Organization
WIC: Special Supplemental Nutrition Program for Women, Infants, and Children