# Endnotes

1 The definition of social media has been highly debated over the past few decades. As a result, there isn’t a single, widely-accepted scholarly definition of social media. (Aichner et al., 2021) The definition may vary from the cited research in this document based on the methods used in each study. In making conclusions and recommendations, this document regards social media as “internet-based channels that allow users to opportunistically interact and selectively self-present, either in real-time or asynchronously, with both broad and narrow audiences who derive value from user-generated content and the perception of interaction with others.” (Carr & Hayes, 2015) For the purposes of this product, we did not include studies specific to online gaming or e-sports. Source: Aichner, T., Grünfelder, M., Maurer, O., & Jegeni, D. (2021). Twenty-Five Years of Social Media: A Review of Social Media Applications and Definitions from 1994 to 2019. Cyberpsychology, Behavior And Social Networking, 24(4), 215–222. 10.1089/cyber.2020.0134 33847527 Source: Carr, C. T., & Hayes, R. A. (2015). Social Media: Defining, Developing, and Divining. Atlantic Journal of Communication, 23:1, 46–65. 10.1080/15456870.2015.972282

2 Vogels, E., Gelles-Watnick, R. & Massarat, N. (2022). Teens, Social Media and Technology 2022. Pew Research Center: Internet, Science & Tech. United States of America. Retrieved from https://www.pewresearch.org/internet/2022/08/10/teens-social-media-and-technology-2022/

3 The minimum required age set by social media platforms is informed by the Children’s Online Privacy Protection Act that requires social media platforms to collect verifiable parental consent before collecting, storing, and sharing data from children under age 13. Source: Federal Trade Commission. (n.d.). Children’s Online Privacy Protection Act (“COPPA”). Federal Trade Commission. Retrieved from https://www.ftc.gov/legal-library/browse/statutes/childrens-online-privacy-protection-act (https://www.ftc.gov/legal-library/browse/rules/childrens-online-privacy-protection-rule-coppa)

4 Rideout, V., Peebles, A., Mann, S., & Robb, M. B. (2022). Common Sense Census: Media use by tweens and teens, 2021. San Francisco, CA: Common Sense. Retrieved from https://www.commonsensemedia.org/sites/default/files/research/report/8-18-census-integrated-report-final-web_0.pdf

5 It is important to note that many factors can shape mental health, and a comprehensive approach, including prevention strategies, will be needed to support and protect the mental health of children and adolescents. Source: Office of the Surgeon General (OSG). (2021). Protecting Youth Mental Health: The U.S. Surgeon General’s Advisory. US Department of Health and Human Services. Retrieved from https://www.hhs.gov/sites/default/files/surgeon-general-youth-mental-health-advisory.pdf

6 American Psychological Association. (2023). Health Advisory on Social Media Use in Adolescence. American Psychological Association. Retrieved from https://www.apa.org/topics/social-media-internet/health-advisory-adolescent-social-media-use.pdf

7 Beyens, I., Pouwels, J. L., van Driel, I. I., Keijsers, L., & Valkenburg, P. M. (2020). The effect of social media on well-being differs from adolescent to adolescent. Scientific reports, 10(1), 10763. 10.1038/s41598-020-67727-7 32612108

8 Hollis, C., Livingstone, S., & Sonuga-Barke, E. (2020). Editorial: The role of digital technology in children and young people’s mental health - a triple-edged sword?. Journal of child psychology and psychiatry, and allied disciplines, 61(8), 837–841. 10.1111/jcpp.13302 32706126

9 Uhls, Y. T., Ellison, N. B., & Subrahmanyam, K. (2017). Benefits and Costs of Social Media in Adolescence. Pediatrics, 140(Suppl 2), S67–S70. 10.1542/peds.2016-1758E 29093035

10 Fuhrmann, D., Knoll, L. J., & Blakemore, S. J. (2015). Adolescence as a Sensitive Period of Brain Development. Trends in cognitive sciences, 19(10), 558–566. 10.1016/j.tics.2015.07.008 26419496

11 Blakemore, S. J., & Mills, K. L. (2014). Is adolescence a sensitive period for sociocultural processing?. Annual review of psychology, 65, 187–207. 10.1146/annurev-psych-010213-115202

12 Romer D. (2010). Adolescent risk taking, impulsivity, and brain development: implications for prevention. Developmental psychobiology, 52(3), 263–276. 10.1002/dev.20442 20175097

13 National Academies of Sciences, Engineering, and Medicine (NASEM). (2019). The Promise of Adolescence: Realizing Opportunity for All Youth. Washington, DC: The National Academies Press. 10.17226/25388

14 Kessler, R. C., Amminger, G. P., Aguilar-Gaxiola, S., Alonso, J., Lee, S., & Ustün, T. B. (2007). Age of onset of mental disorders: a review of recent literature. Current opinion in psychiatry, 20(4), 359–364. 10.1097/YCO.0b013e32816ebc8c 17551351

15 Maza, M. T., Fox, K. A., Kwon, S. J., Flannery, J. E., Lindquist, K. A., Prinstein, M. J., & Telzer, E. H. (2023). Association of Habitual Checking Behaviors on Social Media With Longitudinal Functional Brain Development. JAMA pediatrics, 177(2), 160–167. 10.1001/jamapediatrics.2022.4924 36595277

16 Crone, E. A., & Konijn, E. A. (2018). Media use and brain development during adolescence. Nature communications, 9(1), 588. 10.1038/s41467-018-03126-x

17 Orben, A., Przybylski, A. K., Blakemore, S. J., & Kievit, R. A. (2022). Windows of developmental sensitivity to social media. Nature communications, 13(1), 1649. 10.1038/s41467-022-29296-3

18 Anderson, M. & Jiang, J. (2018). Teens’ Social Media Habits and Experiences. Pew Research Center: Internet, Science & Tech. United States of America. Retrieved from https://www.pewresearch.org/internet/2018/11/28/teens-social-media-habits-and-experiences/

19 Seabrook, E. M., Kern, M. L., & Rickard, N. S. (2016). Social Networking Sites, Depression, and Anxiety: A Systematic Review. JMIR mental health, 3(4), e50. 10.2196/mental.5842 27881357

20 According to the National Institutes of Health, sexual and gender minority (SGM) populations include, but are not limited to, individuals who identify as lesbian, gay, bisexual, asexual, transgender, Two-Spirit, queer, and/or intersex. Individuals with same-sex or -gender attractions or behaviors and those with a difference in sex development are also included. These populations also encompass those who do not self-identify with one of these terms but whose sexual orientation, gender identity or expression, or reproductive development is characterized by non-binary constructs of sexual orientation, gender, and/or sex. Source: U.S. Department of Health and Human Services. National Institutes of Health. (2022, December 8). Sex, gender, and Sexuality. National Institutes of Health. https://www.nih.gov/nih-style-guide/sex-gender-sexuality

21 Charmaraman, L., Hernandez, J., & Hodes, R. (2022). Marginalized and Understudied Populations Using Digital Media. In J. Nesi, E. Telzer, & M. Prinstein (Eds.), Handbook of Adolescent Digital Media Use and Mental Health (pp. 188-214). Cambridge: Cambridge University Press. 10.1017/9781108976237.011

22 Ybarra, M. L., Mitchell, K. J., Palmer, N. A., & Reisner, S. L. (2015). Online social support as a buffer against online and offline peer and sexual victimization among U.S. LGBT and non-LGBT youth. Child abuse & neglect, 39, 123–136. 10.1016/j.chiabu.2014.08.006 25192961

23 Berger, M. N., Taba, M., Marino, J. L., Lim, M. S. C., & Skinner, S. R. (2022). Social Media Use and Health and Well-being of Lesbian, Gay, Bisexual, Transgender, and Queer Youth: Systematic Review. Journal of medical Internet research, 24(9), e38449. 10.2196/38449 36129741

24 Nesi, J., Mann, S. and Robb, M. B. (2023). Teens and mental health: How girls really feel about social media. San Francisco, CA: Common Sense. Retrieved from https://www.commonsensemedia.org/sites/default/files/research/report/how-girls-really-feel-about-social-media-researchreport_final_1.pdf

25 Vogels, E., & Gelles-Watnick, R. (2023). Teens and social media: Key findings from Pew Research Center surveys. Pew Research Center: Internet, Science & Tech. United States of America. Retrieved from https://www.pewresearch.org/short-reads/2023/04/24/teens-and-social-media-key-findings-from-pew-research-center-surveys/

26 Kauer, S. D., Mangan, C., & Sanci, L. (2014). Do online mental health services improve help-seeking for young people? A systematic review. Journal of medical Internet research, 16(3), e66. 10.2196/jmir.3103 24594922

27 Rice, S. M., Goodall, J., Hetrick, S. E., Parker, A. G., Gilbertson, T., Amminger, G. P., Davey, C. G., McGorry, P. D., Gleeson, J., & Alvarez-Jimenez, M. (2014). Online and social networking interventions for the treatment of depression in young people: a systematic review. Journal of medical Internet research, 16(9), e206. 10.2196/jmir.3304 25226790

28 Ridout, B., & Campbell, A. (2018). The Use of Social Networking Sites in Mental Health Interventions for Young People: Systematic Review. Journal of medical Internet research, 20(12), e12244. 10.2196/12244 30563811

29 Kruzan, K. P., Williams, K. D. A., Meyerhoff, J., Yoo, D. W., O’Dwyer, L. C., De Choudhury, M., & Mohr, D. C. (2022). Social media-based interventions for adolescent and young adult mental health: A scoping review. Internet interventions, 30, 100578. 10.1016/j.invent.2022.100578 36204674

30 Riehm, K. E., Feder, K. A., Tormohlen, K. N., Crum, R. M., Young, A. S., Green, K. M., Pacek, L. R., La Flair, L. N., & Mojtabai, R. (2019). Associations Between Time Spent Using Social Media and Internalizing and Externalizing Problems Among US Youth. JAMA psychiatry, 76(12), 1266–1273. 10.1001/jamapsychiatry.2019.2325 31509167

31 Miech, R. A., Johnston, L. D., Bachman, J. G., O’Malley, P. M., Schulenberg, J. E., and Patrick, M. E. (2022). Monitoring the Future: A Continuing Study of American Youth (8th- and 10th-Grade Surveys), 2021. Inter-university Consortium for Political and Social Research [distributor]. 10.3886/ICPSR38502.v1

32 Braghieri, L., Levy, R., & Makarin, A. (2022). Social Media and Mental Health. American Economic Review, 112(11), 3660–3693. https://pubs.aeaweb.org/doi/abs/10.1257/aer.20211218

33 Doucleff, M. (2023, April 25). The Truth About Teens, Social Media and the Mental Health Crisis. NPR. Retrieved May 2, 2023, from https://www.npr.org/sections/health-shots/2023/04/25/1171773181/social-media-teens-mental-health

34 Hunt, M. G., Marx, R., Lipson, C., & Young, J. (2018). No more FOMO: Limiting social media decreases loneliness and depression. Journal of Social and Clinical Psychology, 37(10), 751–768. 10.1521/jscp.2018.37.10.751

35 From a mean Beck Depression Inventory (BDI) of 23 at baseline to a mean BDI of 14.5 at Week 4.

36 Allcott, H., Braghieri, L., Eichmeyer, S., & Gentzkow, M. (2020). The Welfare Effects of Social Media. American Economic Review, 110(3), 629–76. DOI: 10.1257/aer.20190658

37 Abi-Jaoude, E., Naylor, K. T., & Pignatiello, A. (2020). Smartphones, social media use and youth mental health. Canadian Medical Association journal, 192(6), E136–E141. 10.1503/cmaj.190434 32041697

38 Orben, A., & Przybylski, A. K. (2020). Reply to: Underestimating digital media harm. Nature human behaviour, 4(4), 349–351. 10.1038/s41562-020-0840-y

39 Twenge, J. M., Haidt, J., Lozano, J., & Cummins, K. M. (2022). Specification curve analysis shows that social media use is linked to poor mental health, especially among girls. Acta psychologica, 224, 103512. 10.1016/j.actpsy.2022.103512 35101738

40 Hamm, M. P., Newton, A. S., Chisholm, A., Shulhan, J., Milne, A., Sundar, P., Ennis, H., Scott, S. D., & Hartling, L. (2015). Prevalence and Effect of Cyberbullying on Children and Young People: A Scoping Review of Social Media Studies. JAMA pediatrics, 169(8), 770–777. 10.1001/jamapediatrics.2015.0944 26098362

41 Holland, G., & Tiggemann, M. (2016). A systematic review of the impact of the use of social networking sites on body image and disordered eating outcomes. Body image, 17, 100–110. 10.1016/j.bodyim.2016.02.008 26995158

42 Alonzo, R., Hussain, J., Stranges, S., & Anderson, K. K. (2021). Interplay between social media use, sleep quality, and mental health in youth: A systematic review. Sleep medicine reviews, 56, 101414. 10.1016/j.smrv.2020.101414 33385767

43 Kelly, Y., Zilanawala, A., Booker, C., & Sacker, A. (2019). Social Media Use and Adolescent Mental Health: Findings From the UK Millennium Cohort Study. EClinicalMedicine, 6, 59–68. 10.1016/j.eclinm.2018.12.005 31193561

44 Gelles-Watnick, R. (2022). Explicit Content, Time-wasting Are Key Social Media Worries For Parents Of U.S. Teens. Pew Research Center. United States of America. Retrieved from https://www.pewresearch.org/fact-tank/2022/12/15/explicit-content-time-wasting-are-key-social-media-worries-for-parents-of-u-s-teens/

45 Dyer C. (2022). Social media content contributed to teenager’s death “in more than a minimal way,” says coroner. BMJ (Clinical research ed.), 379, o2374. 10.1136/bmj.o2374 36191932

46 Carville, O. (2022, November 30). TikTok’s Viral Challenges Keep Luring Young Kids to Their Deaths. Bloomberg. Retrieved from https://www.bloomberg.com/news/features/2022-11-30/is-tiktok-responsible-if-kids-die-doing-dangerous-viral-challenges

47 Sumner, S. A., Ferguson, B., Bason, B., Dink, J., Yard, E., Hertz, M., Hilkert, B., Holland, K., Mercado-Crespo, M., Tang, S., & Jones, C. M. (2021). Association of Online Risk Factors With Subsequent Youth Suicide-Related Behaviors in the US. JAMA network open, 4(9), e2125860. 10.1001/jamanetworkopen.2021.25860 34542614

48 Dyson, M. P., Hartling, L., Shulhan, J., Chisholm, A., Milne, A., Sundar, P., Scott, S. D., & Newton, A. S. (2016). A Systematic Review of Social Media Use to Discuss and View Deliberate Self-Harm Acts. PloS one, 11(5), e0155813. 10.1371/journal.pone.0155813 27191728

49 Lonergan, A. R., Bussey, K., Fardouly, J., Griffiths, S., Murray, S. B., Hay, P., Mond, J., Trompeter, N., & Mitchison, D. (2020). Protect me from my selfie: Examining the association between photo-based social media behaviors and self-reported eating disorders in adolescence. The International journal of eating disorders, 53(5), 485–496. 10.1002/eat.23256 32259344

50 Meier, E. P., & Gray, J. (2014). Facebook photo activity associated with body image disturbance in adolescent girls. Cyberpsychology, behavior and social networking, 17(4), 199–206. 10.1089/cyber.2013.0305 24237288

51 Thai, H., Davis, C. G., Mahboob, W., Perry, S., Adams, A., & Goldfield, G. S. (2023). Reducing Social Media Use Improves Appearance and Weight Esteem in Youth With Emotional Distress. Psychology of Popular Media. 10.1037/ppm0000460.

52 Vogel, E. A., Rose, J. P., Roberts, L. R., & Eckles, K. (2014). Social comparison, social media, and self-esteem. Psychology of Popular Media Culture, 3(4), 206–222. 10.1037/ppm0000047

53 Nesi, J., & Prinstein, M. J. (2015). Using Social Media for Social Comparison and Feedback-Seeking: Gender and Popularity Moderate Associations with Depressive Symptoms. Journal of abnormal child psychology, 43(8), 1427–1438. 10.1007/s10802-015-0020-0 25899879

54 Appel, H., Gerlach, A. L., & Crusius, J. (2016). The Interplay Between Facebook Use, Social Comparison, Envy, And Depression. Current Opinion in Psychology, 9, 44–49. 10.1016/j.copsyc.2015.10.006

55 Kleemans, M., Daalmans, S., Carbaat, I., & Anschütz, D. (2018). Picture Perfect: The Direct Effect Of Manipulated Instagram Photos On Body Image In Adolescent Girls. Media Psychology, 21(1), 93–110. 10.1080/15213269.2016.1257392

56 Mabe, A. G., Forney, K. J., & Keel, P. K. (2014). Do You “Like” My Photo? Facebook Use Maintains Eating Disorder Risk. The International journal of eating disorders, 47(5), 516–523. 10.1002/eat.22254 25035882

57 Bickham, D.S., Hunt, E., Bediou, B., & Rich, M. (2022). Adolescent Media Use: Attitudes, Effects, and Online Experiences. Boston, MA: Boston Children’s Hospital Digital Wellness Lab. Retrieved from https://digitalwellnesslab.org/wp-content/uploads/Pulse-Survey_Adolescent-Attitudes-Effects-and-Experiences.pdf

58 Rideout, V., & Robb, M. B. (2018). Social media, social life: Teens reveal their experiences. San Francisco, CA: Common Sense Media. Retrieved from https://www.commonsensemedia.org/sites/default/files/research/report/2018-social-media-social-life-executive-summary-web.pdf

59 Alhajji, M., Bass, S., & Dai, T. (2019). Cyberbullying, Mental Health, and Violence in Adolescents and Associations With Sex and Race: Data From the 2015 Youth Risk Behavior Survey. Global pediatric health, 6, 2333794X19868887. 10.1177/2333794X19868887

60 Rice, E., Petering, R., Rhoades, H., Winetrobe, H., Goldbach, J., Plant, A., Montoya, J., & Kordic, T. (2015). Cyberbullying perpetration and victimization among middle-school students. American journal of public health, 105(3), e66–e72. 10.2105/AJPH.2014.302393 25602905

61 Vogels, E. (2022). Teens and Cyberbullying 2022. Pew Research Center: Internet, Science & Tech. United States of America. Retrieved from https://www.pewresearch.org/internet/2022/12/15/teens-and-cyberbullying-2022/

62 Wolak, J., Finkelhor, D., Walsh, W., & Treitman, L. (2018). Sextortion of Minors: Characteristics and Dynamics. The Journal of adolescent health, 62(1), 72–79. 10.1016/j.jadohealth.2017.08.014 29055647

63 Federal Bureau of Investigations. (2022, December 19). FBI and Partners Issue National Public Safety Alert on Financial Sextortion Schemes. FBI. Retrieved from https://www.fbi.gov/news/press-releases/fbi-and-partners-issue-national-public-safety-alert-on-financial-sextortion-schemes

64 U.S. Drug Enforcement Administration. (2021, July 23). DEA Washington warns of deadly counterfeit drugs on social media. DEA. Retrieved from https://www.dea.gov/stories/2021/2021-07/2021-07-23/counterfeit-drugs-social-media

65 Finkelhor, D., Turner, H.A., & Colburn, D. (2023). Which dynamics make online child sexual abuse and cyberstalking more emotionally impactful: Perpetrator identity and images? Child Abuse & Neglect, 137, 106020. 10.1016/j.chiabu.2023.106020 36657227

66 Finkelhor, D., Turner, H., & Colburn, D. (2022). Prevalence of Online Sexual Offenses Against Children in the US. JAMA network open, 5(10), e2234471. 10.1001/jamanetworkopen.2022.34471 36239942

67 5Rights Foundation. (2021). Pathways: How Digital Design Puts Children At Risk. Retrieved from https://5rightsfoundation.com/uploads/Pathways-how-digital-design-puts-children-at-risk.pdf

68 Kuss, D. J., & Griffiths, M. D. (2011). Online social networking and addiction--a review of the psychological literature. International journal of environmental research and public health, 8(9), 3528–3552. 10.3390/ijerph8093528 22016701

69 Griffiths, M.D. (2018). Adolescent social networking: How do social media operators facilitate habitual use? Education and Health, 36(3), 66–69. Retrieved from https://sheu.org.uk/sheux/EH/eh363mdg.pdf

70 Marino, C., Gini, G., Vieno, A., & Spada, M. M. (2018). The associations between problematic Facebook use, psychological distress and well-being among adolescents and young adults: A systematic review and meta-analysis. Journal of affective disorders, 226, 274–281. 10.1016/j.ypmed.2020.106270 29024900

71 Allcott, H., Gentzkow, M., & Song, L. (2022). Digital Addiction. American Economic Review, 112 (7): 2424–63. 10.1257/aer.20210867

72 Andreassen, C. S. (2015). Online Social Network Site Addiction: A Comprehensive Review. Current Addiction Reports, 2, 175–184. 10.1007/s40429-015-0056-9

73 He, Q., Turel, O., & Bechara, A. (2017). Brain anatomy alterations associated with Social Networking Site (SNS) addiction. Scientific reports, 7, 45064. 10.1038/srep45064 28332625

74 Montag, C., Markowetz, A., Blaszkiewicz, K., Andone, I., Lachmann, B., Sariyska, R., Trendafilov, B., Eibes, M., Kolb, J., Reuter, M., Weber, B., & Markett, S. (2017). Facebook Usage On Smartphones And Gray Matter Volume Of The Nucleus Accumbens. Behavioural Brain Research, 329, 221–228. 10.1016/j.bbr.2017.04.035 28442353

75 Shannon, H., Bush, K., Villeneuve, P. J., Hellemans, K. G., & Guimond, S. (2022). Problematic Social Media Use in Adolescents and Young Adults: Systematic Review and Meta-analysis. JMIR mental health, 9(4), e33450. 10.2196/33450 35436240

76 Boer, M., Stevens, G., Finkenauer, C., & van den Eijnden, R. (2020). Attention deficit hyperactivity disorder-symptoms, social media use intensity, and social media use problems in adolescents: Investigating directionality. Child Development, 91(4), e853–e865. 10.1111/cdev.13334 31654398

77 Franchina, V., Vanden Abeele, M., van Rooij, A. J., Lo Coco, G., & De Marez, L. (2018). Fear of Missing Out as a Predictor of Problematic Social Media Use and Phubbing Behavior among Flemish Adolescents. International Journal Of Environmental Research And Public Health, 15(10), 2319. 10.3390/ijerph15102319 30360407

78 Telzer, E. H., Goldenberg, D., Fuligni, A. J., Lieberman, M. D., & Gálvan, A. (2015). Sleep variability in adolescence is associated with altered brain development. Developmental cognitive neuroscience, 14, 16–22. 10.1016/j.dcn.2015.05.007 26093368

79 Liu, R. T., Steele, S. J., Hamilton, J. L., Do, Q. B. P., Furbish, K., Burke, T. A., Martinez, A. P., & Gerlus, N. (2020). Sleep and suicide: A systematic review and meta-analysis of longitudinal studies. Clinical psychology review, 81, 101895. 10.1016/j.cpr.2020.101895 32801085

80 Shochat, T., Cohen-Zion, M., & Tzischinsky, O. (2014). Functional consequences of inadequate sleep in adolescents: a systematic review. Sleep medicine reviews, 18(1), 75–87. 10.1016/j.smrv.2013.03.005 23806891

81 Dekkers, T. J., & van Hoorn, J. (2022). Understanding Problematic Social Media Use in Adolescents with Attention-Deficit/Hyperactivity Disorder (ADHD): A Narrative Review and Clinical Recommendations. Brain Sciences, 12(12), 1625. 10.3390/brainsci12121625 36552085

82 Ra, C. K., Cho, J., Stone, M. D., De La Cerda, J., Goldenson, N. I., Moroney, E., Tung, I., Lee, S. S., & Leventhal, A. M. (2018). Association of Digital Media Use With Subsequent Symptoms of Attention-Deficit/Hyperactivity Disorder Among Adolescents. JAMA, 320(3), 255–263. 10.1001/jama.2018.8931 30027248

83 Przybylski A. K., Murayama K., DeHaan C.R., & Gladwell V. (2013). Motivational, emotional, and behavioral correlates of fear of missing out. Computers in Human Behavior; 29:1841–1848.

84 Fioravanti, G., Casale, S., Benucci, S.B., Prostamo, A., Falone, A., Ricca, V., & Rotella, F. (2021). Fear of missing out and social networking sites use and abuse: A meta-analysis. Computers in Human Behavior, 122, 106839. 10.1016/j.chb.2021.106839

85 Odgers, C. L., & Jensen, M. R. (2020). Annual Research Review: Adolescent mental health in the digital age: facts, fears, and future directions. Journal of Child Psychology and Psychiatry, and Allied Disciplines, 61(3), 336–348. 10.1111/jcpp.13190 31951670

86 Office of the Surgeon General (OSG). (2021). Protecting Youth Mental Health: The U.S. Surgeon General’s Advisory. U.S. Department of Health and Human Services. Retrieved from https://www.hhs.gov/sites/default/files/surgeon-general-youth-mental-health-advisory.pdf

87 Odgers, C.L., Allen, N.B., Pfeifer, J.H., Dahl, R.E., Nesi, J., Schueller, S.M., Williams, J. L., & the National Scientific Council on Adolescence (2022). Engaging, safe, and evidence-based: What science tells us about how to promote positive development and decrease risk in online spaces, Council Report No 2. doi: 10.31234/osf.io/rvn8q

88 Clark, S. J., Schultz, S. L., Gebremariam, A., Singer, D. C., & Freed, G. L. (2021). Sharing too soon? Children and social media apps. C.S. Mott Children’s Hospital National Poll on Children’s Health, University of Michigan, 39(4). Retrieved from https://mottpoll.org/sites/default/files/documents/101821_SocialMedia.pdf

89 Auxier, B., Anderson, M., Perrin, A., & Turner, E. (2020). Parenting Children in the Age of Screens. Pew Research Center: Internet, Science & Tech. Retrieved from https://www.pewresearch.org/internet/2020/07/28/parenting-children-in-the-age-of-screens/

90 U.S. Consumer Product Safety Commission. (n.d.). Toy Safety Business Guidance & Small Entity Compliance Guide. U.S. Consumer Product Safety Commission. Retrieved from https://www.cpsc.gov/Business--Manufacturing/Business-Education/Toy-Safety-Business-Guidance-and-Small-Entity-Compliance-Guide

91 Unites States Department of Transportation. (n.d.). National Highway Traffic Safety Administration. Retrieved from https://www.nhtsa.gov/

92 U.S. Food and Drug Administration. (n.d.). Center for Drug Evaluation and Research. U.S. Food and Drug Administration. Retrieved from https://www.fda.gov/drugs

93 Australian Government, eSafety Commissioner. (nd). Safety by Design. Retrieved from https://www.esafety.gov.au/industry/safety-by-design

94 Information Commissioner’s Office. (nd). Introduction To The Age Appropriate Design Code. Retrieved from https://ico.org.uk/for-organisations/childrens-code-hub/

95 Perrino, J. (2022, July 27). Using “Safety By Design” To Address Online Harms. Brookings Institute. https://www.brookings.edu/techstream/using-safety-by-design-to-address-online-harms/

96 Lenhart, A., & Owens, K. (2021). The Unseen Teen: The Challenges of Building Healthy Tech for Young People. Data & Society. Retrieved from https://datasociety.net/library/the-unseen-teen/

97 American Academy of Pediatrics (AAP). (2018, October 8). Kids & Tech: Tips for parents in the Digital age. HealthyChildren.org. Retrieved from https://www.healthychildren.org/English/family-life/Media/Pages/Tips-for-Parents-Digital-Age.aspx

98 Morgan Stanley Alliance For Children’s Mental Health & Child Mind Institute. (2022, May). How to set limits on screen time and internet use. Retrieved from https://www.morganstanley.com/assets/pdfs/setting-limits-on-screen-time-tip-sheet.pdf

99 Ehmke, R. (2023, March 13). How using social media affects teenagers. Child Mind Institute. Retrieved from https://childmind.org/article/how-using-social-media-affects-teenagers/

100 American Psychological Association. (2019, December 12). Digital Guidelines: Promoting healthy technology use for children. American Psychological Association. Retrieved from https://www.apa.org/topics/social-media-internet/technology-use-children

101 US Department of Health and Human Services, Assistant Secretary for Public Affairs (ASPA). (2021, November 10). Prevent cyberbullying. StopBullying.gov. Retrieved from https://www.stopbullying.gov/cyberbullying/prevention https://www.stopbullying.gov/cyberbullying/how-to-report

102 National Academies of Sciences, Engineering, and Medicine (NASEM). (n.d.). Assessment of the Impact of Social Media on the Health and Wellbeing of Adolescents and Children. Retrieved from https://www.nationalacademies.org/our-work/assessment-of-the-impact-of-social-media-on-the-health-and-wellbeing-of-adolescents-and-children

103 American Academy of Pediatrics. (2023, February 7). Center of Excellence on Social Media and Youth Mental Health. Retrieved from https://www.aap.org/en/patient-care/media-and-children/center-of-excellence-on-social-media-and-youth-mental-health/#:~:text=What%20We%20Do,protect%20youth%20mental%20health%20online

104 American Academy of Pediatrics. (2017). Bright Futures Guidelines for Health Supervision of Infants, Children, and Adolescents (4th ed., pp. 229–234). American Academy of Pediatrics. https://downloads.aap.org/AAP/PDF/Bright%20Futures/BF4_HealthySocialMedia.pdf