# Critical Questions Remain Unanswered

Nearly every teenager in America uses social media, and yet we do not have enough evidence to conclude that it is sufficiently safe for them. Our children have become unknowing participants in a decades-long experiment. It is critical that independent researchers and technology companies work together to rapidly advance our understanding of the impact of social media on children and adolescents. This section describes the known gaps and proposes additional areas for research that warrant urgent consideration.

## Known Evidence Gaps

The relationship between social media and youth mental health is complex and potentially bidirectional.^19^ There is broad concern among the scientific community that a lack of access to data and lack of transparency from technology companies have been barriers to understanding the full scope and scale of the impact of social media on mental health and well-being. Most prior research to date has been correlational, focused on young adults or adults, and generated a range of results.^85^ Critical areas of research have been proposed to fill knowledge gaps and create evidence-based interventions, resources, and tools to support youth mental health.^86^ Thus, there is an urgent need for additional research including on, but not limited to, the following questions:

- How do in-person vs. digital social interactions differ in terms of the impact on health, and what are the unique contributions of social media behavior to social connectedness, social isolation, and mental health symptoms?
- What are the potential pathways through which social media may cause harm to children’s and adolescents’ mental health and well-being? For example:
  » How does social comparison affect one’s sense of life satisfaction and in-person relationships?
  » How does the use of social media, including specific designs and features, relate to dopamine pathways involved in motivation, reward, and addiction?
- What type of content, and at what frequency and intensity, generates the most harm? Through which modes of social media access (e.g., smartphone, computer) and design features? For which users and why?
- What are the beneficial effects of social media? For whom are the benefits greatest? In what ways, and under what circumstances?
- What individual-, community-, and societal-level factors may protect youth from the negative effects of social media?
- What types of strategies and approaches are effective in protecting the mental health and well-being of children and adolescents on social media (e.g., programs, policies, design features, interventions, norms)?
- How does social media use interact with a person’s developmental stage for measuring risk of mental health impact?

It is critical that independent researchers and technology companies work together to rapidly advance our understanding of the impact of social media on children and adolescents.