# References

1 U.S. Department of Health & Human Services. (2020 May 28). What is Mental Health. MentalHealth.gov. Accessed on November 10, 2021. Retrieved from https://www.mentalhealth.gov/basics/what-is-mental-health
2 U.S. Department of Health and Human Services. (1999) Mental health: A report of the Surgeon General, Rockville, MD. U.S. Department of Health and Human Services, Substance Abuse and Mental Health Services Administration, Center for Mental Health Services, National Institutes of Health, National Institute of Mental Health. Retrieved from https://profiles.nlm.nih.gov/101584932X120
3 U.S. National Library of Medicine. (2021 October 12). Mental Disorders. MedlinePlus. Accessed on November 10, 2021. Retrieved from https://medlineplus.gov/mentaldisorders.html
4 Cross-Disorder Group of the Psychiatric Genomics Consortium (2013). Identification of risk loci with shared effects on five major psychiatric disorders: a genome-wide analysis. Lancet (London, England), 381(9875), 1371–1379. 10.1016/S0140-6736(12)62129-1
5 Marshall M. (2020). The hidden links between mental disorders. Nature, 581(7806), 19–21. 10.1038/d41586-020-00922-8 32372044
6 Williams D. R. (2018). Stress and the Mental Health of Populations of Color: Advancing Our Understanding of Race-related Stressors. Journal of Health and Social Behavior, 59(4), 466–485. 10.1177/0022146518814251 30484715
7 Kalin N. H. (2021). Impacts of Structural Racism, Socioeconomic Deprivation, and Stigmatization on Mental Health. The American Journal of Psychiatry, 178(7), 575–578. 10.1176/appi.ajp.2021.21050524 34270339
8 Doom, J. R., Seok, D., Narayan, A. J., & Fox, K. R. (2021). Adverse and Benevolent Childhood Experiences Predict Mental Health During the COVID-19 Pandemic. Adversity and resilience science, 1–12. Advance online publication. 10.1007/s42844-021-00038-6
9 Hughes, K., Bellis, M. A., Hardcastle, K. A., Sethi, D., Butchart, A., Mikton, C., Jones, L., Dunne, M. P. (2017). The effect of multiple adverse childhood experiences on health: A systematic review and meta-analysis. The Lancet Public Health, 2(8), e356–e366.29253477
10 U.S. Department of Health and Human Services, Substance Abuse and Mental Health Services Administration. (2009). Risk and Protective Factors for Mental, Emotional and Behavioral Disorders Across the Life Cycle. https://www.csifdl.org/wp-content/uploads/2018/07/Risk-and-Protective-Factors-Study.pdf.
11 Trent, M., Dooley, D. G., Dougé, J., Section on Adolescent Health, Council on Community Pediatrics, & Committee on Adolescence. (2019). The Impact of Racism on Child and Adolescent Health. Pediatrics, 144(2), e20191765. 10.1542/peds.2019-1765 31358665
12 Bhushan D, Kotz K, McCall J, Wirtz S, Gilgoff R, Dube SR, Powers C, Olson-Morgan J, Galeste M, Patterson K, Harris L, Mills A, Bethell C, Burke Harris N, Office of the California Surgeon General. (2020). Roadmap for Resilience: The California Surgeon General’s Report on Adverse Childhood Experiences, Toxic Stress, and Health. Office of the California Surgeon General. DOI: 10.48019/PEAM8812
13 Centers for Disease Control and Prevention. (2021 April 6). What are adverse childhood experiences? Retrieved from https://www.cdc.gov/violenceprevention/aces/fastfact.html
14 Shonkoff, J. P., Garner, A. S., & Committee on Psychosocial Aspects of Child and Family Health, Committee `on Early Childhood, Adoption, and Dependent Care and Section on Developmental and Behavioral Pediatrics. (2012). The lifelong effects of early childhood adversity and toxic stress. Pediatrics, 129(1), e232–e246.22201156
15 Arango, C., Díaz-Caneja, C. M., McGorry, P. D., Rapoport, J., Sommer, I. E., Vorstman, J. A., McDaid, D., Marín, O., Serrano-Drozdowskyj, E., Freedman, R., & Carpenter, W. (2018). Preventive strategies for mental health. The Lancet. Psychiatry, 5(7), 591–604. 10.1016/S2215-0366(18)30057-9 29773478
16 Schmidt C. W. (2007). Environmental connections: a deeper look into mental illness. Environmental Health Perspectives, 115(8), A404–A410. 10.1289/ehp.115-a404 17687431
17 Perou, R., Bitsko, R. H., Blumberg, S. J., Pastor, P., Ghandour, R. M., Gfroerer, J. C., Hedden, S. L., Crosby, A. E., Visser, S. N., Schieve, L. A., Parks, S. E., Hall, J. E., Brody, D., Simile, C. M., Thompson, W. W., Baio, J., Avenevoli, S., Kogan, M. D., Huang, L. N., & Centers for Disease Control and Prevention (CDC) (2013). Mental health surveillance among children-United States, 2005-2011. MMWR. Morbidity and Mortality Weekly Report Supplements, 62(2), 1–35.
18 Whitney, D.G. & Peterson, M. (2019). US national and state-level prevalence of mental health disorders and disparities of mental health care use in children. JAMA Pediatrics, 173(4), 389–391. doi:10.1001/jamapediatrics.2018.5399 30742204
19 Centers for Disease Control and Prevention. (2020). Youth Risk Behavior Surveillance Data Summary & Trends Report: 2009-2019. Retrieved from https://www.cdc.gov/nchhstp/dear_colleague/2020/dcl-102320-YRBS-2009-2019-report.html
20 Kalb, L. G., Stapp, E. K., Ballard, E. D., Holingue, C., Keefer, A., & Riley, A. (2019). Trends in Psychiatric Emergency Department Visits Among Youth and Young Adults in the US. Pediatrics, 143(4), e20182192. 10.1542/peds.2018-2192 30886112
21 Curtin, S. C. (2020). State suicide rates among adolescents and young adults aged 10–24: United States, 2000–2018. National Vital Statistics Reports; vol 69 no 11. Hyattsville, MD: National Center for Health Statistics.
22 Curtin, S. C., Hedegaard, H., Ahmad, F. B. (2021). Provisional numbers and rates of suicide by month and demographic characteristics: United States, 2020. Vital Statistics Rapid Release; no 16. Hyattsville, MD: National Center for Health Statistics.
23 Armstrong, K. (2020 September 30). Technology in Context: The Surprising Social Upsides of Constant Connectivity. Association for Psychological Science. Accessed on November 30, 2021. Retrieved from https://www.psychologicalscience.org/observer/technology-social-context
24 Hagan, J. F., Shaw, J. S., & Duncan, M. P. (2017). Bright Futures: Guidelines for Health Supervision of Infants, Children, and Adolescents. 4th ed. Elk Grove Village, IL: American Academy of Pediatrics. https://brightfutures.aap.org/materials-and-tools/guidelines-and-pocket-guide/Pages/default.aspx
25 Twenge, J. M., Joiner, T. E., Rogers, M. L., & Martin, G. N. (2018). Increases in Depressive Symptoms, Suicide-Related Outcomes, and Suicide Rates Among U.S. Adolescents After 2010 and Links to Increased New Media Screen Time. Clinical Psychological Science, 6(1), 3–17. 10.1177/2167702617723376
26 Riehm, K. E., Feder, K. A., Tormohlen, K. N., Crum, R. M., Young, A. S., Green, K. M., Pacek, L. R., La Flair, L. N., & Mojtabai, R. (2019). Associations Between Time Spent Using Social Media and Internalizing and Externalizing Problems Among US Youth. JAMA psychiatry, 76(12), 1266–1273. 10.1001/jamapsychiatry.2019.2325 31509167
27 Kasser, T., & Ryan, R. M. (1996). Further Examining the American Dream: Differential Correlates of Intrinsic and Extrinsic Goals. Personality and Social Psychology Bulletin, 22(3), 280–287. 10.1177/0146167296223006
28 Eckersley, R., & Dear, K. (2002). Cultural correlates of youth suicide. Social science & medicine (1982), 55(11), 1891–1904. 10.1016/s0277-9536(01)00319-7 12406459
29 Twenge, J. M., Gentile, B., DeWall, C. N., Ma, D., Lacefield, K., & Schurtz, D. R. (2010). Birth cohort increases in psychopathology among young Americans, 1938-2007: A cross-temporal meta-analysis of the MMPI. Clinical Psychology Review, 30(2), 145–154. 10.1016/j.cpr.2009.10.005 19945203
30 Fairbrother, G., Stuber, J., Galea, S., Pfefferbaum, B., & Fleischman, A. R. (2004). Unmet need for counseling services by children in New York City after the September 11th attacks on the World Trade Center: implications for pediatricians. Pediatrics, 113(5), 1367–1374. 10.1542/peds.113.5.1367 15121955
31 Rodway, C., Tham, S. G., Ibrahim, S., Turnbull, P., Windfuhr, K., Shaw, J., Kapur, N., & Appleby, L. (2016). Suicide in children and young people in England: a consecutive case series. The Lancet Psychiatry, 3(8), 751–759. 10.1016/S2215-0366(16)30094-3 27236279
32 Golberstein, E., Gonzales, G., & Meara, E. (2019). How do economic downturns affect the mental health of children? Evidence from the National Health Interview Survey. Health Economics, 28(8), 955–970. 10.1002/hec.3885 31165566
33 Doepke, M., & Zilibotti, F. (2019). Love, money & parenting: How economics explains the way we raise our kids. Princeton, NJ: Princeton University Press.
34 Marks, E., Hickman, C., Pihkala, P., Clayton, S., Lewandowski, ER., Mayall, EE., Wray, B., Mellor, C., & van Susteren, L. (2021). Young People’s Voices on Climate Anxiety, Government Betrayal and Moral Injury: A Global Phenomenon. The Lancet. Preprint. 10.2139/ssrn.3918955
35 Clayton, S., Manning, C. M., Speiser, M., & Hill, A. N. (2021). Mental Health and Our Changing Climate: Impacts, Inequities, Responses. Washington, D.C.: American Psychological Association, and ecoAmerica.
36 McLean, C. P., Asnaani, A., Litz, B. T., & Hofmann, S. G. (2011). Gender differences in anxiety disorders: prevalence, course of illness, comorbidity and burden of illness. Journal of Psychiatric Research, 45(8), 1027–1035. 10.1016/j.jpsychires.2011.03.006 21439576
37 Salk, R. H., Hyde, J. S., & Abramson, L. Y. (2017). Gender differences in depression in representative national samples: Meta-analyses of diagnoses and symptoms. Psychological Bulletin, 143(8), 783–822. 10.1037/bul0000102 28447828
38 Hedegaard, H., Curtin, S. C., & Warner, M. (2020). Increase in suicide mortality in the United States, 1999–2018. NCHS Data Brief, (362), 1–8. Hyattsville, MD: National Center for Health Statistics.
39 Bridge JA, Horowitz LM, Fontanella CA, (2018). Age-Related Racial Disparity in Suicide Rates Among US Youths From 2001 Through 2015. JAMA Pediatrics, 172(7):697–699. doi:10.1001/jamapediatrics.2018.0399 29799931
40 Reiss F. (2013). Socioeconomic inequalities and mental health problems in children and adolescents: a systematic review. Social Science & Medicine (1982), 90, 24–31. 10.1016/j.socscimed.2013.04.026 23746605
41 Substance Abuse and Mental Health Services Administration. (2021). Key substance use and mental health indicators in the United States: Results from the 2020 National Survey on Drug Use and Health (HHS Publication No. PEP21-07-01-003, NSDUH Series H-56). Rockville, MD: Center for Behavioral Health Statistics and Quality, Substance Abuse and Mental Health Services Administration. Retrieved from https://www.samhsa.gov/data/
42 Hillis, S. D., Blenkinsop A., Villaveces A., Annor F. B., Liburd, L., Massetti, G. M., Demissie, Z., Mercy, J. A., Nelson, C. A., Cluver, L., Flaxman, S., Sherr, L., Donelly, C. A., Ratmann, O., & Unwin, J. T. (2021). Covid-19-Associated Orphanhood and Caregiver Death in the United States. Pediatrics. DOI: 10.1542/peds.2021-053760
43 Racine, N., McArthur, B. A., Cooke, J. E., Eirich, R., Zhu, J., & Madigan, S. (2021). Global Prevalence of Depressive and Anxiety Symptoms in Children and Adolescents During COVID-19: A Meta-analysis. JAMA Pediatrics, 175(11), 1142–1150. 10.1001/jamapediatrics.2021.2482 34369987
44 Sharma, M., Idele, P., Manzini, A., Aladro, CP., Ipince, A., Olsson, G., Banati, P., Anthony, D. (2021). Life in Lockdown: Child and adolescent mental health and well-being in the time of COVID-19, UNICEF Office of Research – Innocenti, Florence; pages 43–46, https://www.unicef-irc.org/publications/pdf/Life-in-Lockdown.pdf
45 Yard, E., Radhakrishnan, L., Ballesteros, M. F., Sheppard, M., Gates, A., Stein, Z., Hartnett, K., Kite-Powell, A., Rodgers, L., Adjemian, J., Ehlman, D. C., Holland, K., Idaikkadar, N., Ivey-Stephenson, A., Martinez, P., Law, R., & Stone, D. M. (2021). Emergency Department Visits for Suspected Suicide Attempts Among Persons Aged 12-25 Years Before and During the COVID-19 Pandemic - United States, January 2019-May 2021. MMWR. Morbidity and Mortality Weekly Report, 70(24), 888–894. 10.15585/mmwr.mm7024e1 34138833
46 The New York Times. (2020 June 9). Child Abuse Cases Drop 51 Percent. The Authorities Are Very Worried. Accessed on November 23, 2021. Retrieved from https://www.nytimes.com/2020/06/09/nyregion/coronavirus-nyc-child-abuse.html
47 Ssentongo, P., Fronterre, C., Ssentongo, A. E., Advani, S., Heilbrunn, E. S., Hazelton, J. P., Oh, J. S., McCall-Hosenfeld, J. S., & Chinchilli, V. M. (2021). Gun violence incidence during the COVID-19 pandemic is higher than before the pandemic in the United States. Scientific Reports, 11(1), 20654. 10.1038/s41598-021-98813-z 34675321
48 Office of the Surgeon General (OSG). (2021). Confronting Health Misinformation: The U.S. Surgeon General’s Advisory on Building a Healthy Information Environment. US Department of Health and Human Services. https://www.hhs.gov/sites/default/files/surgeon-general-misinformation-advisory.pdf
49 WHO, UN, UNICEF, UNDP, UNESCO, UNAIDS, ITU, UN Global Pulse, & IFRC. (2020, September 23). Managing the COVID-19 infodemic: Promoting healthy behaviours and mitigating the harm from misinformation and disinformation. World Health Organization. https://www.who.int/news/item/23-09-2020-managing-the-covid-19-infodemic-promoting-healthy-behaviours-andmitigating-the-harm-from-misinformation-and-disinformation
50 Johnston, W. M., & Davey, G. C. (2011). The psychological impact of negative TV news bulletins: the catastrophizing of personal worries. British Journal of Psychology (London, England: 1953), 88 (Pt 1), 85–91. 10.1111/j.2044-8295.1997.tb02622.x
51 Duan, L., Shao, X., Wang, Y., Huang, Y., Miao, J., Yang, X., & Zhu, G. (2020). An investigation of mental health status of children and adolescents in china during the outbreak of COVID-19. Journal of Affective Disorders, 275, 112–118. 10.1016/j.jad.2020.06.029 32658812
52 Goldmann, E., & Galea, S. (2014). Mental health consequences of disasters. Annual Review of Public Health, 35, 169–183. 10.1146/annurev-publhealth-032013-182435
53 Aknin, L. B., De Neve, J. E., Dunn, E. W., Fancourt, D., Goldberg, E., Helliwell, J., Jones, S.P., Karam, E., Layard, R., Lyubomirsky, S., Rzepa, A., Saxena, S., Thornton, E., VanderWeele, T., Whillans, A., Zaki, J., Caman, O.K., Ben Amor, Y. (2021, February 19). Mental health during the first year of the COVID-19 pandemic: A review and recommendations for moving forward. 10.31234/osf.io/zw93g
54 Brülhart, M., Klotzbücher, V., Lalive, R., & Reich, S. K. (2021). Mental health concerns during the COVID-19 pandemic as revealed by helpline calls. Nature, 10.1038/s41586-021-04099-6. Advance online publication. 10.1038/s41586-021-04099-6
55 Luchetti, M., Lee, J. H., Aschwanden, D., Sesker, A., Strickhouser, J. E., Terracciano, A., & Sutin, A. R. (2020). The trajectory of loneliness in response to COVID-19. American Psychologist, 75(7), 897–908. 10.1037/amp0000690
56 Appleby, L., Richards, N., Ibrahim, S., Turnbull, P., Rodway, C., & Kapur, N. (2021). Suicide in England in the COVID-19 pandemic: Early observational data from real time surveillance. The Lancet Regional Health. Europe, 4, 100110. 10.1016/j.lanepe.2021.100110 34557817
57 Ahmad, F. B., & Cisewski, J. A. (2021). Quarterly provisional estimates for selected indicators of mortality, 2019-Quarter 1, 2021. National Center for Health Statistics. National Vital Statistics System, Vital Statistics Rapid Release Program. Retrieved from https://www.cdc.gov/nchs/nvss/vsrr/mortality-dashboard.htm#
58 Roy, A., Breaux, R., Sciberras, E., Patel, P., Ferrara, E., Shroff, D., Cash, A., Dvorsky, M., Langberg, J., Quach, J., Melvin, G. A., Jackson, A., & Becker, S. P. (2021). A Preliminary Examination of Key Strategies, Challenges, and Benefits of Remote Learning Expressed by Parents During the COVID-19 Pandemic. 10.31234/osf.io/5ca4v
59 Wright, K. P., Jr, Linton, S. K., Withrow, D., Casiraghi, L., Lanza, S. M., Iglesia, H., Vetter, C., & Depner, C. M. (2020). Sleep in university students prior to and during COVID-19 Stay-at-Home orders. Current Biology: CB, 30(14), R797–R798. 10.1016/j.cub.2020.06.022 32693068
60 Vaillancourt, T., Brittain, H., Krygsman, A., Farrell, A. H., Landon, S., & Pepler, D. (2021). School bullying before and during COVID-19: Results from a population-based randomized design. Aggressive Behavior, 47, 557–569. 10.1002/ab.21986 34235773
61 Osgood, K., Sheldon-Dean, H., & Kimball, H. (2021). 2021 Children’s Mental Health Report: What we know about the COVID-19 pandemic’s impact on children’s mental health — and what we don’t know. Child Mind Institute.
62 Centers for Disease Control and Prevention. COVID Data Tracker. Trends in Number of COVID-19 Cases and Deaths in the US Reported to CDC, by State/Territory. Accessed on November 29, 2021. Retrieved from https://covid.cdc.gov/covid-data-tracker/#trends_dailydeaths
63 Jones, K. (2021). The Initial Impact of COVID-19 on Children and Youth (Birth to 24 years): Literature Review in Brief. Retrieved from https://aspe.hhs.gov/reports/impact-covid-19-children-youth
64 Nikolaidis, A., DeRosa, J., Kass, M., Droney, I., Alexander, L., Di Martino, A., Bromet, E., Merikangas, K., Milham, M. P., & Paksarian, D. (2021). Heterogeneity in COVID-19 Pandemic-Induced Lifestyle Stressors and Predicts Future Mental Health in Adults and Children in the US and UK. medRxiv : the preprint server for health sciences, 2021.08.10.21261860. 10.1101/2021.08.10.21261860
65 Fitzpatrick, K. M., Harris, C., & Drawve, G. (2020). Fear of COVID-19 and the mental health consequences in America. Psychological Trauma: Theory, Research, Practice, and Policy. 12(S1), S17–S21. 10.1037/tra0000924
66 Sugg, M. M., Runkle, J. D., Andersen, L., Weiser, J., & Michael, K. D. (2021). Crisis response among essential workers and their children during the COVID-19 pandemic. Preventive Medicine, 153, 106852. Advance online publication. 10.1016/j.ypmed.2021.106852 34673081
67 Griffith A. K. (2020). Parental Burnout and Child Maltreatment During the COVID-19 Pandemic. Journal of Family Violence, 1–7. Advance online publication. 10.1007/s10896-020-00172-2
68 Sinko, L., He, Y., Kishton, R. (2021). “The Stay at Home Order is Causing Things to Get Heated Up”: Family Conflict Dynamics During COVID-19 From The Perspectives of Youth Calling a National Child Abuse Hotline. J Fam Viol. 10.1007/s10896-021-00290-5
69 Esposito, S., Giannitto, N., Squarcia, A., Neglia, C., Argentiero, A., Minichetti, P., Cotugno, N. & Principi, N. (2021). Development of Psychological Problems Among Adolescents During School Closures Because of the COVID-19 Lockdown Phase in Italy: A Cross-Sectional Survey. Frontiers in Pediatrics, 8:628072. 10.3389/fped.2020.628072 33553079
70 Verlenden, J. V., Pampati, S., Rasberry, C. N., Liddon, N., Hertz, M., Kilmer, G., Viox, M. H., Lee, S., Cramer, N. K., Barrios, L. C., & Ethier, K. A. (2021). Association of Children’s Mode of School Instruction with Child and Parent Experiences and Well-Being During the COVID-19 Pandemic - COVID Experiences Survey, United States, October 8-November 13, 2020. MMWR. Morbidity and mortality weekly report, 70(11), 369–376. 10.15585/mmwr.mm7011a1 33735164
71 Hawrilenko M, Kroshus E, Tandon P, Christakis D. The Association Between School Closures and Child Mental Health During COVID-19. JAMA Netw Open. 2021;4(9):e2124092. doi:10.1001/jamanetworkopen.2021.24092 34477850
72 Stinson, E. A., Sullivan, R. M., Peteet, B. J., Tapert, S. F., Baker, F. C., Breslin, F. J., Dick, A. S., Gonzalez, M. R., Guillaume, M., Marshall, A. T., McCabe, C. J., Pelham, W. E., 3rd, Van Rinsveld, A. M., Sheth, C. S., Sowell, E. R., Wade, N. E., Wallace, A. L., & Lisdahl, K. M. (2021). Longitudinal Impact of Childhood Adversity on Early Adolescent Mental Health During the COVID-19 Pandemic in the ABCD Study® Cohort: Does Race or Ethnicity Moderate Findings?. Biological Psychiatry Global Open Science, 10.1016/j.bpsgos.2021.08.007. Advance online publication. 10.1016/j.bpsgos.2021.08.007
73 Henderson MD, Schmus CJ, McDonald C, Irving SY. (2020). The COVID-19 pandemic and the impact on child mental health: a socio-ecological perspective. Pediatric Nursing. 46(6). https://www.pediatricnursing.net/issues/20novdec/267.pdf
74 [Pediatrics publication not currently available] Hernandez, J. (2021, November 8). A study links facing discrimination at a young age with future mental health issues. NPR. Retrieved November 9, 2021, from https://www.npr.org/2021/11/08/1053632912/study-discrimination-young-age-future-mental-health-issue
75 Westrupp, E. M., Bennett, C., Berkowitz, T., Youssef, G. J., Toumbourou, J. W., Tucker, R., Andrews, F. J., Evans, S., Teague, S. J., Karantzas, G. C., Melvin, G. M., Olsson, C., Macdonald, J. A., Greenwood, C. J., Mikocka-Walus, A., Hutchinson, D., Fuller-Tyszkiewicz, M., Stokes, M. A., Olive, L., Wood, A. G., … Sciberras, E. (2021). Child, parent, and family mental health and functioning in Australia during COVID-19: comparison to pre-pandemic data. European child & adolescent psychiatry, 1–14. Advance online publication. 10.1007/s00787-021-01861-z 33219859
76 Patrick, S. W., Henkhaus, L. E., Zickafoose, J. S., Lovell, K., Halvorson, A., Loch, S., Letterie, M., & Davis, M. M. (2020). Well-being of Parents and Children During the COVID-19 Pandemic: A National Survey. Pediatrics, 146(4), e2020016824. 10.1542/peds.2020-016824 32709738
77 Bergman, A. S., Axberg, U., & Hanson, E. (2017). When a parent dies - a systematic review of the effects of support programs for parentally bereaved children and their caregivers. BMC palliative care, 16(1), 39. 10.1186/s12904-017-0223-y 28797262
78 White, L.C., Law, J.K., Daniels, A.M., Toroney, J., Vernoia, B., Xiao, S., The SPARK Consortium, Feliciano, P., & Chung, W.K. (2020). Brief Report: Impact of COVID-19 on individuals with ASD and their caregivers: A perspective form the SPARK cohort. Journal of Autism and Developmental Disorders. 10.1007/s10803-020-04816-6
79 Jeste, S., Hyde, C., Distefano, C., Halladay, A., Ray, S., Porath, M., Wilson, R. B., & Thurm, A. (2020). Changes in access to educational and healthcare services for individuals with intellectual and developmental disabilities during COVID-19 restrictions. Journal of intellectual disability research: JIDR, 10.1111/jir.12776. Advance online publication. 10.1111/jir.12776
80 Neece, C., McIntyre, L. L., & Fenning, R. (2020). Examining the impact of COVID-19 in ethnically diverse families with young children with intellectual and developmental disabilities. Journal of intellectual disability research: JIDR, 64(10), 739–749. 10.1111/jir.12769 32808424
81 Patel K. (2020). Mental health implications of COVID-19 on children with disabilities. Asian journal of psychiatry, 54, 102273. 10.1016/j.ajp.2020.102273 32653852
82 National Council on Disability. (2021). 2021 Progress Report: The Impact of COVID-19 on People with Disabilities. https://ncd.gov/sites/default/files/NCD_COVID-19_Progress_Report_508.pdf
83 Racial and ethnic disparities in pediatric mental health. Child and adolescent psychiatric clinics of North America, 19(4), 759–774. 10.1016/j.chc.2010.07.001)
84 American Indian Policy Institute. (2021). Tribal Digital Divide: Policy Brief and Recommendations. Accessed on November 10, 2021. Retrieved from https://aipi.asu.edu/sites/default/files/tribal_digital_divide_stimulus_bill_advocacy_04032020.pdf
85 Rogers, A. A., Ha, T., & Ockey, S. (2021). Adolescents’ Perceived Socio-Emotional Impact of COVID-19 and Implications for Mental Health: Results From a U.S.-Based Mixed-Methods Study. The Journal of adolescent health, 68(1), 43–52. 10.1016/j.jadohealth.2020.09.039 33143986
86 Flanagan, S., Margolius, M., Pileggi, M., Glaser L., Burkander, K., Kincheloe, M., & Freeman, J. (2021). Where Do We Go Next? Youth Insights on the High School Experience During a Year of Historic Upheaval. America’s Promise Alliance and Research for Action. https://www.researchforaction.org/wp-content/uploads/2021/07/where-do-we-go-next.pdf
87 Cheah, C., Wang, C., Ren, H., Zong, X., Cho, H. S., & Xue, X. (2020). COVID-19 Racism and Mental Health in Chinese American Families. Pediatrics, 146(5), e2020021816. 10.1542/peds.2020-021816 32873719
88 Wakabayashi, K., Cheah, C. S. L., Chang, T., Lai, G., Subrahmanyam, K., Chaudhary, N., Hyun, S., & Patel P. (2020). Addressing Inequities in Education: Considerations for Asian American Children and Youth in the Era of COVID-19. Society for Research in Child Development. https://www.srcd.org/research/addressing-inequities-education-considerations-asian-american-children-and-youth-era-covid
89 Panchal, N., Kamal, R., Cox, C., Garfield, R., & Chidambaram, P. (2021, May 26). Mental health and substance use considerations among children during the COVID-19 pandemic. Kaiser Family Foundation. https://www.kff.org/coronavirus-covid-19/issue-brief/mental-healthand-substance-use-considerations-among-children-during-the-covid19-pandemic/
90 Department of Education Office of Civil Rights. (2021). Education in a Pandemic: The Disparate Impacts of COVID-19 on America’s Students. https://www2.ed.gov/about/offices/list/ocr/docs/20210608-impacts-of-covid19.pdf
91 Dooley, D., Bandealy, A., & Tschudy, M. (2020). Low-income children and coronavirus disease 2019 (COVID-19) in the US. JAMA Pediatrics, 174(10), 922–923.32401283
92 Lai, J., & Widmar, N. O. (2020). Revisiting the Digital Divide in the COVID-19 Era. Applied economic perspectives and policy, 10.1002/aepp.13104. Advance online publication. 10.1002/aepp.13104
93 Endale, T., St Jean, N., & Birman, D. (2020). COVID-19 and refugee and immigrant youth: A community-based mental health perspective. Psychological trauma: theory, research, practice and policy, 12(S1), S225–S227. 10.1037/tra0000875
94 Robinson, L. R., Holbrook, J. R., Bitsko, R. H., Hartwig, S. A., Kaminski, J. W., Ghandour, R. M., Peacock, G., Heggs, A., & Boyle, C. A. (2017). Differences in Health Care, Family, and Community Factors Associated with Mental, Behavioral, and Developmental Disorders Among Children Aged 2-8 Years in Rural and Urban Areas - United States, 2011-2012. Morbidity and mortality weekly report. Surveillance summaries (Washington, D.C. : 2002), 66(8), 1–11. 10.15585/mmwr.ss6608a1
95 Lawrence, H. R., Burke, T. A., Sheehan, A. E., Pastro, B., Levin, R. Y., Walsh, R., Bettis, A. H., & Liu, R. T. (2021). Prevalence and correlates of suicidal ideation and suicide attempts in preadolescent children: A US population-based study. Translational psychiatry, 11(1), 489. 10.1038/s41398-021-01593-3 34552053
96 Development Services Group, Inc. (2017). “Intersection Between Mental Health and the Juvenile Justice System.” Literature review. Washington, D.C.: Office of Juvenile Justice and Delinquency Prevention. https://www.ojjdp.gov/mpg/litreviews/Intersection-Mental-Health-Juvenile-Justice.pdf
97 Houtrow, A., Harris, D., Molinero, A., Levin-Decanini, T., & Robichaud, C. (2020). Children with disabilities in the United States and the COVID-19 pandemic. Journal of pediatric rehabilitation medicine, 13(3), 415–424. 10.3233/PRM-200769 33185616
98 Kugelmass H. (2016). “Sorry, I’m Not Accepting New Patients”: An Audit Study of Access to Mental Health Care. Journal of health and social behavior, 57(2), 168–183. 10.1177/0022146516647098 27251890
99 Drescher J. (2015). Out of DSM: Depathologizing Homosexuality. Behavioral sciences (Basel, Switzerland), 5(4), 565–575. 10.3390/bs5040565
100 Centers for Disease Control and Prevention. (2021 October 14). Medical Conditions. Accessed on November 10, 2021. Retrieved from https://www.cdc.gov/coronavirus/2019-ncov/need-extra-precautions/people-with-medical-conditions.html
101 Fond, G., Nemani, K., Etchecopar-Etchart, D., Loundou, A., Goff, D. C., Lee, S. W., Lancon, C., Auquier, P., Baumstarck, K., Llorca, P. M., Yon, D. K., & Boyer, L. (2021). Association Between Mental Health Disorders and Mortality Among Patients With COVID-19 in 7 Countries: A Systematic Review and Meta-analysis. JAMA psychiatry, 78(11), 1208–1217. 10.1001/jamapsychiatry.2021.2274 34313711
102 Ceban, F., Nogo, D., Carvalho, I. P., Lee, Y., Nasri, F., Xiong, J., Lui, L., Subramaniapillai, M., Gill, H., Liu, R. N., Joseph, P., Teopiz, K. M., Cao, B., Mansur, R. B., Lin, K., Rosenblat, J. D., Ho, R. C., & McIntyre, R. S. (2021). Association Between Mood Disorders and Risk of COVID-19 Infection, Hospitalization, and Death: A Systematic Review and Meta-analysis. JAMA psychiatry, 78(10), 1079–1091. 10.1001/jamapsychiatry.2021.1818 34319365
103 World Economic Forum. (2020 October 9). 7 ways young people are making a difference in mental health. Accessed on November 10, 2021. Retrieved from https://www.weforum.org/agenda/2020/10/7-ways-young-people-making-a-difference-mental-health/
104 Packman, K.J. (2020 October 15). The pandemic has shown us that parents have a bigger role to play in education. Accessed on November 10, 2021. Retrieved from: https://www.involve.org.uk/resources/blog/opinion/pandemic-has-shown-us-parents-have-bigger-role-play-education
105 Edsource. (2021 March 19). Teachers reflect on a year of Covid: students struggling, others thriving. Accessed on November 10, 2021. Retrieved from: https://edsource.org/2021/teachers-reflect-on-a-year-of-covid-students-struggling-others-thriving/649705
106 Children’s Hospital Colorado. (2021). Providing Mental Health Care During the COVID-19 Pandemic. Accessed on November 10, 2021. Retrieved from https://www.childrenscolorado.org/health-professionals/coronavirus-professional-resources/clinical-guidance-practice-resources/providing-care-during-covid-19-pandemic/
107 Boys and Girls Club of America. (2020 March 19). Clubs Offer Critical Care During COVID-19. Accessed on November 10, 2021. Retrieved from https://www.bgca.org/news-stories/2020/March/Clubs-Offer-Critical-Care-During-COVID-19
108 Mental Health America. (2020 May 5). 8 Employers Supporting Employee Mental Health During COVID-19. Accessed on November 10, 2021. Retrieved from https://mhanational.org/blog/8-employers-supporting-employee-mental-health-during-covid-19
109 National Conference of State Legislatures. (2021 April 17). Bridging the gap to youth mental health during COVID-19. Accessed on November 10, 2021. Retrieved from https://www.ncsl.org/blog/2020/04/17/bridging-the-gap-to-youth-mental-health-during-covid-19.aspx
110 The White House. (2021 October 29). Fact Sheet: Biden Administration Announces Additional Actions to Increase COVID-19 Screening Testing in Schools and Keep Students Safe. https://www.whitehouse.gov/briefing-room/statements-releases/2021/10/29/fact-sheet-biden-administration-announces-additional-actions-to-increase-covid-19-screening-testing-in-schools-and-keep-students-safe/
111 The White House. (2021 July 15). FACT SHEET: Biden-Harris Administration Distributes First Monthly Payments of the Expanded Child Tax Credit. https://www.whitehouse.gov/briefing-room/statements-releases/2021/07/15/fact-sheet-biden-harris-administration-distributes-first-monthly-payments-of-the-expanded-child-tax-credit/
112 Department of Health and Human Services, Office of Disease Prevention and Health Promotion. (nd). Social Determinants of Health. Accessed on November 10, 2021. Retrieved from https://health.gov/healthypeople/objectives-and-data/social-determinants-health
113 Parolin, Zachary, Sophie Collyer, Megan A. Curran, and Christopher Wimer. 2021. “Monthly Poverty Rates among Children after Expansion of the Child Tax Credit.” Poverty and Social Policy Brief. Center on Poverty and Social Policy, Columbia University. Vol. 5, no. 4. https://www.povertycenter.columbia.edu/news-internal/monthly-poverty-july-2021
114 Roehlkepartain, E. C., Pekel, K., Syvertsen, A. K., Sethi, J., Sullivan, T. K., & Scales, P. C. (2017). Relationships First: Creating Connections that Help Young People Thrive. Minneapolis, MN: Search Institute. https://www.search-institute.org/wp-content/uploads/2017/12/2017-Relationships-First-final.pdf
115 Oberle, E., Guhn, M., Gadermann, A. M., Thomson, K., & Schonert-Reichl, K. A. (2018). Positive mental health and supportive school environments: A population-level longitudinal study of dispositional optimism and school relationships in early adolescence. Social science & medicine (1982), 214, 154–161. 10.1016/j.socscimed.2018.06.041 30072159
116 Ballard, P. J., Hoyt, L. T., & Pachucki, M. C. (2019). Impacts of Adolescent and Young Adult Civic Engagement on Health and Socioeconomic Status in Adulthood. Child development, 90(4), 1138–1154. 10.1111/cdev.12998 29359473
117 Spagnola, M., & Fiese, B. (2007). Family routines and rituals. Infants and Young Children, 20(4), 284–299. 10.1097/01.IYC.0000290352.32170.5A
118 Glynn, L. M., Davis, E. P., Luby, J. L., Baram, T. Z., & Sandman, C. A. (2021). A predictable home environment may protect child mental health during the COVID-19 pandemic. Neurobiology of stress, 14, 100291. 10.1016/j.ynstr.2020.100291 33532520
119 National Academies of Sciences, Engineering, and Medicine; Health and Medicine Division; Division of Behavioral and Social Sciences and Education; Board on Children, Youth, and Families; Committee on Applying Lessons of Optimal Adolescent Health to Improve Behavioral Outcomes for Youth, Kahn, N. F., & Graham, R. (Eds.). (2019). Promoting Positive Adolescent Health Behaviors and Outcomes: Thriving in the 21st Century. National Academies Press (US).
120 Centers for Disease Control and Prevention. (2021). Coping with Stress. Accessed on November 10, 2021. Retrieved from: https://www.cdc.gov/mentalhealth/stress-coping/cope-with-stress/index.html
121 The National Institute of Mental Health Information Resource Center. (2021). 5 Action Steps for Helping Someone in Emotional Pain. Accessed on November 10, 2021. Retrieved from: https://www.nimh.nih.gov/health/publications/5-action-steps-for-helping-someone-in-emotional-pain?utm_campaign=shareNIMH&utm_medium=Portal&utm_source=NIMHwebsite
122 Substance Abuse and Mental Health Administration. (2016). Creating a Youth Advisory Board. Accessed on November 12, 2021. Retrieved from https://youthmovenational.org/wp-content/uploads/2019/05/T2C_3-Final_Youth_Advisory_Boards.pdf
123 Centers for Disease Control and Prevention. (2021). Care for Yourself. Accessed on November 12, 2021. Retrieved from: https://www.cdc.gov/mentalhealth/stress-coping/care-for-yourself/index.html
124 National Scientific Council on the Developing Child (2015). Supportive Relationships and Active Skill-Building Strengthen the Foundations of Resilience: Working Paper No. 13. Retrieved from www.developingchild.harvard.edu
125 U.S. Department of Justice, Office of Juvenile Justice and Delinquency Prevention. (nd). Mentoring. Accessed on November 12, 2021. Retrieved from https://ojjdp.ojp.gov/programs/mentoring
126 Whitebread D. (2017). Free play and children’s mental health. The Lancet. Child & adolescent health, 1(3), 167–169. 10.1016/S2352-4642(17)30092-5 30169163
127 Masten, A. S. (2014). Ordinary magic: Resilience in development. New York, NY: Guilford Press. 10.1002/imhj.21625
128 American Psychological Association. (2021 January 14). How to talk to children about difficult news. Accessed on November 29, 2021. Retrieved from https://www.apa.org/topics/stress/talking
129 Centers for Disease Control and Prevention. (2021 January 5). Risk and Protective Factors. Accessed on November 12, 2021. Retrieved from https://www.cdc.gov/violenceprevention/aces/riskprotectivefactors.html
130 Centers for Disease Control and Prevention. (2020 February 10). Teen Substance Use & Risks. Accessed on November 30, 2021. Retrieved from https://www.cdc.gov/ncbddd/fasd/features/teen-substance-use.html
131 Hingson, R. W., & Zha, W. (2009). Age of drinking onset, alcohol use disorders, frequent heavy drinking, and unintentionally injuring oneself and others after drinking. Pediatrics, 123(6), 1477–1484. 10.1542/peds.2008-2176 19482757
132 Substance Abuse and Mental Health Services Administration. (2021 November 9). Warning Signs and Risk Factors for Emotional Distress. Accessed on November 30, 2021. Retrieved from https://www.samhsa.gov/find-help/disaster-distress-helpline/warning-signs-risk-factors
133 Centers for Disease Control and Prevention. (2021 May 11). Alcohol Use and Your Health. Accessed on November 30, 2021. Retrieved from https://www.cdc.gov/alcohol/fact-sheets/alcohol-use.htm
134 National Eating Disorders Association. (2021). Warning signs and symptoms. Accessed on November 22, 2021. Retrieved from https://www.nationaleatingdisorders.org/warning-signs-and-symptoms
135 Korioth, T. (2018). Guns in child’s home raise risk of suicide, unintentional death. Accessed on November 29, 2021. Retrieved from https://publications.aap.org/aapnews/news/10383
136 Swanson, S. A., Eyllon, M., Sheu, Y. H., & Miller, M. (2020). Firearm access and adolescent suicide risk: toward a clearer understanding of effect size. Injury prevention: Journal of the International Society for Child and Adolescent Injury Prevention, 27(3), 264–270. Advance online publication. 10.1136/injuryprev-2019-043605
137 Conner, A., Azrael, D., & Miller, M. (2019). Suicide Case-Fatality Rates in the United States, 2007 to 2014: A Nationwide Population-Based Study. Annals of internal medicine, 171(12), 885–895. 10.7326/M19-1324 31791066
138 Rideout, V., Fox, S., Peebles, A., & Robb, M. B. (2021). Coping with COVID-19: How young people use digital media to manage their mental health. San Francisco, CA: Common Sense and Hopelab. Retrieved from: https://www.commonsensemedia.org/sites/default/files/uploads/research/2021-coping-with-covid19-full-report.pdf
139 Coyne, S. M., Radesky, J., Collier, K. M., Gentile, D. A., Linder, J. R., Nathanson, A. I., Rasmussen, E. E., Reich, S. M., & Rogers, J. (2017). Parenting and Digital Media. Pediatrics, 140(Suppl 2), S112–S116. 10.1542/peds.2016-1758N 29093044
140 Morgan Stanley Alliance for Children’s Mental Health. (2021 August). Tips for Supporting Students’ Mental Health This Fall. Accessed on November 12, 2021. Retrieved from: https://www.morganstanley.com/assets/pdfs/reemergence-program-educator-tips-english.pdf
141 Centers for Disease Control and Prevention. (2018 August 7). School Connectedness. Accessed on November 12, 2021. Retrieved from https://www.cdc.gov/healthyyouth/protective/school_connectedness.htm
142 Adolescent Sleep Working Group, Committee on Adolescence, & Council on School Health (2014). School start times for adolescents. Pediatrics, 134(3), 642–649. 10.1542/peds.2014-1697 25156998
143 Centers for Disease Control and Prevention. (2020 May 29). Sleep and Sleep Disorders. Accessed on November 22, 2021. Retrieved from https://www.cdc.gov/sleep/features/schools-start-too-early.html
144 Stone, D.M., Holland, K.M., Bartholow, B., Crosby, A.E., Davis, S., and Wilkins, N. (2017). Preventing Suicide: A Technical Package of Policies, Programs, and Practices. Atlanta, GA: National Center for Injury Prevention and Control, Centers for Disease Control and Prevention. Retrieved from: https://www.cdc.gov/violenceprevention/pdf/suicideTechnicalPackage.pdf
145 National Health Promotion Associates. Botvin Life Skills Training. Accessed on November 12, 2021. Retrieved from https://www.lifeskillstraining.com/
146 PATHS Program Holding, LLC. PATHS Program. Accessed on November 12, 2021. Retrieved from https://pathsprogram.com/
147 PBIS Rewards. (nd). Check-In/Check-Out Behavior Intervention & PBIS. Accessed on November 18, 2021. Retrieved from https://www.pbisrewards.com/blog/check-in-check-out-behavior-intervention/
148 Substance Abuse and Mental Health Services Administration. (2021 November 5). Recognizing and Treating Child Traumatic Stress. Accessed on November 12, 2021. Retrieved from https://www.samhsa.gov/child-trauma/recognizing-and-treating-child-traumatic-stress
149 U.S. Department of Health & Human Services (MentalHealth.gov). (2019 March 22). For Educators. Accessed on November 12, 2021. Retrieved from https://www.mentalhealth.gov/talk/educators
150 National Association of School Psychologists. (2020). Providing effective social–emotional and behavioral supports after COVID-19 closures: Universal screening and Tier 1 interventions. Retrieved from https://www.nasponline.org/resources-and-publications/resources-and-podcasts/covid-19-resource-center/crisis-and-mental-health-resources/providing-effective-social%E2%80%93emotional-and-behavioral-supports-after-covid-19-closures-universal-screening-and-tier-1-interventions
151 U.S. Department of Health and Human Services. (2021 August 27). SAMHSA Awards $74.2M in Grants to Strengthen Youth Mental Health. Press Release. Retrieved from https://www.hhs.gov/about/news/2021/08/27/samhsa-awards-74-2m-in-grants-to-strengthen-youth-mental-health.html
152 National Academies of Sciences, Engineering, and Medicine. (2021). School-Based Strategies for Addressing the Mental Health and Well-Being of Youth in the Wake of COVID-19. Washington, DC: The National Academies Press. 10.17226/26262
153 American School Counselor Association. (2021). School Counselor Roles & Ratios. Accessed on November 23, 2021. Retrieved from https://www.schoolcounselor.org/About-School-Counseling/School-Counselor-Roles-Ratios
154 Department of Education, Office of Elementary & Secondary Education. (2021 March 17). American Rescue Plan Elementary and Secondary School Emergency Relief. Retrieved from https://oese.ed.gov/offices/american-rescue-plan/american-rescue-plan-elementary-and-secondary-school-emergency-relief/
155 U.S. Department of Education, Office of Special Education and Rehabilitative Services. (2021). Supporting Child and Student Social, Emotional, Behavioral, and Mental Health Needs. Washington, DC. Retrieved from https://www2.ed.gov/documents/students/supporting-child-student-social-emotional-behavioral-mental-health.pdf
156 Lever, N., Mathis, E., & Mayworm, A. (2017). School Mental Health Is Not Just for Students: Why Teacher and School Staff Wellness Matters. Report on emotional & behavioral disorders in youth, 17(1), 6–12.30705611
157 Schubel, J. (2017 April 18). Medicaid Helps Schools Help Children. Center on Budget and Policy Priorities. Accessed on November 12, 2021. Retrieved from https://www.cbpp.org/research/health/medicaid-helps-schools-help-children
158 U.S. Department of Education. (2020 June 25). Disability Discrimination. Accessed on November 12, 2021. Retrieved from https://www2.ed.gov/policy/rights/guid/ocr/disability.html
159 Watson P. (2019). How to screen for ACEs in an efficient, sensitive, and effective manner. Paediatrics & Child Health, 24(1), 37–38. 10.1093/pch/pxy146 30792599
160 American Academy of Pediatrics. (2021 July 28). Interim Guidance on Supporting the Emotional and Behavioral Health Needs of Children, Adolescents, and Families During the COVID-19 Pandemic. Retrieved from https://www.aap.org/en/pages/2019-novel-coronavirus-covid-19-infections/clinical-guidance/interim-guidance-on-supporting-the-emotional-and-behavioral-health-needs-of-children-adolescents-and-families-during-the-covid-19-pandemic/
161 Juillard, C., Cooperman, L., Allen, I., Pirracchio, R., Henderson, T., Marquez, R., Orellana, J., Texada, M., & Dicker, R. A. (2016). A decade of hospital-based violence intervention: Benefits and shortcomings. The journal of trauma and acute care surgery, 81(6), 1156–1161. 10.1097/TA.0000000000001261 27653168
162 Bell, T. M., Gilyan, D., Moore, B. A., Martin, J., Ogbemudia, B., McLaughlin, B. E., Moore, R., Simons, C. J., & Zarzaur, B. L. (2018). Long-term evaluation of a hospital-based violence intervention program using a regional health information exchange. The journal of trauma and acute care surgery, 84(1), 175–182. 10.1097/TA.0000000000001671 28787376
163 The White House Briefing Room. (2021 April 7). FACT SHEET: More Details on the Biden-Harris Administration’s Investments in Community Violence Interventions. Accessed on November 12, 2021. Retrieved from https://www.whitehouse.gov/briefing-room/statements-releases/2021/04/07/fact-sheet-more-details-on-the-biden-harris-administrations-investments-in-community-violence-interventions/
164 U.S. Department of Justice, Office for Victims of Crime. (2021 May 19). OVC FY 2021 VOCA Victim Assistance Formula Grant. Accessed on November 12, 2021. Retrieved from https://ovc.ojp.gov/funding/opportunities/o-ovc-2021-19002
165 NPR. (2021 June 11). How A Hospital And A School District Teamed Up To Help Kids In Emotional Crisis. Accessed on November 12, 2021. Retrieved from https://www.npr.org/sections/health-shots/2021/05/26/1000400903/n-y-hospital-schools-aim-to-improve-kids-access-to-mental-health-provider
166 Centers for Medicare & Medicaid Services. (2021 May 04). Integrated Care for Kids (InCK) Model. Accessed on November 12, 2021. Retrieved from https://innovation.cms.gov/innovation-models/integrated-care-for-kids-model
167 Walking The Talk. (nd). A toolkit for engaging youth in mental health: Create Youth-friendly spaces. Accessed on November 12, 2021. Retrieved from: http://www.yetoolkit.ca/content/create-youth-friendly-spaces
168 Impact of media use on children and youth. (2003). Paediatrics & child health, 8(5), 301–317. 10.1093/pch/8.5.301 20020034
169 McGinty, E. E., Webster, D. W., & Barry, C. L. (2013). Effects of news media messages about mass shootings on attitudes toward persons with serious mental illness and public support for gun control policies. The American journal of psychiatry, 170(5), 494–501. 10.1176/appi.ajp.2013.13010014 23511486
170 Klin, A., & Lemish, D. (2008). Mental disorders stigma in the media: review of studies on production, content, and influences. Journal of health communication, 13(5), 434–449. 10.1080/10810730802198813 18661386
171 Pfefferbaum, B., Nixon, S. J., Tucker, P. M., Tivis, R. D., Moore, V. L., Gurwitch, R. H., Pynoos, R. S., & Geis, H. K. (1999). Posttraumatic stress responses in bereaved children after the Oklahoma City bombing. Journal of the American Academy of Child and Adolescent Psychiatry, 38(11), 1372–1379. 10.1097/00004583-199911000-00011 10560223
172 Holman, E. A., Garfin, D. R., & Silver, R. C. (2014). Media’s role in broadcasting acute stress following the Boston Marathon bombings. Proceedings of the National Academy of Sciences of the United States of America, 111(1), 93–98. 10.1073/pnas.1316265110 24324161
173 Johnston, W. M., & Davey, G. C. (1997). The psychological impact of negative TV news bulletins: the catastrophizing of personal worries. British journal of psychology (London, England : 1953), 88 (Pt 1), 85–91. 10.1111/j.2044-8295.1997.tb02622.x
174 Thompson, R. R., Jones, N. M., Holman, E. A., & Silver, R. C. (2019). Media exposure to mass violence events can fuel a cycle of distress. Science advances, 5(4), eaav3502. 10.1126/sciadv.aav3502 31001584
175 Stainback, K., Hearne, B.N., & Trieu, M.M. (2020). COVID-19 and the 24/7 News Cycle: Does COVID-19 News Exposure Affect Mental Health? Socius: Sociological Research for a Dynamic World; (6). 10.1177/2378023120969339
176 Su, Z., McDonnell, D., Wen, J., Kozak, M., Abbas, J., Šegalo, S., Li, X., Ahmad, J., Cheshmehzangi, A., Cai, Y., Yang, L., & Xiang, Y. T. (2021). Mental health consequences of COVID-19 media coverage: the need for effective crisis communication practices. Globalization and health, 17(1), 4. 10.1186/s12992-020-00654-4 33402169
177 Mental Health Media Guide. (nd). Step 5: Support Your Audience Before, During, and After Viewing. Accessed on November 12, 2021. Retrieved from https://mentalhealthmediaguide.com/guide-front-page/tips-by-step/support-your-audience-before-during-after-viewing/
178 Stanford University, Department of Psychiatry and Behavioral Sciences. (nd). Media & Mental Health Initiative (MMHI). Accessed on November 12, 2021. Retrieved from https://med.stanford.edu/psychiatry/special-initiatives/mediamh.html
179 Choe, J. Y., Teplin, L. A., & Abram, K. M. (2008). Perpetration of violence, violent victimization, and severe mental illness: balancing public health concerns. Psychiatric services (Washington, D.C.), 59(2), 153–164. 10.1176/ps.2008.59.2.153
180 Crocker, A. F., & Smith, S. N. (2019). Person-first language: are we practicing what we preach?. Journal of multidisciplinary healthcare, 12, 125–129. 10.2147/JMDH.S140067 30799931
181 Metzl, J. M., & MacLeish, K. T. (2015). Mental illness, mass shootings, and the politics of American firearms. American journal of public health, 105(2), 240–249. 10.2105/AJPH.2014.302242 25496006
182 National Action Alliance for Suicide Prevention. (2019). National Recommendations for Depicting Suicide. Accessed on November 12, 2021. Retrieved from https://theactionalliance.org/resource/national-recommendations-depicting-suicide
183 Nagata, J. M., Cortez, C. A., Cattle, C. J., Ganson, K. T., Iyer, P., Bibbins-Domingo, K., & Baker, F. C. (2021). Screen Time Use Among US Adolescents During the COVID-19 Pandemic: Findings From the Adolescent Brain Cognitive Development (ABCD) Study. JAMA pediatrics, 10.1001/jamapediatrics.2021.4334. Advance online publication. 10.1001/jamapediatrics.2021.4334
184 New Public. (2021 January 11). Building better digital public spaces, “Civic Signals: The qualities of flourishing digital spaces,” Research Overview. Accessed on November 12, 2021. Retrieved from https://newpublic.org/signals and https://docs.google.com/presentation/d/1lO4skPVekwciJGFYxxJBIBitFzzDSC0zL1-AvhgfeNs/
185 5Rights Foundation. (2021). Pathways: How digital design puts children at risk. Accessed on November 12, 2021. Retrieved from https://5rightsfoundation.com/uploads/Pathways-how-digital-design-puts-children-at-risk.pdf
186 Council on Communications and Media. (2016). Media and Young Minds. Pediatrics, 138(5), e20162591. 10.1542/peds.2016-2591 27940793
187 Hill D. L. (2020). Social Media: Anticipatory Guidance. Pediatrics in review, 41(3), 112–119. 10.1542/pir.2018-0236 32123022
188 Haidt, J., & Twenge, J. (2021). Social media use and mental health: A review. Unpublished manuscript, New York University. https://docs.google.com/document/d/1w-HOfseF2wF9YIpXwUUtP65-olnkPyWcgF5BiAtBEy0/edit
189 Hagan, J. F., Shaw, J. S., & Duncan, M. P. (2017). Bright Futures: Guidelines for Health Supervision of Infants, Children, and Adolescents. 4th ed. Elk Grove Village, IL: American Academy of Pediatrics. https://brightfutures.aap.org/Bright%20Futures%20Documents/BF4_HealthySocialMedia.pdf
190 Chang, A. M., Aeschbach, D., Duffy, J. F., & Czeisler, C. A. (2015). Evening use of light-emitting eReaders negatively affects sleep, circadian timing, and next-morning alertness. Proceedings of the National Academy of Sciences of the United States of America, 112(4), 1232–1237. 10.1073/pnas.1418490112 25535358
191 Sumner, S. A., Ferguson, B., Bason, B., Dink, J., Yard, E., Hertz, M., Hilkert, B., Holland, K., Mercado-Crespo, M., Tang, S., & Jones, C. M. (2021). Association of Online Risk Factors With Subsequent Youth Suicide-Related Behaviors in the US. JAMA network open, 4(9), e2125860. 10.1001/jamanetworkopen.2021.25860 34542614
192 Swedo, E. A., Beauregard, J. L., de Fijter, S., Werhan, L., Norris, K., Montgomery, M. P., Rose, E. B., David-Ferdon, C., Massetti, G. M., Hillis, S. D., & Sumner, S. A. (2021). Associations Between Social Media and Suicidal Behaviors During a Youth Suicide Cluster in Ohio. The Journal of adolescent health, 68(2), 308–316. 10.1016/j.jadohealth.2020.05.049 32646827
193 McCrae, N., Gettings, S. & Purssell, E. (2017). Social Media and Depressive Symptoms in Childhood and Adolescence: A Systematic Review. Adolescent Res Rev, 2: 315–330. 10.1007/s40894-017-0053-4
194 Allcott, H., Braghieri, L., Eichmeyer, S., & Gentzkow, M. (2020). “The Welfare Effects of Social Media.” American Economic Review, 110 (3): 629–76. https://www.aeaweb.org/articles?id=10.1257/aer.20190658
195 Ra, C. K., Cho, J., Stone, M. D., De La Cerda, J., Goldenson, N. I., Moroney, E., Tung, I., Lee, S. S., & Leventhal, A. M. (2018). Association of Digital Media Use With Subsequent Symptoms of Attention-Deficit/Hyperactivity Disorder Among Adolescents. JAMA, 320(3), 255–263. 10.1001/jama.2018.8931 30027248
196 American Psychiatric Association. (2018 June). Internet Gaming. Accessed on November 12, 2021. Retrieved from https://www.psychiatry.org/patients-families/internet-gaming
197 Przybylski, A. K., Weinstein, N., & Murayama, K. (2017). Internet Gaming Disorder: Investigating the Clinical Relevance of a New Phenomenon. The American journal of psychiatry, 174(3), 230–236. 10.1176/appi.ajp.2016.16020224 27809571
198 Orben, A., & Przybylski, A. K. (2019). The association between adolescent well-being and digital technology use. Nature human behaviour, 3(2), 173–182. 10.1038/s41562-018-0506-1
199 Coyne, S. M., Rogers, A. A., Zurcher, J. D., Stockdale, L., & Booth M. (2020). Does time spent using social media impact mental health?: An eight year longitudinal study. Computers in Human Behavior, 104. 10.1016/j.chb.2019.106160
200 Orben, A., Dienlin, T., & Przybylski, A. K. (2019). Social media’s enduring effect on adolescent life satisfaction. Proceedings of the National Academy of Sciences of the United States of America, 116(21), 10226–10228. 10.1073/pnas.1902058116 31061122
201 George, M. J., Jensen, M. R., Russell, M. A., Gassman-Pines, A., Copeland, W. E., Hoyle, R. H., & Odgers, C. L. (2020). Young Adolescents’ Digital Technology Use, Perceived Impairments, and Well-Being in a Representative Sample. The Journal of pediatrics, 219, 180–187. 10.1016/j.jpeds.2019.12.002 32057438
202 Odgers, C. L., & Jensen, M. R. (2020). Annual Research Review: Adolescent mental health in the digital age: facts, fears, and future directions. Journal of child psychology and psychiatry, and allied disciplines, 61(3), 336–348. 10.1111/jcpp.13190
203 Valkenburg, P. M., Meier, A., & Beyens, I. (2021). Social media use and its impact on adolescent mental health: An umbrella review of the evidence. Current opinion in psychology, 44, 58–68. Advance online publication. 10.1016/j.copsyc.2021.08.017 34563980
204 Beyens, I., Pouwels, J. L., van Driel, I. I., Keijsers, L., & Valkenburg, P. M. (2020). The effect of social media on well-being differs from adolescent to adolescent. Scientific reports, 10(1), 10763. 10.1038/s41598-020-67727-7 32612108
205 Verduyn, P., Lee, D. S., Park, J., Shablack, H., Orvell, A., Bayer, J., … Kross, E. (2015). Passive Facebook usage undermines affective well-being: Experimental and longitudinal evidence. Journal of Experimental Psychology: General, 144(2), 480–488. 10.1037/xge0000057 25706656
206 Przybylski, A. K., & Weinstein, N. (2017). A large-scale test of the Goldilocks hypothesis: Quantifying the relations between digital-screen use and the mental well-being of adolescents. Psychological Science, 28(2), 204–215. 10.1177/0956797616678438 28085574
207 Hinduja, S. & Patchin, J. W. (2020). Bullying, Cyberbullying, and LGBTQ Students. Cyberbullying Research Center. Retrieved from https://cyberbullying.org/bullying-cyberbullying-sexual-orientation-lgbtq.pdf
208 Dickson, K., Richardson, M., Kwan, I., MacDowall, W., Burchett, H., Stansfield, C., Brunton, G., Sutcliffe, K., & Thomas, J. (2018). Screen-based activities and children and young people’s mental health: A Systematic Map of Reviews, London: EPPI-Centre, Social Science Research Unit, UCL Institute of Education, University College London.
209 Parry, D. A., Fisher, J. T., Mieczkowski, H., Sewall, C. J. R., & Davidson, B. I. (2021). Social Media and Well-being: A Methodological Perspective. PsyArXiv Preprints. 10.31234/osf.io/exhru
210 Lenhart, A., & Owens, K. (2021). The Unseen Teen: The Challenges of Building Healthy Tech for Young People. Data & Society. Retrieved from: https://datasociety.net/wp-content/uploads/2021/05/The-Unseen-Teen-.pdf
211 Austrialian Government, eSafety Commissioner. (nd). Safety by Design. Accessed on November 12, 2021. Retrieved from https://www.esafety.gov.au/about-us/safety-by-design/principles-and-background
212 Meyer, M., Adkins, V., Yuan, N., Weeks, H. M., Chang, Y. J., & Radesky, J. (2019). Advertising in Young Children’s Apps: A Content Analysis. Journal of developmental and behavioral pediatrics: JDBP, 40(1), 32–39. 10.1097/DBP.0000000000000622 30371646
213 Fair Play Alliance. (nd). Fair Play Alliance. Accessed on November 12, 2021. Retrieved from https://fairplayalliance.org/
214 Chen, C. A. (2021 September 21). Introducing Age Verification. Roblox. Accessed on November 12, 2021. Retrieved from https://blog.roblox.com/2021/09/introducing-age-verification/
215 Elgersma, C. (2019 September 23). How to Use Apple’s Screen Time Feature. Common Sense Media. Accessed on November 12, 2021. Retrieved from https://www.commonsensemedia.org/blog/how-to-use-apples-screen-time-feature
216 Davies, R. (2020 December 10). Google to let YouTube users opt out of gambling and alcohol ads. The Guardian. Accessed on November 12, 2021. Retrieved from https://www.theguardian.com/technology/2020/dec/10/google-to-allow-youtube-users-in-uk-to-opt-out-of-gambling-and-alcohol-ads
217 World Health Organization. (2021 October 4). WHO brings vital mental health messages to gamers via digital channels. Accessed on November 12, 2021. Retrieved from https://www.who.int/news/item/04-10-2021-the-who-and-angry-birds-friends-team-up-for-world-mental-health-day
218 Makin S. (2019). The emerging world of digital therapeutics. Nature, 573(7775), S106–S109. 10.1038/d41586-019-02873-1 31554990
219 Hackett, A., Hung, A., Leclerc, O., & Velamoor, S. (2020 March 31). The promise of digital therapeutics. McKinsey & Company. Accessed on November 23, 2021. Retrieved from https://www.mckinsey.com/industries/life-sciences/our-insights/the-promise-of-digital-therapeutics
220 Centers for Disease Control and Prevention. (2019). Preventing Adverse Childhood Experiences: Leveraging the Best Available Evidence. Atlanta, GA: National Center for Injury Prevention and Control, Centers for Disease Control and Prevention. Retrieved from: https://www.cdc.gov/violenceprevention/pdf/preventingACES.pdf
221 The Martinsburg Initiative. (2020). The Martinsburg Initiative: A Model Solution To A National Problem. Retrieved from: https://themartinsburginitiative.com/
222 Centers for Disease Control and Prevention (2021). Drug-Free Communities Support Program. Accessed on October 7, 2021. Retrieved from: https://www.cdc.gov/drugoverdose/drug-free-communities/about.html
223 U.S. Department of Health and Human Services (HHS) Office of the Surgeon General, & National Action Alliance for Suicide Prevention. (2021). The Surgeon General’s Call to Action to Implement The National Strategy for Suicide Prevention. HHS. https://www.hhs.gov/sites/default/files/sprc-call-to-action.pdf
224 Dopp, A. R., & Lantz, P. M. (2020). Moving Upstream to Improve Children’s Mental Health Through Community and Policy Change. Administration and policy in mental health, 47(5), 779–787. 10.1007/s10488-019-01001-5 31828555
225 Needels, K., Richman, S., Maxwell, N., & Anderson M.A. (2020). Scaling an Intervention: Recommendations and Resources, A Guide for Funders and Grantmakers. AmeriCorps and Mathematica. Retrieved from: https://americorps.gov/sites/default/files/document/AmeriCorps_ScalingRecsAndResources_ORE_9Apr2021.pdf
226 Headstream. (nd). Building wellness through inclusive digital experiences. Accessed on November 12, 2021. Retrieved from https://www.headstreaminnovation.com/
227 University of California Berkeley. (nd). The Fung Fellowship. Accessed on November 12, 2021. Retrieved from https://fungfellows.berkeley.edu/about/our-story/
228 Goetzel, R. Z., Roemer, E. C., Holingue, C., Fallin, M. D., McCleary, K., Eaton, W., Agnew, J., Azocar, F., Ballard, D., Bartlett, J., Braga, M., Conway, H., Crighton, K. A., Frank, R., Jinnett, K., Keller-Greene, D., Rauch, S. M., Safeer, R., Saporito, D., Schill, A., … Mattingly, C. R. (2018). Mental Health in the Workplace: A Call to Action Proceedings From the Mental Health in the Workplace-Public Health Summit. Journal of occupational and environmental medicine, 60(4), 322–330. 10.1097/JOM.0000000000001271 29280775
229 Weissman, M. M., Wickramaratne, P., Nomura, Y., Warner, V., Pilowsky, D., & Verdeli, H. (2006). Offspring of depressed parents: 20 years later. The American journal of psychiatry, 163(6), 1001–1008. 10.1176/ajp.2006.163.6.1001 16741200
230 Forry, N. D., & Hofferth, S. L. (2011). Maintaining Work: The Influence of Child Care Subsidies on Child Care-Related Work Disruptions. Journal of family issues, 32(3), 346–368. 10.1177/0192513X10384467 22194641
231 Ray, T. K., & Pana-Cryan, R. (2021). Work Flexibility and Work-Related Well-Being. International journal of environmental research and public health, 18(6), 3254. 10.3390/ijerph18063254 33801122
232 Centers for Disease Control and Prevention. (2021). Mental Health in the Workplace. Accessed on November 12, 2021. Retrieved from: https://www.cdc.gov/workplacehealthpromotion/tools-resources/workplace-health/mental-health/index.html
233 The White House. (2021 June 11). FACT SHEET. Biden-Harris Administration Announces Child Tax Credit Awareness Day and Releases Guidance for Unprecedented American Resue Plan Investments to Support Parents and Healthy Child Development. Accessed on November 12, 2021. Retrieved from https://www.whitehouse.gov/briefing-room/statements-releases/2021/06/11/fact-sheet-biden-harrisadministration-announces-child-tax-credit-awareness-day-and-releases-guidance-for-unprecedented-american-rescue-plan-investments-to-support-parents-and-healthy-child-dev/
234 Information Commissioner’s Office. (nd). Introduction to the Age appropriate design code. Accessed on November 12, 2021. Retrieved from https://ico.org.uk/for-organisations/guide-to-data-protection/ico-codes-of-practice/age-appropriate-design-code/
235 Lomas, N. (2021 September 1). UK now expects compliance with children’s privacy design code. Tech Crunch. Accessed on November 12, 2021. Retrieved from https://techcrunch.com/2021/09/01/uk-now-expects-compliance-with-its-child-privacy-design-code/
236 Australian Government, eSafety Commissioner. (nd). Safety by Design. Accessed on November 29, 2021. Retrieved from https://www.esafety.gov.au/industry/safety-by-design
237 The White House. (2021 October 19). FACT SHEET: Improving Access and Care for Youth Mental Health and Substance Use Conditions. Retrieved from https://www.whitehouse.gov/briefing-room/statements-releases/2021/10/19/fact-sheet-improving-access-and-care-for-youth-mental-health-and-substance-use-conditions/
238 U.S. Department of Health & Human Services. (2021 August 27). Biden-Harris Administration Invests $10.7 Million in American Rescue Plan Funds to Expand Pediatric Mental Health Care Access. Press Release. Retrieved from https://www.hhs.gov/about/news/2021/08/27/biden-harris-admin-invests-nearly-11-million-for-pediatric-mental-health-access.html
239 Massachusetts Child Psychiatry Access Program. Connecting Primary Care with Child Psychiatry. Accessed on November 12, 2021. Retrieved from https://www.mcpap.com/
240 The White House. (2021 May 20). PRESS RELEASE. HHS Announces $14.2 Million from American Rescue Plan to Expand Pediatric Mental Health Care Access. Accessed on November 29, 2021. Retrieved from https://www.hhs.gov/about/news/2021/05/20/hhs-announces-142-million-american-rescue-plan-expand-pediatric-mental-health-care-access.html
241 Office of the California Surgeon General. (2021 October 8). PRESS RELEASE. New ACEs Equity Act Significantly Expands ACE Screening in California. Retrieved from https://osg.ca.gov/wp-content/uploads/sites/266/2021/10/CA-OSG-News-Release-ACEs-Equity-Act.pdf
242 U.S. Department of Health and Human Services. (2021 August 27). SAMHSA Awards $74.2M in Grants to Strengthen Youth Mental Health. Press Release. Retrieved from https://www.hhs.gov/about/news/2021/08/27/samhsa-awards-74-2m-in-grants-to-strengthen-youth-mental-health.html
243 California Legislation Information. (2021). SB-224 Pupil instruction: mental health education (2021-2022). Retrieved from https://leginfo.legislature.ca.gov/faces/billNavClient.xhtml?bill_id=202120220SB224
244 Tap Into Bordentown. (2021 October 2). New Law Creates Grant Program for Depression Screening in Schools. Accessed on November 23, 2021. Retrieved from https://www.tapinto.net/towns/bordentown/sections/education/articles/new-law-creates-grant-program-for-depression-screening-in-schools
245 Centers for Disease Control and Prevention. (2021 February 22). Behavioral and Socioemotional Outcomes Through Age 5 of the Legacy for Children™ Public Health Approach to Improving Developmental Outcomes among Children Born into Poverty. Accessed on November 22, 2021. Retrieved from https://www.cdc.gov/ncbddd/childdevelopment/features/legacy-for-children-keyfindings.html
246 Colorado Department of Human Services. (2021). I Matter - Providing Free Mental Health Support for Colorado Youth. Accessed on November 23, 2021. Retrieved from https://cdhs.colorado.gov/i-matter-program
247 Brooks, T., Roygardner, L., Artiga, S., Pham, O, & Dolan, R. (2020 March 26). Medicaid and CHIP Eligibility, Enrollment, and Cost Sharing Policies as of January 2020: Findings from a 50-State Survey. Kaiser Family Foundation. Retrieved from https://www.kff.org/report-section/medicaid-and-chip-eligibility-enrollment-and-cost-sharing-policies-as-of-january-2020-findings-from-a-50-state-survey-enrollment-and-renewal-processes/
248 Mental Health and Juvenile Justice Collaborative for Change: A Training, Technical Assistance and Education Center and a member of the Models for Change Resource Center Partnership. (nd). Better Solutions for Youth with Mental Health Needs in the Juvenile Justice System. Retrieved from https://ncyoj.policyresearchinc.org/img/resources/Better_Solutions_for_Youth_with_Mental_Health_Needs_in_the_Juvenile_Justice_System-501172.pdf
249 Shufelt, J. L., Cocozza, J. J., & Skowyra, K. R. (2010). Successfully Collaborating With the Juvenile Justice System: Benefits, Challenges, and Key Strategies. Washington, DC: Technical Assistance Partnership for Child and Family Mental Health. https://www.air.org/sites/default/files/downloads/report/jjresource_collaboration.pdf
250 Berger, L. M., & Font, S. A. (2015). The Role of the Family and Family-Centered Programs and Policies. The Future of children, 25(1), 155–176.30679897
251 Villagrana, M. (2021). Foster Care Alumni’s Perceptions of Mental Health Services Received While in Foster Care. Child Adolesc Soc Work J. 10.1007/s10560-021-00803-7
252 The White House. (2021 January 20). Executive Order On Advancing Racial Equity and Support for Underserved Communities Through the Federal Government. Retrieved from https://www.whitehouse.gov/briefing-room/presidential-actions/2021/01/20/executive-order-advancing-racial-equity-and-support-for-underserved-communities-through-the-federal-government/
253 Williams, C., & Martinez, R. (2008). Increasing Access to CBT: Stepped Care and CBT Self-Help Models in Practice. Behavioural and Cognitive Psychotherapy, 36(6), 675–683. doi:10.1017/S1352465808004864
254 Teplin, L. A., Abram, K. M., Washburn, J. J., Welty, L. J., Hershfield, J. A., & Dulcan, M. K. (2013 February). The Northwestern Juvenile Project: Overview. U.S. Department of Justice, Office of Justice Programs, Office of Juvenile Justice and Delinquency Prevention. Retrieved from https://ojjdp.ojp.gov/sites/g/files/xyckuh176/files/pubs/234522.pdf

### Figure 1 Sources

World Health Organization. (2014). Health for the World’s Adolescents: A second chance in the second decade. WHO Press, World Health Organization. https://apps.who.int/adolescent/second-decade/files/1612_MNCAH_HWA_Executive_Summary.pdf
Bronfenbrenner, U., & Ceci, S. J. (1994). Nature-nurture reconceptualized in developmental perspective: A bioecological model. Psychological Review, 101(4), 568–586. doi:10.1037/0033-295X.101.4.568 7984707