# ACKNOWLEDGMENTS

This Advisory was prepared by the Office of the Surgeon General (OSG) with contributions from the following interagency partners:

## Department of Health and Human Services

- Administration for Children and Families (ACF)
- Administration for Community Living (ACL)
- Behavioral Health Coordinating Council Subcommittee on Children and Youth
- Centers for Disease Control and Prevention (CDC)
  - National Center for Injury Prevention and Control (NCIPC)
  - National Center for HIV, Viral Hepatitis, STD, and TB Prevention (NCHHSTP)
    - Division of Adolescent and School Health (DASH)
- Centers for Medicare and Medicaid Services
  - Center for Medicaid and CHIP Services
- Food and Drug Administration (FDA)
  - Office of Pediatric Therapeutics
- Health Resources and Services Administration (HRSA)
- Maternal and Child Health Bureau (MCHB)
- Indian Health Service (IHS)
- National Institutes of Health (NIH)
  - National Institute of Mental Health (NIMH)
  - National Institute on Drug Abuse (NIDA)
  - Eunice Kennedy Shriver National Institute of Child Health and Human Development (NICHD)
- Office of the Assistant Secretary for Health (OASH)
  - Office of Minority Health (OMH)
- Office of the Assistant Secretary for Planning and Evaluation (ASPE)
  - Office of Human Services Policy (HSP)
  - Office of Behavioral Health, Disability, and Aging Policy (BHDAP)
- Substance Abuse and Mental Health Services Administration (SAMHSA)

## Additional Partners

- Department of Education
  - Office of Special Education and Rehabilitative Services (OSERS)
- Department of Justice (DOJ)
  - Office of Justice Programs (OJP)
- White House Domestic Policy Council (DPC)
- White House Office of Science and Technology Policy (OSTP)

Note: Examples and external resources in this advisory are provided for informational purposes only, and their inclusion does not constitute an endorsement by any government office or agency.