# Preface, from the Surgeon General

One of the most significant public health successes in modern U.S. history has been the reduction in smoking that has occurred during the past half century. Today, the prevalence of cigarette smoking among American adults is at an all-time low, 14%. Although this overall achievement is a source of pride, there is still more work to be done. Today, 16 million Americans are living with a smoking-related disease. In addition to the human costs, smoking places a significant financial burden on Americans, as smoking-attributable healthcare spending exceeds $170 billion per year.

Research, medical advances, and years of documented experience have given us many tools to tackle the tobacco use epidemic in this country. Although quitting smoking can be a difficult process for many smokers, most say they want to quit, and every year more than half make a serious quit attempt. But only a small portion of smokers who try to quit succeed, and only a small portion use any of the tested and proven aids that will significantly increase their chances of success. This Surgeon General’s report on smoking cessation, the 34th report on smoking and health since 1964, examines the most current research on this important issue, identifies barriers to continued success in reducing the prevalence of smoking across all populations, and summarizes evidence-based solutions that can help to eliminate those barriers.

Clinical interventions for smoking cessation are critical if we are to achieve our goal of eliminating the devastating effects of smoking on public health. Primary care physicians, nurses, pharmacists, and other providers in all medical disciplines and in all healthcare environments should take advantage of these opportunities to inform and encourage smokers to quit. Doing so could enable half a million smokers to quit each year.

As a physician, I am acutely aware of the many pressing demands that healthcare providers must address to deliver the highest quality care possible to their patients. At the same time, the evidence in this report clearly points to the tremendous positive impact that healthcare professionals can have on the health and quality of life of their patients and on the public health of our nation—just by helping smokers to quit.

But healthcare professionals alone cannot solve this public health challenge. Everyone has a role in helping to continue to reduce the burden of tobacco use on our society. It is critical that clinical interventions be adopted alongside broader efforts at the health system and population levels to promote and cultivate successful cessation and tobacco-free norms. Even today, with all the gains that have been made over the past few decades, smoking remains the single largest cause of preventable disease and death in the United States. As a nation, we can and must spare no effort to reduce the completely preventable health and financial costs that tobacco smoking has on society.

Jerome M. Adams, M.D., M.P.H. Vice Admiral, U.S. Public Health Service Surgeon General of the United States