# List of Abbreviations

α: alpha
β: beta
δ: delta
κ: kappa
μ: mu
μg/ml: microgram per milliliter
15-D: 15 dimensions [generic, self-administered measure of HRQoL]
2-SORA: selective receptor 2 antagonist
5 A’s: Ask, Advise, Assess, Assist, Arrange
AAA: abdominal aortic aneurysm
AAC: Ask, Advise, Connect
AACR: American Association for Cancer Research
AAR: Ask, Advise, Refer
AARP: American Association of Retired Persons
ABI: ankle-brachial index
ACA: Patient Protection and Affordable Care Act
ACC: anterior cingulate
ACE: angiotensin-converting enzyme
ACT: acceptance-based therapy
ADHD: attention-deficit/hyperactivity disorder
AF: atrial fibrillation
aFRs: adjusted fecundability ratios
AGS: additive genetic score
AHRR: aryl-hydrocarbon receptor repressor
AMI: acute myocardial infarction
AML: acute myeloid leukemia
AMPA: α-amino-3-hydroxy-5-methyl-4-isoxazolepropionic acid
ANOVA: analysis of variance
AoAC: aortic artery calcium
aOR: adjusted odds ratio
APO: apolipoprotein
APPROACH: Alberta Provincial Project for Outcomes Assessment in Coronary Heart Disease
aPR: adjusted prevalence ratio
AQCs: alternative quality contracts
ARIC: Atherosclerosis Risk in Communities
ARR: absolute risk reduction
ASCO: American Society of Clinical Oncology
ASSET: AngloScandinavian Study of Early Thrombolysis
BAL: bronchoalveolar lavage
BENESCO: Benefits of Smoking Cessation on Outcomes
bid: twice a day
BMI: body mass index
BRFSS: Behavioral Risk Factor Surveillance System
C3I: Cancer Center Cessation Initiative
CABG: coronary artery bypass grafting
CAC: coronary artery calcification
CAD: coronary artery disease
CAGE 50: number of segments with coronary artery stenosis of greater than or equal to 50%
CALIBER: ClinicAL research using LInked Bespoke studies and Electronic health Records
CASS: Coronary Artery Surgery Study
CAST: Cardiac Arrhythmia Suppression Trial
CBT: cognitive behavioral therapy
CCA: common carotid artery
CCQ: Clinical COPD Questionnaire
CCS: Cancer Control Supplement
CDC: Centers for Disease Control and Prevention
CDER: Center for Drug Evaluation and Research
CHANCES: Consortium on Health and Ageing: Network of Cohorts in Europe and the United States
CHD: coronary heart disease
CHDA: coronary heart disease hard, definite angina, probable angina if followed by revascularization
CHDH: coronary heart disease hard [myocardial infarction, resuscitated cardiac arrest, coronary heart disease death]
CHF: congestive heart failure
CHIP: Children’s Health Insurance Program
CI: confidence interval
CIMP-high: CpG island methylator phenotype
CIN3: cervical intraepithelial cancer grade 3
CIS: carcinoma in situ
cm: centimeter
CMS: Centers for Medicare and Medicaid Services
CO: carbon monoxide
COLD: chronic obstructive lung disease
CONSTANCES: Consultants des Centres d’Examens de Santé
COPD: chronic obstructive pulmonary disease
cpd: cigarettes smoked per day
CpG: cytosine-phosphate-guanine
CPP: conditioned place preference
CPS: Cancer Prevention Study
CRF: corticotropin-releasing factor
CRP: C-reactive protein
CT: computed tomography
CTP: Center for Tobacco Products
CVA: cerebrovascular accident
CVD: cardiovascular disease
CVDA: CVDH, CHDH, atherosclerotic death, CVD death
CVDH: CHDH, stroke death, stroke
dACC: dorsal anterior cingulate cortex
DALYs: disability-adjusted life-years
DART: Diet and Reinfarction Trial
dlPFC: dorsolateral prefrontal cortex
DM: diabetes mellitus
DMN: default mode network
dmPFC: dorsomedial prefrontal cortex
DNA: deoxyribonucleic acid
DoD: U.S. Department of Defense
DORs: delta opioid receptors
DRD2: dopamine receptor D2
EAGLES: Evaluating Adverse Events in a Global Smoking Cessation Study
e-cigarettes: electronic cigarettes
ECLIPSE: Evaluation of COPD Longitudinally to Identify Predictive Surrogate Endpoints
ED: erectile dysfunction
EHRs: electronic health records
ELSA: English Longitudinal Study of Aging
ELSA-Brazil: Brazilian Longitudinal Study of Adult Health
EMS: emergency management system
ENDS: electronic nicotine delivery systems
EORTC: European Organisation for Research and Treatment of Cancer
EORTC-H&N35: European Organization for Research and Treatment of Cancer Quality of Life Questionnaire, Head and Neck Module
EORTC-LC13: European Organization for Research and Treatment of Cancer Quality of Life Questionnaire, Lung Cancer Module
EPIC: European Prospective Investigation into Cancer and Nutrition
eReferral: electronic referral
ESTHER: Epidemiological Investigations on Opportunities for Prevention, Early Detection and Optimised Treatment of Chronic Diseases in the Elderly Population
EURQoL: European quality of life
EVALI: e-cigarette- or vaping-associated lung injury
F: females
F2:Cr: F2 isoprostane:creatinine
F2RL3: factor II receptor-like 3
FCTC: Framework Convention on Tobacco Control
FDA: U.S. Food and Drug Administration
FEV_1_: forced expiratory volume at 1 second
FINRISK: Large Finnish population survey on Risk factors on chronic, noncommunicable diseases
FMD: flow-mediated dilation
fMRI: functional magnetic resonance imaging
FRENA: Factores de Riesgo y Enfermedad Arterial [Registry]
FSH: follicular-stimulating hormone
FTND: Fagerström Test for Nicotine Dependence
FVC: forced vital capacity
g: gram
GDM: gestational diabetes mellitus
GED: General Education Development
GLT: glutamate transporter
GPR15: G protein-coupled receptor 15
GPS: global positioning system
GRADE: Grading of Recommendations Assessment, Development, and Evaluation
GWAS: genomewide association study
HAPIEE: Health, Alcohol, and Psychosocial factors In Eastern Europe
HB–IPN: habenula–interpeduncular
HDL: high-density lipoprotein
HDL-C: high-density lipoprotein cholesterol
HEDIS: Healthcare Effectiveness Data and Information Set
HELLP: hemolysis, elevated liver enzymes, and low platelet count
HINTS: Health Information National Trends Survey
HIPAA: Health Insurance Portability and Accountability Act of 1996
HITECH: Health Information Technology for Economic and Clinical Health
HMO: health maintenance organization
HPV: human papillomavirus
HR: hazard ratio
HRQoL: health-related quality of life
HT: hypertension
IARC: International Agency for Research on Cancer
IASLC: International Association for the Study of Lung Cancer
ICAM-1: intercellular adhesion molecule-1
ICC: invasive cervical cancer
ICD: International Classification of Diseases
ICESCC: International Collaboration of Epidemiological Studies of Cervical Cancer
ICH: intracerebral hemorrhage
IL: interleukin
IMT: intimal-media thickness
IOM: Institute of Medicine
IPAQ: International Physical Activity Questionnaire
IPN: interpeduncular nucleus
ISFAMI: Israel Study of First Acute Myocardial Infarction
IVF: in vitro fertilization
IVR: interactive voice response
KAROLA: Langzeiterfolge der Kardiologischen Anschlussheilbehandlung [Long Term Success of Cardiologic Rehabilitation Therapy]
kg: kilogram
km: kilometer
KORA: Kooperative Gesundheitsforschung in der Region Augsburg [Cooperative Health Research in the Augsburg Region]
KORs: kappa opioid receptors
L: liter
lbs: pounds
LDCT: low-dose computed tomography
LDL: low-density lipoprotein
LDL-C: low-density lipoprotein cholesterol
LDTg: laterodorsal tegmental nucleus
LGBT: lesbian, gay, bisexual, and transgender
LVEF: left ventricular ejection fraction
M: males
MAO: monoamine oxidase
MAOI: monoamine oxidase inhibitor
MassHealth: Massachusetts Medicaid
MCS: Mental Component Summary
MEPS: Medical Expenditure Panel Survey
MESA: Multi-Ethnic Study of Atherosclerosis
MeSH: Medical Subject Headings
MF: males and females
mg: milligram
mg/dL: milligram per deciliter
mGluR: metabotropic glutamate receptor
Mh: to search Medical Subjects Headings in MEDLINE or PubMed
MHb: medial habenula
MHb-IPN: medial habenulo-interpeduncular nucleus
mHealth: mobile health
MI: myocardial infarction
MILIS: Multicenter Investigation of Limitation of Infarct Size
mL: milliliter
mm: millimeter
mmol: millimole
MORGAM: Monica Risk Genetics Archiving and Monograph
MORs: mu opioid receptors
MPEP: 2-methyl-6-(phenylethynyl) pyridine
MRFIT: Multiple Risk Factor Intervention Trial
MRI: magnetic resonance imaging
MRTP: modified risk tobacco product
MSA: Master Settlement Agreement
MSI-high: microsatellite instability
MTF: Monitoring the Future
NA: not applicable
NA: not available
NAc: nucleus accumbens
nAChR: nicotinic acetylcholine receptor
NAM: negative allosteric modulator
NAMCS: National Ambulatory Medical Care Survey
NATS: National Adult Tobacco Survey
NCCN: National Comprehensive Cancer Network
NCHS: National Center for Health Statistics
NCI: National Cancer Institute
NCQA: National Committee for Quality Assurance
ng/mL: nanogram per milliliter
NHANES: National Health and Nutrition Examination Survey
NHIS: National Health Interview Survey
NIBS: noninvasive brain stimulation
NICU: neonatal intensive care unit
NIH: National Institutes of Health
NIH-AARP: National Institutes of Health-American Association of Retired Persons
NMDA: N-methyl-D-aspartate
NMR: nicotine metabolite ratio
NQF: National Quality Forum
NRT: nicotine replacement therapy
NSDUH: National Survey on Drug Use and Health
NTCP: National Tobacco Control Program
NYTS: National Youth Tobacco Survey
OACISy: Osaka Acute Coronary Insufficiency Study
OASIS: Organization to Assess Strategies in Ischemic Syndromes
OFC: orbitofrontal cortex
OR: odds ratio
OTC: over the counter
PAD: peripheral artery disease
PAM: positive allosteric modulator
PAS: pharmacists action on smoking
PATH: Population Assessment of Tobacco and Health
PCASRM: Practice Committee of American Society for Reproductive Medicine
PCC: posterior cingulate cortex
PCI: percutaneous coronary intervention
PCS: Physical Component Summary
PEF: peak expiratory flow
PEFR: peak expiratory flow rate
PET: positron emission tomography
PFC: prefrontal cortex
PHS: U.S. Public Health Service
PIGF: placental growth factor
PLCO: Prostate, Lung, Colorectal, and Ovarian cancer screening
PMTA: Premarket Tobacco Product Application
po: by mouth
PPROM: preterm premature rupture of the membranes
PPTg: pedunculopontine tegmental nucleus
PRAMS: Pregnancy Risk Assessment Monitoring System
PROM: premature rupture of the membranes
PTCA: percutaneous transluminal coronary angioplasty
PVD: peripheral vascular disease
q: every
QALYs: quality-adjusted life years
QLQ-30: quality of life questionnaire 30 items
QoL: quality of life
RCT: randomized controlled trial
RE-AIM: Reach, Effectiveness, Adoption, Implementation, and Maintenance
RIVM: chronic disease model developed at the National Institute of Public Health and the Environment in The Netherlands
RNA: ribonucleic acid
RR: relative risk
RR: risk ratio
RSE: relative standard error
RV: residual volume
Rx: prescription product
SAH: subarachnoid hemorrhage
SAMMEC: Smoking-Attributable Mortality, Morbidity and Economic Costs
SAST: serum aspartate amino transferase
SAVE: Sleep Apnea Cardiovascular Endpoints Trial
SBRT: stereotactic body radiation therapy
SCD: sudden cardiac death
SCHIP: State Children’s Health Insurance Program
SCQoL: Smoking Cessation Quality of Life
SD: standard deviation
SDT: self-determination therapy
SE: standard error
SENECA: Survey Europe on Nutrition in the Elderly
sEng: soluble endoglin
SF: Short Form [survey]
sFlt-1: soluble fms-like tyrosine kinase 1
SGA: small-for-gestational age
SHARE: Survey of Health, Aging, and Retirement in Europe
SMC: Swedish Mammography Cohort
SMS: short text message
SNP: single nucleotide polymorphism
SNpc: substantia nigra pars compacta
SP-A: surface protein A
SR: sustained release
sRAGE: soluble Receptor for Advanced Glycation End [product]
SYNTAX: Synergy between Percutaneous Coronary Intervention with Taxus and Cardiac Surgery Trial
TDD: telecommunications device for the deaf
THC: tetrahydrocannabinol
TLC: total lung capacity
TPSAC: Tobacco Product Scientific Advisory Committee
TUS-CPS: Tobacco Use Supplement to the Current Population Survey
UCSD: University of California–San Diego
UK: United Kingdom
USAF: United States Air Force
USDHEW: U.S. Department of Health, Education, and Welfare
USDHHS: U.S. Department of Health and Human Services
USPSTF: U.S. Preventive Services Task Force
VA: U.S. Department of Veterans Affairs
VascuQoL: Vascular Quality of Life [questionnaire]
VC: vital capacity
VEGF: vascular endothelial growth factor
VLNC: very-low-nicotine-content
VTA: ventral tegmental area
VTE: venous thromboembolism
WHO: World Health Organization
WHOQoL-BREF: World Health Organization Quality of Life-BREF
WPS: Work Performance Scale
xCT: cystine/glutamate exchanger
YRBS: Youth Risk Behavior Survey
YRBSS: Youth Risk Behavior Surveillance System