# Foreword

Tobacco use remains the number one cause of preventable disease, disability, and death in the United States. Approximately 34 million American adults currently smoke cigarettes, with most of them smoking daily. Nearly all adult smokers have been smoking since adolescence. More than two-thirds of smokers say they want to quit, and every day thousands try to quit. But because the nicotine in cigarettes is highly addictive, it takes most smokers multiple attempts to quit for good.

Today, we know much more about the science of quitting than ever before. Research shows that smokers who use evidence-based tools to help them quit are more likely to succeed than those who do not use such tools, and that using a combination of these tools—for example, calling 1-800-QUIT-NOW and using nicotine replacement therapy, such as the nicotine patch or gum or a prescription medication— raises success rates even higher. Studies also show that policies that prohibit smoking in indoor public places and work spaces and that increase the price of tobacco products promote smoking cessation. This Surgeon General’s report

- Examines the effectiveness of various smoking cessation tools and resources;
- Reviews the health effects of smoking and catalogues the improvements to health that can occur when smokers quit;
- Highlights important new data on populations in which the prevalence of smoking is high and quit rates are low; and
- Identifies gaps in the availability and utilization of programs, policies, and resources that can improve cessation rates and help smokers quit.

Although the benefits of quitting are greater the earlier in life that an individual quits, this report confirms that it is never too late to quit smoking. Even persons who have smoked for many years or who have smoked heavily can realize health and financial benefits from quitting smoking.

The financial toll of smoking is substantial. Each year in the United States, annual healthcare spending attributed to smoking exceeds $170 billion. Measured against these numbers, comprehensive tobacco prevention and control strategies are extremely cost-effective investments that yield significant returns. For example, the first year of CDC’s Tips From Former Smokers national campaign prevented thousands of premature deaths in the United States, costing less than $500 for every smoker who quit.

We know what works to prevent and reduce tobacco use, including how to best help smokers quit for good. Putting this knowledge into action prevents disease, saves lives, and improves the quality of life for all Americans. At CDC, we remain committed to supporting the longstanding national effort to end the tobacco use epidemic and provide all Americans with the opportunity to live tobacco-free.

Robert R. Redfield, M.D. Director Centers for Disease Control and Prevention