# Acknowledgments

This report was prepared by the U.S. Department of Health and Human Services under the general direction of the Centers for Disease Control and Prevention, National Center for Chronic Disease Prevention and Health Promotion, Office on Smoking and Health.

- Vice Admiral (VADM) Jerome M. Adams, M.D., M.P.H., Surgeon General, U.S. Public Health Service, Office of the Assistant Secretary for Health, Office of the Surgeon General, Office of the Secretary, U.S. Department of Health and Human Services, Washington, D.C.
- Robert R. Redfield, M.D., Director, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Dana Shelton, M.P.H., Director (Acting), National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Peter A. Briss, M.D., M.P.H., Medical Director, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Rachel Kaufmann, Ph.D., M.P.H., Associate Director for Science, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Corinne Graffunder, Dr.P.H., M.P.H., Director, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.

## Editors of the report were

- Rachel A. Grana, Ph.D., M.P.H., Senior Scientific Editor, Program Director, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Ann Malarcher, Ph.D., M.S.P.H., Contributing Editor, Consultant, Epidemiologist (Retired), Office on Smoking and Health, National Center for Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Jonathan M. Samet, M.D., M.S., Senior Scientific Editor, Dean and Professor, Colorado School of Public Health, University of Colorado, Aurora, Colorado.
- Gillian L. Schauer, Ph.D., M.P.H., Senior Scientific Editor, Senior Consultant (Contractor), Centers for Disease Control and Prevention, Atlanta, Georgia; Clinical Instructor, Department of Health Services, School of Public Health, University of Washington, Seattle, Washington.
- Jennifer Unger, Ph.D., Senior Scientific Editor, Professor of Preventive Medicine, Keck School of Medicine, University of Southern California, Los Angeles, California.
- Brian A. King, Ph.D. M.P.H., Senior Associate Editor, Deputy Director for Research Translation, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Leslie A. Norman, M.B.A., Managing Editor, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Peter L. Taylor, M.B.A., Technical Editor, Fairfax, Virginia.

## Contributing authors were

- Robert T. Adsit, M.Ed., Director of Education and Outreach Programs, University of Wisconsin School of Medicine and Public Health, Center for Tobacco Research and Intervention, Madison, Wisconsin.
- Anthony J. Alberg, Ph.D., M.P.H., Professor and Chair, Department of Epidemiology and Biostatistics, Arnold School of Public Health, University of South Carolina, Columbia, South Carolina.
- Erik Augustson, Ph.D., M.P.H., Lead, Smokefree.gov Initiative, Program Director and Health Scientist, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Stephen Babb, M.P.H., Public Health Analyst, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Timothy B. Baker, Ph.D., Director of Research, Center for Tobacco Research and Intervention; Professor, Department of Medicine, University of Wisconsin School of Medicine and Public Health, Madison, Wisconsin.
- William Checkley, M.D., Ph.D., Associate Professor of Medicine, Division of Pulmonary and Critical Care, School of Medicine, Bloomberg School of Public Health, The Johns Hopkins University, Baltimore, Maryland.
- Graham A. Colditz, M.D., Dr.P.H., F.A.F.P.H.M., Niess-Gain Professor of Surgery, Professor of Medicine; Chief, Division of Public Health Sciences, Department of Surgery; Associate Director, Prevention and Control, Alvin J. Siteman Cancer Center; Deputy Director, Institute for Public Health, Washington University School of Medicine, St. Louis, Missouri.
- MeLisa Creamer, Ph.D., M.P.H., Oak Ridge Institute for Science and Education Fellow, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Kirsten S. Dorans, Sc.D., Postdoctoral Fellow, Department of Epidemiology, School of Public Health and Tropical Medicine, Tulane University, New Orleans, Louisiana.
- Lucinda England, M.D., M.S.P.H., Medical Officer, Division of Congenital and Developmental Disorders, National Center on Birth Defects and Developmental Disabilities, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Brenda Eskenazi, Ph.D., Jennifer and Brian Maxwell Professor of Maternal and Child Health and Epidemiology, Director, Center for Environmental Research and Children’s Health, School of Public Health, University of California, Berkeley, California.
- Michael C. Fiore, M.D., M.P.H., M.B.A., Hilldale Professor of Medicine, Director, Center for Tobacco Research and Intervention, University of Wisconsin School of Medicine and Public Health, Madison, Wisconsin.
- Jiang He, M.D., Ph.D., Professor and Joseph S. Copes, M.D. Chair; Department of Epidemiology, School of Public Health and Tropical Medicine; Director, Tulane University Translational Science Institute, Tulane University, New Orleans, Louisiana.
- Lauren A. Hunter, M.P.H., Graduate Student Researcher, Division of Epidemiology, School of Public Health, University of California, Berkeley, California.
- Eric J. Jacobs, Ph.D., Senior Scientific Director, Behavioral and Epidemiology Research Group, American Cancer Society, Atlanta, Georgia.
- Ahmed Jamal, M.D., M.P.H., Epidemiologist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Glenda Lassi, Ph.D., Genomics Project Leader, Centre for Genomics Research, Precision Medicine and Genomics, Innovative Medicines and Early Development Biotech Unit, AstraZeneca, Cambridge; Research Fellow, Medical Research Council Integrative Epidemiology Unit, School of Psychological Science, University of Bristol, Bristol, United Kingdom.
- Adam M. Leventhal, Ph.D., Director, USC Health, Emotion, and Addiction Laboratory, Professor, Departments of Preventive Medicine and Psychology, University of Southern California, Los Angeles, California.
- David T. Levy, Ph.D., Professor, Lombardi Comprehensive Cancer Center, Georgetown University, Washington, D.C.
- Maggie Mahoney, J.D., Public Health Analyst, Carter Consulting, Inc. (Contractor), Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Ann Malarcher, Ph.D., M.S.P.H., Contributing Editor, Consultant, Epidemiologist (Retired), Office on Smoking and Health, National Center for Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Kristy L. Marynak, M.P.P., Lead Public Health Analyst, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Tim McAfee, M.D., M.P.H., Senior Medical Officer, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Megan B. Miller, Ph.D., Postdoctoral Fellow, Department of Psychiatry, Yale University, New Haven, Connecticut.
- Marcus R. Munafò, Ph.D., Professor of Biological Psychology, School of Psychological Science, University of Bristol, Bristol, United Kingdom.
- Christina C. Newton, M.S.P.H., Scientist, Behavioral and Epidemiology Research Group, American Cancer Society, Atlanta, Georgia.
- Leslie A. Norman, M.B.A., Public Health Analyst, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Michael K. Ong, M.D., Ph.D., Professor in Residence, Division of General Internal Medicine and Health Services Research, Department of Medicine, David Geffen School of Medicine, Department of Health Policy and Management, Jonathan and Karin Fielding School of Public Health, University of California; Chief, Hospitalist Division, Department of Medicine, Veteran’s Administration Greater Los Angeles Healthcare System; Chair, State of California Tobacco Education and Research Oversight Committee, Los Angeles, California.
- Paul R. Pentel, M.D., Professor of Medicine, Division of Clinical Pharmacology, University of Minnesota; Chief, Pharmacy, Hennepin Healthcare, Minneapolis, Minnesota.
- Marina R. Picciotto, Ph.D., Charles B.G. Murphy Professor and Deputy Chair for Basic Science in Psychiatry; Professor of Neuroscience, of Pharmacology, and in the Child Study Center; School of Medicine, Yale University, New Haven, Connecticut.
- Judith J. Prochaska, Ph.D., M.P.H., Associate Professor of Medicine, Stanford Prevention Research Center, Department of Medicine, Stanford University, Stanford, California.
- Mays Shamout, M.D., M.P.H., Epidemic Intelligence Service Officer, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Sundar Shrestha, Ph.D., Senior Economist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Trishul Siddharthan M.D., Postdoctoral Fellow, Division of Pulmonary and Critical Care Medicine, The Johns Hopkins University, Baltimore, Maryland.
- Elliot A. Stein, Ph.D., Chief, Neuroimaging Research Branch, National Institute on Drug Abuse, Intramural Research Program, National Institutes of Health, Baltimore, Maryland.
- Carolyn R. T. Stoll, M.P.H., M.S.W., Staff Scientist, Division of Public Health Sciences, Department of Surgery, Washington University School of Medicine, St. Louis, Missouri.
- Dennis R. Trinidad, Ph.D., M.P.H., Associate Professor, Department of Family Medicine and Public Health, University of California—San Diego, La Jolla, California.
- James Tsai, M.D., M.P.H., Epidemiologist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Michael A. Tynan, Public Health Analyst, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Rachel F. Tyndale, Ph.D., Canada Research Chair in Pharmacogenomics, Centre for Addiction and Mental Health; Professor, Department of Pharmacology and Toxicology, Department of Psychiatry, University of Toronto, Toronto, Ontario, Canada.
- Graham Warren, M.D., Ph.D., Vice Chairman for Research, Professor, Department of Radiation Oncology, Department of Cell and Molecular Pharmacology and Experimental Therapeutics, Medical University of South Carolina, Charleston, South Carolina.
- Lei Zhang, Ph.D., Health Scientist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.

## Reviewers were

- Israel Agaku, D.M.D., Ph.D., M.P.H., Senior Scientist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Brian S. Armour, Ph.D., Associate Director for Science, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Stephen Babb, M.P.H., Public Health Analyst, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- R. Graham Barr, M.D., Dr.P.H., Professor of Medicine and Epidemiology, Columbia University Medical Center, New York, New York.
- Neal L. Benowitz, M.D., Professor of Medicine, Bioengineering, and Therapeutic Sciences; Chief, Division of Clinical Pharmacology, University of California, San Francisco, California.
- Carla J. Berg, Ph.D., M.B.A., L.P., Associate Professor, Department of Behavioral Sciences and Health Education, Rollins School of Public Health; Associate Director for Population Sciences, Winship Cancer Institute, Emory University Woodruff Health Sciences Center, Atlanta, Georgia.
- David Berrigan, Ph.D., M.P.H., Program Director, Health Behaviors Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Michele Bloch, M.D., Ph.D., Chief, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Raymond Boyle, Ph.D., M.P.H., Director of Research Programs, ClearWay Minnesota, Minneapolis, Minnesota.
- Thomas H. Brandon, Ph.D., Chair, Department of Health Outcomes and Behavior; Director, Tobacco Research and Intervention Program, Moffitt Cancer Center; Professor, Departments of Psychology and Oncologic Sciences, University of South Florida, Tampa, Florida.
- David M. Burns, M.D., Professor Emeritus, Department of Family Medicine and Public Health, University of California— San Diego, School of Medicine, San Diego, California.
- Ralph Caraballo, Ph.D., M.P.H., Senior Advisor, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Frank J. Chaloupka, Ph.D., Director, Health Policy Center, Research Professor, Division of Health Policy and Administration, School of Public Health, University of Illinois at Chicago, Chicago, Illinois.
- Graham A. Colditz, M.D., Dr.P.H., F.A.F.P.H.M., Niess-Gain Professor of Surgery, Professor of Medicine; Chief, Division of Public Health Sciences, Department of Surgery; Associate Director Prevention and Control, Alvin J. Siteman Cancer Center; Deputy Director, Institute for Public Health, Washington University School of Medicine, St. Louis, Missouri.
- Jamie R. Cordova, M.P.H., Cancer Research Training Award Fellow, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- David B. Coultas, M.D., F.A.C.P., Associate Chief of Staff Education, Veterans Affairs Portland Health Care System; Professor of Medicine, Oregon Health and Science University, Portland, Oregon.
- Elizabeth Courtney-Long, M.A., M.S.P.H., Deputy Associate Director for Science, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- K. Michael Cummings, Ph.D., M.P.H., Professor, Department of Psychiatry and Behavior Sciences; Co-Leader, Hollings Cancer Center Tobacco Research Program, Medical University of South Carolina, Charleston, South Carolina.
- Sue Curry, Ph.D., Interim Executive Vice President and Provost, Distinguished Professor of Health Management and Policy, University of Iowa, Iowa City, Iowa.
- Sean P. David, M.D., S.M., D.Phil., Associate Professor of Medicine, Division of Primary Care and Population Health, Stanford University School of Medicine, Palo Alto, California.
- Cristine D. Delnevo, Ph.D., M.P.H., Professor and Director, Center for Tobacco Studies, Rutgers School of Public Health, New Brunswick, New Jersey.
- Dawn L. DeMeo, M.D., M.P.H., Associate Professor of Medicine, Harvard Medical School; Associate Physician, Channing Division of Network Medicine and the Division of Pulmonary and Critical Care, Brigham and Women’s Hospital, Boston, Massachusetts.
- Lucinda England, M.D., M.S.P.H., Medical Officer, Division of Congenital and Developmental Disorders, National Center on Birth Defects and Developmental Disabilities, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Eric J. Feuer, Ph.D., Chief, Statistical Research and Applications Branch, Surveillance Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Aaron F. Folsom, M.D., M.P.H., Professor, University of Minnesota School of Public Health, Division of Epidemiology and Community Health, Minneapolis, Minnesota.
- Neal D. Freedman, Ph.D., M.P.H., Senior Investigator, Metabolic Epidemiology Branch, Division of Cancer Epidemiology and Genetics, National Cancer Institute, National Institutes of Health, Rockville, Maryland.
- Gary A. Giovino, Ph.D., M.S., Professor and Chair, Department of Community Health and Health Behavior, School of Public Health and Health Professions, University at Buffalo, State University of New York (SUNY), Buffalo, New York.
- Meredith A Grady, M.P.H., Co-Lead, Smokefree.gov Initiative, Tobacco Control Research Branch, Behavioral Research Program, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- David C. Grossman, M.D., M.P.H., Senior Associate Medical Director and Senior Investigator, Kaiser Permanente Washington Health Research Institute; Professor, Department of Health Service; Adjunct Professor, Department of Pediatrics, University of Washington, Seattle, Washington.
- Melissa B. Harrell, Ph.D., M.P.H., Associate Professor, The University of Texas Health Science Center at Houston, School of Public Health, Austin Regional Campus, Austin, Texas.
- Dorothy K. Hatsukami, Ph.D., Associate Director, Masonic Cancer Center; Professor of Psychiatry, University of Minnesota, Minneapolis, Minnesota.
- Stephen T. Higgins, Ph.D., Director, Vermont Center on Behavior and Health, Virginia H. Donaldson Professor of Translational Science, Departments of Psychiatry and Psychological Science; Vice Chair, Department of Psychiatry, University of Vermont, Burlington, Vermont.
- Elizabeth S. Holland, M.P.A., Senior Technical Advisor, Quality Measurement and Value-Based Incentives Group, Division of Health Information Technology, Center for Clinical Standards and Quality, Centers for Medicare and Medicaid Services, Baltimore, Maryland.
- David Homa, Ph.D., M.P.H., Epidemiologist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Corinne G. Husten, M.D., M.P.H., Senior Medical Advisor, Office of the Center Director, Center for Tobacco Products, U.S. Food and Drug Administration, Silver Spring, Maryland.
- Maki Inoue-Choi, Ph.D., M.S., Staff Scientist, Metabolic Epidemiology Branch, Division of Cancer Epidemiology and Genetics, National Cancer Institute, National Institutes of Health, Rockville, Maryland.
- Prabhat Jha, O.C., M.D., D.Phil., F.C.A.H.S., F.R.S.C., Professor, University of Toronto; Chair in Global Health and Epidemiology, Dalla Lana School of Public Health; Executive Director, Centre for Global Health Research, St. Michael’s Hospital, Toronto, Canada.
- Michelle C. Kegler, Dr.P.H., M.P.H., Professor, Department of Behavioral Sciences and Health Education, Rollins School of Public Health, Emory University, Atlanta, Georgia.
- Paul J. Kenny, Ph.D., Ward-Coleman Professor and Chairman, Department of Neuroscience, Icahn School of Medicine at Mount Sinai, New York, New York.
- Chris Kotsen, Psy.D., C.T.T.S., N.C.T.T.P., Lead Psychologist, Tobacco Quitcenter, Lung Cancer Institute, Steeplechase Cancer Center, Robert Wood Johnson Barnabas Health University Hospital Somerset, Somerville, New Jersey.
- Thomas E. Kottke, M.D., M.S.P.H., Medical Director for Well-Being and Senior Clinical Investigator, HealthPartners Institute; Professor, Department of Medicine, University of Minnesota, Minneapolis, Minnesota.
- Stephanie R. Land, Ph.D., Program Director and Statistician, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Frank T. Leone, M.D., M.S., Director, Comprehensive Smoking Treatment Program; Professor, Division of Pulmonary, Allergy and Critical Care, University of Pennsylvania, Philadelphia, Pennsylvania.
- Douglas E. Levy, Ph.D., Associate Professor of Medicine, Harvard Medical School, Mongan Institute Health Policy Center, Massachusetts General Hospital, Boston, Massachusetts.
- Shari M. Ling, M.D., Deputy Chief Medical Officer, Centers for Medicare and Medicaid Services, Baltimore, Maryland.
- Jay H. Lubin, Ph.D., National Institutes of Health Scientist Emeritus, Biostatistics Branch, Division of Cancer Epidemiology and Genetics, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- F. Joseph McClernon, Ph.D., Director, Center for Addiction Science and Technology; Professor, Department of Psychiatry and Behavioral Sciences, Duke University School of Medicine, Durham, North Carolina.
- Paul C. Melstrom, Ph.D., Pharm.D., Senior Research Scientist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Glen D. Morgan, Ph.D., Psychologist, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Ajay K. Nangia, M.B.B.S., F.A.C.S., Professor and Vice Chair of Urology, Director of Andrology, Department of Urology, University of Kansas Health System, Kansas City, Kansas.
- Satomi Odani, M.P.H., Oak Ridge Institute for Science and Education Fellow, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- S. Michael Owens, Ph.D., Director, Center for Alcohol and Drug Abuse Studies; Professor, Department of Pharmacology and Toxicology, College of Medicine, University of Arkansas for Medical Sciences, Little Rock, Arkansas.
- Mark Parascandola, Ph.D., M.P.H., Program Director, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Terry F. Pechacek, Ph.D., Professor and Interim Division Director of Health Management and Policy, School of Public Health, Georgia State University, Atlanta, Georgia.
- Megan E. Piper, Ph.D., Associate Professor, Department of Medicine, School of Medicine and Public Health, University of Wisconsin; Associate Director of Research, University of Wisconsin Center for Tobacco Research and Intervention, Madison, Wisconsin.
- Elizabeth A. Platz, Sc.D., M.P.H., Professor, Department of Epidemiology, Bloomberg School of Public Health, The Johns Hopkins University, Baltimore, Maryland.
- Elizabeth Reimels, J.D., Associate Director for Policy, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Carolyn Reyes-Guzman, Ph.D., M.P.H., Epidemiologist and Program Director, Tobacco Research Branch, Control Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Nancy A. Rigotti, M.D., Professor of Medicine, Harvard Medical School; Director, Tobacco Research and Treatment Center, Massachusetts General Hospital, Boston, Massachusetts.
- Catherine Saucedo, Deputy Director, Smoking Cessation Leadership Center, University of California, San Francisco, California.
- Robert Schnoll, Ph.D., Associate Professor and Program Leader, Center for Interdisciplinary Research on Nicotine Addiction, Department of Psychiatry; Associate Director for Population Science and Co-Leader for Tobacco and Environmental Carcinogenesis, Abramson Cancer Center; Senior Fellow, Center for Public Health Initiatives, University of Pennsylvania, Philadelphia, Pennsylvania.
- Steven A. Schroeder, M.D., Professor, Distinguished Professorship in Health and Health Care, Department of Medicine; Director, Smoking Cessation Leadership Center, University of California, San Francisco, California.
- Donna R. Shelley, M.D., M.P.H., Professor, Department of Population Health; Professor, Department of Medicine, New York University School of Medicine; Co-Director, Section for Tobacco, Alcohol, and Drug Abuse, New York, New York.
- Peter G. Shields, M.D., Deputy Director, Comprehensive Cancer Center and James Cancer Hospital; Professor, College of Medicine, The Ohio State University Wexner Medical Center, Columbus, Ohio.
- Sundar Shrestha, Ph.D., Senior Economist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Lia J. Sorgen, Cancer Research Training Award Fellow, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Frank E. Speizer, M.D., E. H. Kass Distinguished Professor of Medicine, Harvard Medical School, Channing Laboratory, Department of Medicine, Brigham and Women’s Hospital, Boston, Massachusetts.
- Margaret R. Spitz, M.D., M.P.H., Professor, Dan L. Duncan Comprehensive Cancer Center, Department of Molecular and Cellular Biology, Baylor College of Medicine, Houston, Texas.
- Meir Stampfer, M.D., Dr.P.H., Professor of Epidemiology and Nutrition, Harvard T.H. Chan School of Public Health, Professor of Medicine, Channing Division of Network Medicine, Department of Medicine, Brigham and Women’s Hospital and Harvard Medical School, Boston, Massachusetts.
- Linda Topping Streitfeld, M.P.H., Social Science Research Analyst, Center for Medicare and Medicaid Innovation, Centers for Medicare and Medicaid Services, Baltimore, Maryland.
- Stephanie Sturgis, M.P.H., Program Analyst, Idoneous Consulting Services (Contractor), Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Van T. Tong, M.P.H., Epidemiologist, Division of Congenital and Developmental Disorders, National Center for Birth Defects and Developmental Disability, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Brenna VanFrank, M.D., M.S.P.H., Medical Officer, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Robert E. Vollinger, Jr., Dr.P.H., M.S.P.H., Program Director, Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Kenneth E. Warner, Ph.D., Avedis Donabedian Distinguished University Professor Emeritus of Public Health and Dean Emeritus, School of Public Health, University of Michigan, Ann Arbor, Michigan.
- Gordon B. Willis, Ph.D., Tobacco Control Research Branch, Behavioral Research Program, Division of Cancer Control and Population Sciences, National Cancer Institute, National Institutes of Health, Bethesda, Maryland.
- Shu-Hong Zhu, Ph.D., Director, Center for Research and Intervention in Tobacco Control; Professor, Family Medicine and Public Health, University of California School of Medicine, San Diego, California.

## Other contributors were

- Katherine J. Asman, M.S.P.H., Statistician, Biostatistics and Epidemiology Division, RTI International, Atlanta, Georgia.
- Susan Bratten, Senior Editor, American Institutes for Research, Washington, D.C.
- Meghan N. Buran, M.P.H., Senior Professional Research Assistant to Dr. Jonathan M. Samet, Department of Epidemiology, Colorado School of Public Health, University of Colorado, Aurora, Colorado.
- Deborah A. Burnette, Expert Consultant, ICF International, Atlanta, Georgia.
- Amy de Boinville, Production Design Associate, American Institutes for Research, Washington, D.C.
- Phil Esra, Editor, American Institutes for Research, Washington, D.C.
- Carolyn Feola Rugamas, Production Design Specialist, American Institutes for Research, Washington, D.C.
- Jane Garwood, Senior Editor, American Institutes for Research, Washington, D.C.
- Andrea S. Gentzke, Ph.D., M.S., Health Scientist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Sondra Hammond, Production Design Associate, American Institutes for Research, Washington, D.C.
- William A. Harris, M.M., Northrop Grumman (Contractor), Division of Adolescent and School Health, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Sean Hu, M.D., M.S., Dr. P.H., Senior Epidemiologist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Angela Jehle, Director, Publications & Creative Services, American Institutes for Research, Washington, D.C.
- Devon LaPoint, Project Associate, American Institutes for Research, Washington, D.C.
- Dara L. Ledford, Senior Manager, Production Design, American Institutes for Research, Washington, D.C.
- Pamela R. Lemos, M.S., Public Health Analyst, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Yong Liu, M.D., M.S., Statistician, Division of Population Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Christine C. Maisano, Editor, Prana Enterprises, Inc. (Contractor), American Institutes for Research, Washington, D.C.
- Kathleen Major, K Major Editorial Services (Contractor), American Institutes for Research, Washington, D.C.
- Kristen N. Mangold, M.S.W., Public Health Advisor, National Cancer Institute, National Institutes of Health, Rockville, Maryland.
- Timothy L. McManus, M.S., Lead Health Scientist, Division of Adolescent and School Health, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Richard A. Miech, Ph.D., M.P.H., Principal Investigator, Monitoring the Future; Professor, Survey Research Center at the Institute for Social Research, University of Michigan, Ann Arbor, Michigan.
- Matthew Mowczko, M.Des., Graphic Design Specialist, American Institutes for Research, Washington, D.C.
- Don Mullins, Jr., M.P.H., Project Director, American Institutes for Research, Washington, D.C.
- Stephanie Neuben, Editor, American Institutes for Research, Washington, D.C.
- Kim O’Brien, Editor, American Institutes for Research, Washington, D.C.
- Patrick M. O’Malley, Ph.D., Research Professor, Institute for Social Research, University of Michigan, Ann Arbor, Michigan.
- Andrew Peterman, Lead Production Editor, American Institutes for Research, Washington, D.C.
- Elyse Phillips, Oak Ridge Institute for Science and Education Fellow, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Ketra L. Rice, Ph.D., M.S., M.B.A., Senior Service Fellow, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Fatma Romeh Ali, Ph.D., Fellow, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Helen A. Sacco, M.S.Ed., Editor, American Institutes for Research, Washington, D.C.
- Saida Sharapova, M.D., M.P.H., C.P.H., Epidemiologist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Kathryn E. Szynal, Editorial Assistant, Idoneous Consulting Services (Contractor), Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Wendy E. Theobald, Ph.D., Researcher, University of Wisconsin-Center for Tobacco Research and Intervention, University of Wisconsin School of Medicine and Public Health, Madison, Wisconsin.
- Stacy Thorne, Ph.D., M.P.H., Health Scientist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Sarah Trigger, M.P.H., Social Scientist, Center for Tobacco Products, U.S. Food and Drug Administration, Silver Spring, Maryland.
- Katrina Trivers, Ph.D., M.S.P.H., Epidemiologist, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Sharon Wallace, Production Design Specialist, American Institutes for Research, Washington, D.C.
- Kimp Walton, M.S., Health Statistician, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Teresa Wang, Ph.D., M.S., Epidemic Intelligence Service Officer, Lieutenant, U.S. Public Health Service, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Karen C. Ward, Production Design Specialist, American Institutes for Research, Washington, D.C.
- Xin Xu, Ph.D., Economist, Center for Tobacco Products, U.S. Food and Drug Administration, Silver Spring, Maryland.