# Message from Alex M. Azar II, Secretary, U.S. Department of Health and Human Services

Throughout its history, the U.S. Department of Health and Human Services (USDHHS) has led efforts to prevent and reduce the devastating effects of tobacco use, especially the use of combustible tobacco products, as part of its mission to enhance and protect the health and well-being of all Americans. USDHHS has provided critical support in the fields of research and evaluation, program and policy development, public information and education, regulatory activities, systems-level change and management, and clinical practices that has contributed to a dramatic 67% decline in cigarette smoking among U.S. adults since 1965. Support from USDHHS has helped medical and healthcare organizations, government agencies at all levels, and nongovernmental partners create and sustain programs that prevent initiation; help tobacco product users quit; and foster healthy, smokefree environments.

This report is the latest of a longstanding tradition of tobacco prevention and control efforts by USDHHS. Our work includes a comprehensive tobacco control strategic action plan, Ending the Tobacco Epidemic, and coordination of tobacco control efforts with related efforts by other federal agencies through the Interagency Committee on Smoking and Health. Reports such as this one from the U.S. Surgeon General give the latest data on tobacco and health to scientists, healthcare professionals, and the public. Research leadership and grant funding through USDHHS’s National Institutes of Health contribute to growing knowledge of effective tobacco control strategies and smoking cessation tools. The National Tobacco Control Program, led by the Centers for Disease Control and Prevention (CDC), ensures that these strategies and tools are readily available to state, local, tribal, and territorial public health programs, as well as to partners serving a variety of populations that are disproportionately affected by tobacco use. The U.S. Food and Drug Administration (FDA) regulates the manufacturing, marketing, and sale of tobacco products. Medicare and Medicaid provide smoking cessation tools and support to millions of Americans. Multiple public information campaigns, such as CDC’s Tips From Former Smokers and FDA’s Every Try Counts, educate Americans about the significant health risks from smoking and the importance of quitting. Additionally, many agencies in USDHHS provide direct assistance to smokers, including the National Cancer Institute through its Smokefree.gov initiative (https://smokefree.gov), and national quitline portal, 1-800-QUIT-NOW.

These and other important efforts are critical to improving the nation’s public health. Smoking kills nearly half a million Americans every year, and millions more live with serious chronic diseases caused by smoking. We know that comprehensive interventions at all levels of government and by partners throughout the public health community are extremely effective at preventing and reducing tobacco use. We remain committed to ending the tobacco use epidemic in the United States.