# References

* Note: Defining “misinformation” is a challenging task, and any definition has limitations. One key issue is whether there can be an objective benchmark for whether something qualifies as misinformation. Some researchers argue that for something to be considered misinformation, it has to go against “scientific consensus” (e.g., Chou, Gaysynsky, & Cappella (2020)). Others consider misinformation to be information that is contrary to the “best available evidence” (e.g., Johns Hopkins Center for Health Security (2021)). Both approaches recognize that what counts as misinformation can change over time with new evidence and scientific consensus. This Advisory prefers the “best available evidence” benchmark since claims can be highly misleading and harmful even if the science on an issue isn’t yet settled. At the same time, it is important to be careful and avoid conflating controversial or unorthodox claims with misinformation. Transparency, humility, and a commitment to open scientific inquiry are critical. A second key issue is whether misinformation should include not only false information but also misleading information. This Advisory includes misleading claims in the definition. Consider an anecdote about someone experiencing a rare side effect after a routine surgery. The specific anecdote may be true but hide the fact that the side effect is very rare and treatable. By misinforming people about the benefits and risks of the surgery, the anecdote can be highly misleading and harmful to public health. Going forward, there is a need for further alignment on a shared definition of misinformation. However, we can meaningfully improve the health information environment even without a consensus definition of misinformation. For further discussion on definitions, see Vraga & Bode (2020).

1 WHO, UN, UNICEF, UNDP, UNESCO, UNAIDS, ITU, UN Global Pulse, & IFRC. (2020, September 23). Managing the COVID-19 infodemic: Promoting healthy behaviours and mitigating the harm from misinformation and disinformation. World Health Organization. https://www.who.int/news/item/23-09-2020-managing-the-covid-19-infodemic-promoting-healthy-behaviours-and-mitigating-the-harm-from-misinformation-and-disinformation
2 Branswell, H. (2021, April 21). We know a lot about Covid-19. Experts have many more questions. STAT News. https://www.statnews.com/2021/04/20/we-know-a-lot-about-covid-19-experts-have-many-more-questions/
3 Smith, R., Cubbon, S., & Wardle, C. (2020, November 12). Under the surface: Covid-19 vaccine narratives, misinformation & data deficits on social media. First Draft. https://firstdraftnews.org/vaccinenarratives-full-report-november-2020
4 Baum, M., Ognyanova, K., Chwe, H., Quintana, A., Perlis, R. H., Lazer, D., Druckman, J., Santillana, M., Lin, J., Della Volpe, J., Simonson, M.D., & Green, J. (2021). The COVID states project #14: Misinformation and vaccine acceptance. OSF Preprints. 10.31219/osf.io/w974j
5 Roozenbeek, J., Schneider, C., Dryhurst, S., Kerr, J., Freeman, A.L.J., Recchia, G., van der Bles, A.M., & van der Linden, S. (2020). Susceptibility to misinformation about COVID-19 around the world. Royal Society Open Science, 7(10). 10.1098/rsos.201199
6 Chou, W.Y.S., Gaysynsky, A., & Cappella, J. N. (2020). Where we go from here: Health misinformation on social media. American Journal of Public Health, 110, S273–S275. 10.2105/AJPH.2020.305905 33001722
7 Vraga, E., & Bode, L. (2020). Defining misinformation and understanding its bounded nature: Using expertise and evidence for describing misinformation. Political Communication, 37(1), 136–144. 10.1080/10584609.2020.1716500
8 Sell, T.K., Hosangadi, D., Smith, E., Trotochaud, P.V., Gronvall, G.K., Rivera, Y., Sutton, J., Ruiz, A., & Cicero, A. (2021, March 23). National priorities to combat misinformation and disinformation for COVID-19 and future public health threats: A call for a national strategy. Johns Hopkins Center for Health Security. https://www.centerforhealthsecurity.org/our-work/publications/national-priorities-to-combat-misinformation-and-disinformation-for-covid-19
9 Chang, A., Schnall, A., Law, R., Bronstein, A.C., Marraffa, J.M., Spiller, H.A., Hays, H.L., Funk, A.R., Mercurio-Zappala, M., Callelo, D.P., Aleguas, A., Borys, D.J., Boehmer, T., & Svendsen, E. (2020). Cleaning and disinfectant chemical exposures and temporal associations with COVID-19 — National Poison Data System, United States, January 1, 2020–March 31, 2020. MMWR Morbidity and Mortality Weekly Report, 69, 496–498. 10.15585/mmwr.mm6916e1 32324720
10 Gottlieb, M., & Dyer, S. (2020). Information and disinformation: Social media in the COVID-19 crisis. Academic Emergency Medicine, 27(7), 640–641. 10.1111/acem.14036 32474977
11 Loomba, S., de Figueiredo, A., Piatek, S.J., . (2021). Measuring the impact of COVID-19 vaccine misinformation on vaccination intent in the UK and USA. Nature Human Behavior, 5, 337–348. 10.1038/s41562-021-01056-1
12 Mello, M. M., Greene, J. A., & Sharfstein, J. M. (2020). Attacks on public health officials during COVID-19. JAMA, 324(8), 741. 10.1001/jama.2020.14423 32777019
13 Stone, W. (2020, June 3). Local public health workers report hostile threats and fears about contact tracing. National Public Radio. https://www.npr.org/sections/health-shots/2020/06/03/868566600/local-public-health-workers-report-hostile-threats-and-fears-about-contact-traci
14 Tucker, J.A., Guess, A., Barbera P, Vaccari, C., Siegel, A., Sanovich, S., Stukal, D., & Nyhan, B. (2018). Social media, political polarization and political disinformation: A review of the scientific literature. SSRN. 10.2139/ssrn.3144139
15 Chou, W.S., Oh, A., & Klein, W.M.P. (2018). Addressing health-related misinformation on social media. JAMA, 320(23), 2417–2418. 10.1001/jama.2018.16865 30428002
16 Jost, J., Van der Linden, S., Panagopoulos, C., & Hardin, C. (2018). Ideological asymmetries in conformity, desire for shared reality, and the spread of misinformation. Current Opinion in Psychology, 23, 77–83. 10.1016/j.copsyc.2018.01.003 29427900
17 Rao, T. S., & Andrade, C. (2011). The MMR vaccine and autism: Sensation, refutation, retraction, and fraud. Indian journal of psychiatry, 53(2), 95–96. 10.4103/0019-5545.82529 21772639
18 Hussain, A., Ali, S., Ahmed, M., & Hussain, S. (2018). The anti-vaccination movement: A regression in modern medicine. Cureus, 10(7), e2919. 10.7759/cureus.2919 30186724
19 City of New York Office of the Mayor. (2019, April 9). De Blasio Administration’s Health Department declares public health emergency due to measles crisis. https://www1.nyc.gov/office-of-the-mayor/news/186-19/de-blasio-administration-s-health-department-declares-public-health-emergency-due-measles-crisis/
20 Clark County Public Health. (2019, January 18). County declares public health emergency due to measles outbreak. https://www.clark.wa.gov/public-health/county-declares-public-health-emergency-due-measles-outbreak
21 Hall, V., Banerjee, E., Kenyon, C., Strain, A., Griffith, J., Como-Sabetti, K., Heath, J., Babta, L., Martin, K., McMahon, M., Johnson, D., Roddy, M., Dunn D., & Ehresmann, K. (2017). Measles outbreak — Minnesota April–May 2017. MMWR Morbidity and Mortality Weekly Report, 66, 713–717. 10.15585/mmwr.mm6627a1 28704350
22 Chigwedere, P., Seage, G. R., Gruskin, S., Lee, T. H., & Essex, M. (2008). Estimating the Lost Benefits of Antiretroviral Drug Use in South Africa. JAIDS Journal of Acquired Immune Deficiency Syndromes, 49(4), 410–415. 10.1097/qai.0b013e31818a6cd5 19186354
23 Swire-Thompson, B., & Lazer, D. (2019). Public health and online misinformation: Challenges and Recommendations. Annual Review of Public Health, 41, 433–451. 10.1146/annurev-publhealth-040119-094127
24 Chou, W.S., & Budenz, A. (2020). Considering emotion in COVID-19 vaccine communication: Addressing vaccine hesitancy and fostering vaccine confidence. Health Communication, 35(14), 1718–1722. 10.1080/10410236.2020.1838096 33124475
25 Wang, Y., McKee, M., Torbica, A., & Stuckler, D. (2019). Systematic literature review on the spread of health-related misinformation on social media. Social science & medicine (1982), 240, 112552. 10.1016/j.socscimed.2019.112552 31561111
26 Suarez-Lledo, V., & Alvarez-Galvez, J. (2021). Prevalence of health misinformation on social media: Systematic review. Journal of Medical Internet Research, 23(1). 10.2196/17187
27 Scales, D., Gorman, J., & Jamieson, K. (2021). The Covid-19 infodemic — applying the epidemiologic model to counter misinformation. New England Journal of Medicine. 10.1056/NEJMp2103798
28 Karanian, J.M., Rabb, N., Wulff, A.N., Torrance, M.G., Thomas, A.K., & Race, E. (2020). Protecting memory from misinformation: Warnings modulate cortical reinstatement during memory retrieval. Proceedings of the National Academy of Sciences, 117 (37), 22771–22779. 10.1073/pnas.2008595117
29 Acerbi, A. (2019). Cognitive attraction and online misinformation. Palgrave Communications, 5(15). 10.1057/s41599-019-0224-y
30 Freiling, I., Krause, N., & Scheufele, D. (2021). Believing and sharing misinformation, fact-checks, and accurate information on social media: The role of anxiety during COVID-19. New Media & Society. 10.1177/14614448211011451
31 Vosoughi, S., Roy, D., & Aral, S. (2018). The spread of true and false news online. Science, 359, 1146–1151. 10.1126/science.aap9559 29590045
32 Lindström, B., Bellander, M., Schultner, D.T., Chang, A., Tobler, P.N., & Amodio, D.M. (2021). A computational reward learning account of social media engagement. Nature Communications, 12(1311). 10.1038/s41467-020-19607-x
33 Brady, W., Gantman, A., & Bavel, J. (2020). Attentional Capture Helps Explain Why Moral and Emotional Content Go Viral. Journal of Experimental Psychology, 149(4), 746–756. doi:10.1037/xge0000673 31486666
34 Tang, L., Fujimoto, K., Amith, M. T., Cunningham, R., Costantini, R. A., York, F., Xiong, G., Boom, J. A., & Tao, C. (2021). "Down the rabbit hole" of vaccine misinformation on YouTube: Network exposure study. Journal of Medical Internet Research, 23(1), e23262. 10.2196/23262 33399543
35 Donovan, J. (2020). Concrete recommendations for cutting through misinformation during the COVID-19 pandemic. American Journal of Public Health, 110, S3. 10.2105/AJPH.2020.305922
36 Pickard, V. (2020). Democracy without journalism?: Confronting the misinformation society. Oxford University Press.
37 Tsfati, Y., Boomgaarden, H.G., Strömbäck, J., Vliegenthart, R. , Damstra, A., & Lindgren, E. (2020). Causes and consequences of mainstream media dissemination of fake news: Literature review and synthesis. Annals of the International Communication Association, 44(2), 157–173. 10.1080/23808985.2020.1759443
38 Phillips, W. (2018, May 22). The oxygen of amplification: Better practices for reporting on extremists, antagonists, and manipulators. Data & Society. https://datasociety.net/library/oxygen-of-amplification/
39 Golebiewski, M. and Boyd, D. (2019, November). Data voids: Where missing data can be easily exploited. Data & Society. https://datasociety.net/wp-content/uploads/2019/11/Data-Voids-2.0-Final.pdf
40 Cubbon, Seb. (2020, December 15). Identifying ‘data deficits’ can pre-empt the spread of disinformation. First Draft Footnotes. https://medium.com/1st-draft/identifying-data-deficits-can-pre-empt-the-spread-of-disinformation-93bd6f680a4e
41 Collins-Dexter, B. (2020, June). Canaries in the coal mine: COVID-19 misinformation and black communities. Technology and Social Change project (TaSC) and Shorenstein Center. 10.37016/TASC-2020-01
42 Boxell, L., Gentzkow, M., & Shapiro, J. (2020, January). Cross-country trends in affective polarization (NBER Working Paper No. 26669). National Bureau of Economic Research. http://www.nber.org/papers/w26669
43 Hameleers, M., & van der Meer, T. (2019). ). Misinformation and polarization in a high-choice media environment: How effective are political fact-checkers? Communication Research, 47(2), 227–250. 10.1177/0093650218819671
44 Seo, H., Blomberg, M., Altschwager, D., & Vu, H. (2020). Vulnerable populations and misinformation: A mixed-methods approach to underserved older adults’ online information assessment. New Media & Society. 10.1177/1461444820925041
45 Center for Countering Digital Hate. (2021, March 24). The disinformation dozen: Why platforms must act on twelve leading online anti-vaxxers. https://www.counterhate.com/disinformationdozen
46 New York Times. (2021). Daily distortions. https://www.nytimes.com/spotlight/disinformation
47 Poynter. Fighting the infodemic: The #CoronaVirusFacts alliance. https://www.poynter.org/coronavirusfactsalliance/
48 Facebook. (2021, May 26). Taking action against people who repeatedly share misinformation. https://about.fb.com/news/2021/05/taking-action-against-people-who-repeatedly-share-misinformation/
49 Twitter (n.d.). COVID-19 misleading information policy. Twitter. https://help.twitter.com/en/rules-and-policies/medical-misinformation-policy
50 Beckerman, M. (2021, February 24). TikTok’s H2 2020 transparency report. TikTok. https://newsroom.tiktok.com/en-us/tiktoks-h-2-2020-transparency-report
51 U.S. Department of Health and Human Services. (2021). We Can Do This COVID-19 public education campaign. https://wecandothis.hhs.gov/about
52 Larson, H.J. (2020). A call to arms: Helping family, friends and communities navigate the COVID-19 infodemic. Nature Reviews Immunology, 20, 449–450. 10.1038/s41577-020-0380-8
53 Southwell, B., Wood, J., & Navar, A.M. (2020). Roles for health care professionals in addressing patient-held misinformation beyond fact correction. American Journal of Public Health, 110(S3), S288–S289. 10.2105/AJPH.2020.305729 33001723
54 Chen, X., Sin, S.C., Theng, Y-L., & Lee, C.S. (2016). Deterring the spread of misinformation on social network sites: A social cognitive theory-guided intervention. Proceedings of the Association for Information Science and Technology. 10.1002/pra2.2015.145052010095
55 Bode, L., & Vraga, E. (2021). Correction experiences on social media during COVID-19. Social Media & Society, 7(2). 10.1177/20563051211008829
56 Vanderpool, R.C., Gaysynsky, A., & Chou, W.S. (2020). Using a global pandemic as a teachable moment to promote vaccine literacy and build resilience to misinformation. American Journal of Public Health, 110, S284–S285. 10.2105/AJPH.2020.305906 33001735
57 Basol, M., Roozenbeek, J., Berriche, M., Uenal, F., McClanahan, W.P., & van der Linden, S. (2021). Towards psychological herd immunity: Cross-cultural evidence for two prebunking interventions against COVID-19 misinformation. Big Data & Society, 8(1). 10.1177/20539517211013868
58 Diethelm, P. & McKee, M. (2009). Denialism: what is it and how should scientists respond? European Journal of Public Health, 19(1), 2–4. 10.1093/eurpub/ckn139 19158101
59 Brenan, M. (2018, December 20). Nurses again outpace other professions for honesty, ethics. Gallup. https://news.gallup.com/poll/245597/nurses-again-outpace-professions-honesty-ethics.aspx/
60 First Draft. (2021, February). The building blocks of reporting and discussing Covid-19 vaccines. https://firstdraftnews.org/wp-content/uploads/2021/02/FD0102_Snapshot-3.pdf
61 O’Connor, C., & Ayad, M. (2021, April). MENA monitor: Arabic COVID-19 vaccine misinformation online. Institute for Strategic Dialogue (ISD). https://www.isdglobal.org/wp-content/uploads/2021/04/MENA-Covid-Vaccine-Misinformation-Monitor-1.pdf
62 Masterson, M., Zaheer, A., Small, C., Cable, J., John, J. (2021, May 4). Rumor control: A framework for countering vaccine misinformation. Virality Project Policy Analysis. https://www.viralityproject.org/policy-analysis/rumor-control