# References

1 Ritchey MD, Gillespie C, Wozniak G, . Potential need for expanded pharmacologic treatment and lifestyle modification services under the 2017 ACC/AHA Hypertension Guideline. J Clin Hypertens (Greenwich). 2018;20(10):1377–1391.30194806
2 Pahigiannis K, Thompson-Paul AM, Barfield W, . Progress toward improved cardiovascular health in the United States. Circulation. 2019;139(16):1957–1973.30986104
3 Wall HK, Ritchey MD, Gillespie C, . Vital Signs: prevalence of key cardiovascular disease risk factors for Million Hearts 2022 – United States, 2011–2016. MMWR Morb Mortal Wkly Rep. 2018;67(35):983–991.30188885
4 Fryar CD, Ostchega Y, Hales CM, Zhang G, Kruszon-Moran D. Hypertension prevalence and control among adults: United States, 2015–2016. NCHS data brief. 2017(289):1–8.
5 Foti K, Auerbach J, Magnan S. Improving hypertension control population-wide in Minnesota. J Public Health Manag Pract. 2018;24(5):432–439.28628583
6 Young A, Ritchey MD, George MG, Hannan J, Wright J. Characteristics of health care practices and systems that excel in hypertension control. Prev Chronic Dis. 2018;15:E73. Accessed June 7, 2020. doi: 10.5888/pcd15.170497.29885674
7 Ritchey MD, Hannan J, Wall HK, George MG, Sperling LS. Notes from the field: characteristics of Million Hearts Hypertension Control Champions, 2012–2019. MMWR Morb Mortal Wkly Rep. 2020;69:196–197.32078589
8 Whelton PK, Carey RM, Aronow WS, . 2017 ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/NMA/PCNA Guideline for the Prevention, Detection, Evaluation, and Management of High Blood Pressure in Adults: Executive Summary: A Report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Hypertension. 2018;71(6):1269–1324.29133354
9 Jackson SL, Zhang Z, Wiltz JL, . Hypertension among youths — United States, 2001–2016. MMWR Morb Mortal Wkly Rep. 2018;67:758–762.30001558
10 White PH, Cooley WC. Supporting the health care transition from adolescence to adulthood in the medical home. 2018;142(5):e20182587.
11 Juonala M, Magnussen CG, Berenson GS, . Childhood adiposity, adult adiposity, and cardiovascular risk factors. N Engl J Med. 2011;365(20):1876–1885.22087679
12 Million Hearts. Hypertension Control Champions website. 2020; https://millionhearts.hhs.gov/partners-progress/champions/index.html. Accessed January 27, 2020.
13 American Health Association. Target: BP. Recognition Program website. 2020; https://targetbp.org/recognition-program/. Accessed January 27, 2020.
14 Jaffe MG, Young JD. The Kaiser Permanente Northern California story: improving hypertension control from 44% to 90% in 13 Years (2000 to 2013). J Clin Hypertens (Greenwich). 2016;18(4):260–261.26939059
15 Shaw KM, Handler J, Wall HK, Kanter MH. Improving blood pressure control in a large multiethnic California population through changes in health care delivery, 2004–2012. Prev Chronic Dis. 2014;11:E191. Accessed Oct 30. doi: 10.5888/pcd11.140173.25357259
16 Fletcher RD, Amdur RL, Kolodner R, . Blood pressure control among US veterans: a large multiyear analysis of blood pressure data from the Veterans Administration health data repository. Circulation. 2012;125(20):2462–2468.22515976
17 Egan BM, Sutherland SE, Rakotz M, . Improving hypertension control in primary care with the measure accurately, act rapidly, and partner with patients protocol. Hypertension (Dallas). 2018;72(6):1320–1327.
18 Pfoh ER, Martinez K, Vakharia N, Rothberg M. Impact of a system-wide quality improvement initiative on blood pressure control: a cohort analysis. BMJ Qual Saf. 2019.
19 Milani RV, Lavie CJ, Bober RM, Milani AR, Ventura HO. Improving hypertension control and patient engagement using digital tools. Am J Med. 2017;130(1):14–20.27591179
20 Shaikh U, Petray J, Wisner DH. Improving blood pressure screening and control at an academic health system. BMJ Open Qual. 2020;9(1):e000614. https://bmjopenquality.bmj.com/content/bmjqir/9/1/e000614.full.pdf. doi: 10.1136/bmjoq-2018-000614.
21 The Community Guide. Cardiovascular disease: reducing out-of-pocket costs for cardiovascular disease preventive services for patients with high blood pressure and high cholesterol website. 2012; https://www.thecommunityguide.org/findings/cardiovascular-disease-reducing-out-pocket-costs-cardiovascular-disease-preventive-services. Accessed January 30, 2020.
22 Egan BM, Li J, Small J, Nietert PJ, Sinopoli A. The growing gap in hypertension control between insured and uninsured adults: National Health and Nutrition Examination Survey 1988 to 2010. Hypertension. 2014;64(5):997–1004.25185135
23 Fang J, Zhao G, Wang G, Ayala C, Loustalot F. Insurance status among adults with hypertension-the impact of underinsurance. J Am Heart Assoc. 2016;5(12).
24 Magnani JW, Mujahid MS, Aronow HD, . Health literacy and cardiovascular disease: fundamental relevance to primary and secondary prevention: a scientific statement from the American Heart Association. Circulation. 2018;138(2):e48–e74. Accessed Jul 10. doi: 10.1161/cir.0000000000000579.29866648
25 Ogedegbe G. Barriers to optimal hypertension control. J Clin Hypertens (Greenwich). 2008;10(8):644–646.18772648
26 Jackson SL, Park S, Loustalot F, . Characteristics, behaviors, and barriers among adults recommended for lifestyle modification by the 2017 ACC/AHA hypertension guideline (poster). Academy Health Annual Research Meeting; June 2019, 2020; Washington, DC.
27 Institute of Medicine (US) Committee on Public Health Priorities to Reduce and Control Hypertension. A Population-Based Policy and Systems Change Approach to Prevent and Control Hypertension. Washington (DC): National Academies Press (US); 2010.
28 Wright JS, Wall HK, Ritchey MD. Million Hearts 2022: small steps are needed for cardiovascular disease prevention. JAMA. 2018;320(18):1857–1858.30193304
29 Bauer UE, Briss PA, Goodman RA, Bowman BA. Prevention of chronic disease in the 21st century: elimination of the leading preventable causes of premature death and disability in the USA. Lancet. 2014;384(9937):45–52.24996589
30 Khatib R, Schwalm JD, Yusuf S, . Patient and healthcare provider barriers to hypertension awareness, treatment and follow up: a systematic review and meta-analysis of qualitative and quantitative studies. PLoS One. 2014;9(1):e84238. doi: 10.1371/journal.pone.0084238.24454721
31 Stevens A, Courtney-Long E, Gillespie C, Armour BS. Hypertension among US adults by disability status and type, National Health and Nutrition Examination Survey, 2001–2010. Prev Chronic Dis. 2014;11:E139. 10.5888/pcd11.140162. doi: 10.5888/pcd11.140162.25121351
32 Smith M, Hosking J, Woodward A, . Systematic literature review of built environment effects on physical activity and active transport - an update and new findings on health equity. Int J Behav Nutr Phys Act. 2017;14(1):158.29145884
33 Bennett GG, Mcneill LH, Wolin KY, . Safe to walk? Neighborhood safety and physical activity among public housing residents. PLoS Med. 2007;4(10):1599–1607.17958465
34 Foster S, Knuiman M, Hooper P, Christian H, Giles-Corti B. Do changes in residents’ fear of crime impact their walking? Longitudinal results from RESIDE. Prev Med. 2014;62:161–166.24552845
35 Mcdonald NC. The effect of objectively measured crime on walking in minority adults. Am J Health Promot. 2008;22(6):433–436.18677884
36 Rozario SS, Masho SW. The associations between mental health status, hypertension, and hospital inpatient visits in women in the United States. Am J Hypertens. 2018;31(7):804–810.29897396
37 Moise N, Davidson KW, Chaplin W, Shea S, Kronish I. Depression and clinical inertia in patients with uncontrolled hypertension. JAMA Intern Med. 2014;174(5):818–819.24615061
38 Bairey Merz CN, Andersen H, Sprague E, . Knowledge, attitudes, and beliefs regarding cardiovascular disease in women: The Women’s Heart Alliance. J Am Coll Cardiol. 2017;70(2):123–132.28648386
39 Saha S, Freeman M, Toure J, . Racial and ethnic disparities in the VA health care system: a systematic review. J Gen Intern Med. 2008;23(5):654–671.18301951
40 Miller WR, Lasiter S, Bartlett Ellis R, Buelow JM. Chronic disease self-management: a hybrid concept analysis. Nurs Outlook. 2015;63(2):154–161.25241136
41 Whitehead M, Dahlgreen G. Levelling up (part 1): a discussion paper on concepts and principles for tackling social inequalities in health. Liverpool, UK 2006.
42 Centers for Disease Control and Prevention. Health equity website. 2020; https://www.cdc.gov/healthequity/index.html. Accessed June 4, 2020.
43 Centers for Disease Control and Prevention. Health equity website. National Center for Chronic Disease Prevention and Health Promotion (NCCDPHP) 2020; https://www.cdc.gov/chronicdisease/healthequity/index.htm. Accessed March 3, 2020.
44 Healthy People 2010. Secretary’s advisory committee on health promotion and disease prevention objectives for 2010 website. https://www.healthypeople.gov/2020/about/foundation-health-measures/Disparities. Accessed March 31, 2020.
45 Carter-Pokras O, Baquet C. What is a “health disparity”? Public Health Rep. 2002;117(5):426–434.12500958
46 Lackland DT. Racial differences in hypertension: implications for high blood pressure management. Am J Med Sci. 2014;348(2):135–138.24983758
47 Havranek EP, Mujahid MS, Barr DA, . Social determinants of risk and outcomes for cardiovascular disease: a scientific statement from the American Heart Association. Circulation. 2015;132(9):873–898.26240271
48 Rodriguez F, Ferdinand KC. Hypertension in minority populations: new guidelines and emerging concepts. Adv Chronic Kidney Dis. 2015;22(2):145–153.25704352
49 Thorpe RJ, Jr., Brandon DT, Laveist TA. Social context as an explanation for race disparities in hypertension: findings from the Exploring Health Disparities in Integrated Communities (EHDIC) Study. Soc Sci Med. 2008;67(10):1604–1611.18701200
50 Liu MY, Li N, Li WA, Khan H. Association between psychosocial stress and hypertension: a systematic review and meta-analysis. Neurol Res. 2017;39(6):573–580.28415916
51 Kershaw KN, Diez Roux AV, Burgard SA, . Metropolitan-level racial residential segregation and black-white disparities in hypertension. Am J Epidemiol. 2011;174(5):537–545.21697256
52 Morenoff JD, House JS, Hansen BB, . Understanding social disparities in hypertension prevalence, awareness, treatment, and control: the role of neighborhood context. Soc Sci Med. 2007;65(9):1853–1866.17640788
53 Cuevas AG, Williams DR, Albert MA. Psychosocial factors and hypertension: a review of the literature. Cardiol Clin. 2017;35(2):223–230.28411896
54 Krieger N, Sidney S. Racial discrimination and blood pressure: the CARDIA Study of young black and white adults. Am J Public Health. 1996;86(10):1370–1378.8876504
55 Brondolo E, Rieppi R, Kelly KP, Gerin W. Perceived racism and blood pressure: a review of the literature and conceptual and methodological critique. Ann Behav Med. 2003;25(1):55–65.12581937
56 Paulose-Ram R, Gu Q, Kit B. Characteristics of U.S. adults with hypertension who are unaware of their hypertension, 2011–2014. NCHS Data Brief. 2017(278):1–8.
57 Bauer UE. Community Health and Economic Prosperity: an initiative of the Office of the Surgeon General. Public Health Rep. 2019;134(5):472–476.31419208
58 Chow N, Fleming-Dutra K, Gierke R EA, Team. CC-R. Preliminary estimates of the prevalence of selected underlying health conditions among patients with Coronavirus Disease 2019 — United States, February 12–March 28, 2020. MMWR Morb Mortal Wkly Rep. 2020;69:382–386.32240123
59 Sperling LS. The future of cardiovascular prevention: unprecedented times. 2020;141(24):1946–1947.
60 Yang Q TX, Schieb L, . Vital Signs: recent trends in stroke death rates — United States, 2000 – 2015. MMWR Morb Mortal Wkly Rep. 2017;66:933–939.28880858
61 Older people projected to outnumber children for first time in U.S. history [news release]. 2018; https://www.census.gov/newsroom/press-releases/2018/cb18-41-population-projections.html. Accessed February 13, 2020.
62 Virani SS, Alonso A, Benjamin EJ, . Heart disease and stroke statistics-2020 update: a report from the American Heart Association. Circulation. 2020;141(9):e139–e596. Accessed Mar 3. doi: 10.1161/cir.0000000000000757.31992061
63 Ritchey MD, Wall HK, George MG, Wright JS. US trends in premature heart disease mortality over the past 50 years: Where do we go from here? Trends Cardiovasc Med. 2020;30(6):364–374.31607635
64 Muntner P, Hardy ST, Fine LJ, . Trends in blood pressure control among US adults with hypertension, 1999–2000 to 2017–2018. JAMA. 2020. doi: 10.1001/jama.2020.14545.
65 Million Hearts. Estimated hypertension prevalence, treatment, and control among U.S. adults website. 2020; https://millionhearts.hhs.gov/data-reports/hypertension-prevalence.html. Accessed March 6, 2020.
66 Zhou B, Danaei G, Stevens GA, . Long-term and recent trends in hypertension awareness, treatment, and control in 12 high-income countries: an analysis of 123 nationally representative surveys. The Lancet. 2019;394(10199):639–651.
67 Cooper T. Hypertension; the silent killer. J Pract Nurs. 1973;23(11):23–25.4490556
68 Arboix A. Hypertension and the acute phase of intracerebral haemorrhage: more evidence of the ‘silent killer’. Eur J Neurol. 2018;25(8):1007–1008.29603497
69 Rapport RS. Hypertension. Silent killer. N J Med. 1999;96(3):41–43.
70 Ahuja R, Ayala C, Tong X, Wall HK, Fang J. Public awareness of health-related risks from uncontrolled hypertension. Prev Chronic Dis. 2018;15:E40. Accessed Apr 5. doi: 10.5888/pcd15.170362.29625630
71 CDC WONDER Online Database website. About Underlying Cause of Death 1999–2017. Centers for Disease Control and Prevention; 2019. http://wonder.cdc.gov/ucd-icd10.html. Accessed February 28 2020.
72 Yano Y, Reis JP, Colangelo LA, . Association of blood pressure classification in young adults using the 2017 American College of Cardiology/American Heart Association blood pressure guideline with cardiovascular events later in life. JAMA. 2018;320(17):1774–1782.30398601
73 Beevers G, Lip GY, O’Brien E. ABC of hypertension: the pathophysiology of hypertension. BMJ. 2001;322(7291):912–916.11302910
74 Kokubo Y, Matsumoto C. Hypertension is a risk factor for several types of heart disease: review of prospective studies. Adv Exp Med Biol. 2017;956:419–426.27815926
75 Nwabuo CC, Vasan RS. Pathophysiology of hypertensive heart disease: beyond left ventricular hypertrophy. Curr Hypertens Rep. 2020;22(2):11.32016791
76 Sander D, Kukla C, Klingelhöfer J, Winbeck K, Conrad B. Relationship Between Circadian Blood Pressure Patterns and Progression of Early Carotid Atherosclerosis. Circulation. 2000;102(13):1536–1541.11004145
77 Xu JQ, Murphy SL, Kochanek KD, Arias E. Mortality in the United States, 2018. NCHS Data Brief 2020. Accessed February 12, 2020.
78 Van Dyke M, Greer S, Odom E, Al. E. Heart disease death rates among blacks and whites aged ≥35 Years — United States, 1968–2015. MMWR Surveill Summ. 2018;67(5):1–11.
79 Casper M, Kramer Michael R, Quick H, . Changes in the geographic patterns of heart disease mortality in the United States. Circulation. 2016;133(12):1171–1180.27002081
80 CDC WONDER Database. About Underlying Cause of Death, 1999–2018. Centers for Disease Control and Prevention, U.S. Dept of Health and Human Services; 2020. http://wonder.cdc.gov/ucd-icd10.html. Accessed March 30, 2020.
81 Hardie K, Hankey GJ, Jamrozik K, Broadhurst RJ, Anderson C. Ten-year risk of first recurrent stroke and disability after first-ever stroke in the Perth Community Stroke Study. Stroke. 2004;35(3):731–735.14764929
82 O’donnell MJ, Xavier D, Liu L, . Risk factors for ischaemic and intracerebral haemorrhagic stroke in 22 countries (the INTERSTROKE study): a case-control study. Lancet. 2010;376(9735):112–123.20561675
83 Hypertension and Stroke: pathophysiology and management. Humana Press; 2011.
84 Moskowitz MA, Lo EH, Iadecola C. The science of stroke: mechanisms in search of treatments. Neuron. 2010;67(2):181–198.20670828
85 Rothwell PM, Howard SC, Dolan E, . Prognostic significance of visit-to-visit variability, maximum systolic blood pressure, and episodic hypertension. Lancet. 2010;375(9718):895–905.20226988
86 Rapsomaniki E, Timmis A, George J, . Blood pressure and incidence of twelve cardiovascular diseases: lifetime risks, healthy life-years lost, and age-specific associations in 1·25 million people. Lancet. 2014;383(9932):1899–1911.24881994
87 Turnbull F, Neal B, Ninomiya T, . Effects of different regimens to lower blood pressure on major cardiovascular events in older and younger adults: meta-analysis of randomised trials. BMJ. 2008;336(7653):1121–1123.18480116
88 Thompson AM, Hu T, Eshelbrenner CL, . Antihypertensive treatment and secondary prevention of cardiovascular disease events among persons without hypertension: a meta-analysis. JAMA. 2011;305(9):913–922.21364140
89 Group. PC. Randomised trial of a perindopril-based blood-pressure-lowering regimen among 6,105 individuals with previous stroke or transient ischaemic attack. Lancet. 2001;358(9287):1033–1041.11589932
90 Madsen TE, Khoury JC, Leppert M, . Temporal trends in stroke incidence over time by sex and age in the GCNKSS. Stroke. 2020;51(4):1070–1076.32078459
91 Howard G, Cushman M, Howard VJ, . Risk factors for intracerebral hemorrhage: the REasons for Geographic and Racial Differences in Stroke (REGARDS) study. Stroke. 2013;44(5):1282–1287.23532012
92 Kleindorfer DO, Khoury J, Moomaw CJ, . Stroke incidence is decreasing in whites but not in blacks: a population-based estimate of temporal trends in stroke incidence from the Greater Cincinnati/Northern Kentucky Stroke Study. Stroke. 2010;41(7):1326–1331.20489177
93 Howard G, Howard VJ. Twenty years of progress toward understanding the stroke belt. Stroke. 2020;51(3):742–750.32078485
94 Gardener H, Sacco RL, Rundek T, . Race and ethnic disparities in stroke incidence in the Northern Manhattan Study. Stroke. 2020;51(4):1064–1069.32078475
95 Morgenstern LB, Smith MA, Lisabeth LD, . Excess stroke in Mexican Americans compared with non-Hispanic Whites: the Brain Attack Surveillance in Corpus Christi Project. Am J Epidemiol. 2004;160(4):376–383.15286023
96 Howard G, Lackland DT, Kleindorfer DO, . Racial differences in the impact of elevated systolic blood pressure on stroke risk. JAMA Intern Med. 2013;173(1):46–51.23229778
97 Gąsecki D, Kwarciany M, Nyka W, Narkiewicz K. Hypertension, brain damage and cognitive decline. Curr Hypertens Rep. 2013;15(6):547–558.24146223
98 Ding J, Davis-Plourde KL, Sedaghat S, . Antihypertensive medications and risk for incident dementia and Alzheimer’s disease: a meta-analysis of individual participant data from prospective cohort studies. Lancet Neurol. 2020;19(1):61–70.31706889
99 Gottesman RF, Albert MS, Alonso A, . Associations between midlife vascular risk factors and 25-year incident dementia in the Atherosclerosis Risk in Communities (ARIC) cohort. JAMA Neurol. 2017;74(10):1246–1254.28783817
100 Yano Y, Griswold M, Wang W, . Long-term blood pressure level and variability from midlife to later life and subsequent cognitive change: The ARIC Neurocognitive Study. J Am Heart Assoc. 2018;7(15):e009578. Accessed Aug 7. doi: 10.1161/jaha.118.009578.30371241
101 Iadecola C, Yaffe K, Biller J, . Impact of hypertension on cognitive function: a scientific statement from the American Heart Association. Hypertension. 2016;68(6):e67–e94. doi: 10.1161/hyp.0000000000000053.27977393
102 Norton S, Matthews FE, Barnes DE, Yaffe K, Brayne C. Potential for primary prevention of Alzheimer’s disease: an analysis of population-based data. Lancet Neurol. 2014;13(8):788–794.25030513
103 Yoo JE, Shin DW, Han K, . Blood pressure variability and the risk of dementia: a nationwide cohort study. Hypertension. 2020;75(4):982–990.32148122
104 Caunca MR, Simonetto M, Cheung YK, . Diastolic blood pressure is associated with regional white matter lesion load. Stroke. 2020;51(2):372–378.31910743
105 Williamson JD, Pajewski NM, Auchus AP, . Effect of intensive vs standard blood pressure control on probable dementia: a randomized clinical trial. JAMA. 2019;321(6):553–561.30688979
106 Group. TSMIFTSR. Association of intensive vs standard blood pressure control with cerebral white matter lesions. JAMA. 2019;322(6):524–534.31408137
107 National Academies of Sciences EaMHaMDBOHSPCOPDaCI. Preventing Cognitive Decline and Dementia: A Way Forward. Washington (DC): National Academies Press (US); 2017.
108 Livingston G, Sommerlad A, Orgeta V, . Dementia prevention, intervention, and care. Lancet. 2017;390(10113):2673–2734.28735855
109 Umesawa M, Kobashi G. Epidemiology of hypertensive disorders in pregnancy: prevalence, risk factors, predictors and prognosis. Hypertens Res. 2017;40(3):213–220.27682655
110 Petersen EE, Davis NL, Goodman DEA. Vital Signs: pregnancy-related deaths, United States, 2011–2015, and strategies for prevention, 13 States, 2013–2017. MMWR Morb Mortal Wkly Rep. 2019;68(18):423–429.31071074
111 Bramham K, Parnell B, Nelson-Piercy C, . Chronic hypertension and pregnancy outcomes: systematic review and meta-analysis. BMJ. 2014;348:g2301.24735917
112 The American College of Obstetricians and Gynecologists. Gestational hypertension and preeclampsia. Practice Bulletin. 2020; https://www.acog.org/clinical/clinical-guidance/practice-bulletin/articles/2020/06/gestational-hypertension-and-preeclampsia. Accessed June 5, 2020.
113 Centers for Disease Control and Prevention. Data on selected pregnancy complications in the United States website. 2019; https://www.cdc.gov/reproductivehealth/maternalinfanthealth/pregnancy-complications-data.htm#hyper. Accessed February 28, 2020.
114 Hirshberg A, Srinivas SK. Epidemiology of maternal morbidity and mortality. Semin Perinatol. 2017;41(6): 332–337.28823579
115 Petersen EE, Davis NL, Goodman DEA. Racial/ethnic disparities in pregnancy-related deaths — United States, 2007–2016. MMWR Morb Mortal Wkly Rep. 2019;68:762–765. https://www.cdc.gov/mmwr/volumes/68/wr/mm6835a3.htm.31487273
116 Lo JO, Mission JF, Caughey AB. Hypertensive disease of pregnancy and maternal mortality. Curr Opin Obstet Gynecol. 2013;25(2):124–132.23403779
117 Wallis AB, Saftlas AF, Hsia J, Atrash HK. Secular trends in the rates of preeclampsia, eclampsia, and gestational hypertension, United States, 1987–2004. Am J Hypertens. 2008;21(5):521–526.18437143
118 Kuklina EV, Ayala C, Callaghan WM. Hypertensive disorders and severe obstetric morbidity in the United States. Obstet Gynecol. 2009;113(6):1299–1306.19461426
119 ACOG Practice Bulletin no. 202: gestational hypertension and preeclampsia. Obstet Gynecol. 2019;133(1): e1–e25. Accessed Jan. doi: 10.1097/aog.0000000000003018.
120 ACOG committee opinion no. 736 summary: optimizing postpartum care. Obstet Gynecol. 2018;131(5):949–951.29683906
121 Stuart JJ, Tanz LJ, Missmer SA, . Hypertensive disorders of pregnancy and maternal cardiovascular disease risk factor development: an observational cohort study. Ann Intern Med. 2018;169(4):224–232.29971437
122 Riise HKR, Sulo G, Tell GS, . Hypertensive pregnancy disorders increase the risk of maternal cardiovascular disease after adjustment for cardiovascular risk factors. Int J Cardiol. 2019;282:81–87.30773269
123 Irizarry OC, Levine LD, Lewey J, . Comparison of clinical characteristics and outcomes of peripartum cardiomyopathy between African American and non–African American women. JAMA Cardiology. 2017;2(11):1256–1260.29049825
124 Horowitz B, Miskulin D, Zager P. Epidemiology of hypertension in CKD. Adv Chronic Kidney Dis. 2015;22(2):88–95.25704344
125 Qian Q. Salt, water and nephron: mechanisms of action and link to hypertension and chronic kidney disease. Nephrology (Carlton). 2018;23 Suppl 4:44–49.30298656
126 Cha RH, Lee H, Lee JP, Kim YS, Kim SG. The influence of blood pressure patterns on renal outcomes in patients with chronic kidney disease: The long-term follow up result of the APrODiTe-2 study. Medicine (Baltimore). 2020;99(8):e19209. Accessed Feb. doi: 10.1097/md.0000000000019209.32080110
127 Crews DC, Plantinga LC, Miller ER, . Prevalence of chronic kidney disease in persons with undiagnosed or prehypertension in the United States. Hypertension. 2010;55(5):1102–1109.20308607
128 Prevention. CFDCA. Chronic Kidney Disease in the United States, 2019 website. 2019; https://www.cdc.gov/kidneydisease/publications-resources/2019-national-facts.html?utm_source=miragenews&utm_medium=miragenews&utm_campaign=news. Accessed March 13, 2020.
129 United States Renal Data System. 2018 USRDS Annual Data Report: Volume 1: CKD in the United States. 2018. https://www.usrds.org/media/2282/2018_volume_1_ckd_in_the_us.pdf.
130 Mensah GA, Croft JB, Giles WH. The heart, kidney, and brain as target organs in hypertension. Cardiol Clin. 2002;20(2):225–247.12119798
131 Bidani AK, Griffin KA. Pathophysiology of hypertensive renal damage: implications for therapy. Hypertension. 2004;44(5):595–601.15452024
132 Parikh NI, Hwang SJ, Larson MG, . Cardiovascular disease risk factors in chronic kidney disease: overall burden and rates of treatment and control. Arch Intern Med. 2006;166(17):1884–1891.17000946
133 Ricardo AC, Yang W, Sha D, . Sex-related disparities in CKD progression. J Am Soc Nephrol. 2019;30(1): 137–146.30510134
134 United States Renal Data System. 2019 ADR Reference Tables website. 2019; https://www.usrds.org/annual-data-report/.
135 National Institutes of Diabetes and Digestive and Kidney Diseases. Race, ethnicity, & kidney disease website. 2014; https://www.niddk.nih.gov/health-information/kidney-disease/race-ethnicity. Accessed February 28, 2020.
136 Saran R, Robinson B, Abbott KC, . US Renal Data System 2016 annual data report: epidemiology of kidney disease in the United States. Am J Kidney Dis. 2017;69(3 Suppl 1):a7–a8.28236831
137 Wang G, Zhou X, Zhuo X, Zhang P. Annual total medical expenditures associated with hypertension by diabetes status in U.S. Adults. Am J Prev Med. 2017;53(6s2):s182–s189. Accessed Dec. doi: 10.1016/j.amepre.2017.07.018.29153119
138 Kirkland EB, Heincelman M, Bishu KG, . Trends in healthcare expenditures among US adults with hypertension: national estimates, 2003–2014. J Am Heart Assoc. 2018;7(11).
139 Ritchey M, Tsipas S, Loustalot F, Wozniak G. Use of pharmacy sales data to assess changes in prescription- and payment-related factors that promote adherence to medications commonly used to treat hypertension, 2009 and 2014. PLoS One. 2016;11(7):e0159366. 10.1371/journal.pone.0159366. doi: 10.1371/journal.pone.0159366.27428008
140 Rti International. Projections of cardiovascular disease prevalence and costs: 2015–2035. Research Triangle Park, NC: RTI International;2016. RTI project number 021480.003.001.001.
141 Asay GRB, Roy K, Lang JE, Payne RL, Howard DH. Absenteeism and employer costs associated with chronic diseases and health risk factors in the US workforce. Prev Chronic Dis. 2016;13.
142 Moran AE, Odden MC, Thanataveerat A, . Cost-effectiveness of hypertension therapy according to 2014 guidelines. N Engl J Med. 2015;372(5):447–455.25629742
143 Redmond N, Baer HJ, Hicks LS. Health behaviors and racial disparity in blood pressure control in the national health and nutrition examination survey. Hypertension. 2011;57(3):383–389.21300667
144 Selby K, Michel M, Gildengorin G, . Disparities in hypertension control across and within three health systems participating in a data-sharing collaborative. J Am Board Fam Med. 2018;31(6):897–904.30413545
145 Ferdinand KC, Yadav K, Nasser SA, . Disparities in hypertension and cardiovascular disease in blacks: the critical role of medication adherence. J Clin Hypertens (Greenwich). 2017;19(10):1015–1024.28856834
146 Rose GA. The Strategy of Preventive Medicine. Oxford, England: Oxford University Press; 1992.
147 Healthy People 2020. Social determinants of health website. 2020; https://www.healthypeople.gov/2020/topics-objectives/topic/social-determinants-of-health. Accessed January 31, 2020.
148 Centers for Disease Control and Prevention. Division for Heart Disease and Stroke Prevention, Science Handbook. September 25, 2019.
149 Centers for Disease Control and Prevention. CDC Convened Hypertension Control Meeting: Sector Leader Panel: Opportunity Knocks for Hypertension Control. In. Atlanta, GA: Centers for Disease Control and Prevention; 2019.
150 Kendrick J, Nuccio E, Leiferman JA, Sauaia A. Primary care providers perceptions of racial/ethnic and socioeconomic disparities in hypertension control. Am J Hypertens. 2015;28(9):1091–1097.25631381
151 Victor RG, Lynch K, Li N, . A cluster-randomized trial of blood-pressure reduction in black barbershops. N Engl J Med. 2018;378(14):1291–1301.29527973
152 Victor RG, Blyler CA, Li N, . Sustainability of blood pressure reduction in black barbershops. Circulation. 2019;139(1):10–19.30592662
153 Kosoko-Lasaki O, Ekundayo OT, Smith J, . Urban minority community safety and its impact on physical activity: The Center for Promoting Health and Health Equity-Racial and Ethnic Approaches to Community Health (CPHHE-REACH) Initiative. J Natl Med Assoc. 2019;111(3):334–344.30711288
154 Mcclintock HF, Bogner HR. Incorporating patients’ social determinants of health into hypertension and depression care: a pilot randomized controlled trial. Community Ment Health J. 2017;53(6):703–710.28378301
155 Green LW, Ottoson JM, Garcia C, Hiatt RA. Diffusion theory and knowledge dissemination, utilization, and integration in public health. Annu Rev Public Health. 2009;30:151–174.19705558
156 Lobb R, Colditz GA. Implementation science and its application to population health. Annu Rev Public Health. 2013;34:235–251.23297655
157 World Health Organization. Commission on social determinants of health, 2005–2008 website. https://www.who.int/social_determinants/thecommission/en/. Accessed February 14, 2020.
158 Healthy People. Healthy People 2030 framework: what is the Healthy People 2030 framework? website. https://www.healthypeople.gov/2020/About-Healthy-People/Development-Healthy-People-2030/Framework. Accessed February 14, 2020.
159 Office of the Surgeon General. Surgeon General Priority: Community Health and Economic Prosperity website. 2020; https://www.hhs.gov/surgeongeneral/priorities/community-health-economic-security/index.html. Accessed February 4, 2020.
160 Jarbol DE, Larsen PV, Gyrd-Hansen D, . Determinants of preferences for lifestyle changes versus medication and beliefs in ability to maintain lifestyle changes. A population-based survey. Prev Med Rep. 2017;6:66–73.28271023
161 Stead M, Craigie AM, Macleod M, . Why are some people more successful at lifestyle change than others? Factors associated with successful weight loss in the BeWEL randomised controlled trial of adults at risk of colorectal cancer. Int J Behav Nutr Phys Act. 2015;12:87–87.26112014
162 Korhonen MJ, Pentti J, Hartikainen J, . Lifestyle changes in relation to initiation of antihypertensive and lipid lowering medication: a cohort study. J Am Heart Assoc. 2020;9(4):e014168. 10.1161/JAHA.119.014168. doi: doi:10.1161/JAHA.119.014168.32019405
163 Trilk J, Nelson L, Briggs A, Muscato D. Including lifestyle medicine in medical education: rationale for American College of Preventive Medicine/American Medical Association resolution 959. Am J Prev Med. 2019;56(5):e169–e175. doi: 10.1016/j.amepre.2018.10.034.31003604
164 Centers for Disease Control and Prevention. Health impact in 5 years website. https://www.cdc.gov/policy/hst/hi5/. Accessed November 19, 2019.
165 Frieden TR. A framework for public health action: the health impact pyramid. Am J Public Health. 2010;100(4): 590–595.20167880
166 Centers for Disease Control and Prevention. Sodium Reduction in Communities Program (SRCP) website. 2020; https://www.cdc.gov/dhdsp/programs/sodium_reduction.htm. Accessed March 13, 2020.
167 Hollis-Hansen K, Vermont L, Zafron ML, Seidman J, Leone L. The introduction of new food retail opportunities in lower-income communities and the impact on fruit and vegetable intake: a systematic review. Transl Behav Med. 2019;9(5):837–846.31570930
168 Block JP, Subramanian SV. Moving beyond “food deserts”: reorienting United States policies to reduce disparities in diet quality. PLoS Med. 2015;12(12):e1001914–e1001914. https://pubmed.ncbi.nlm.nih.gov/26645285. doi: 10.1371/journal.pmed.1001914.26645285
169 Pearson-Stuttard J, Bandosz P, Rehm CD, . Reducing US cardiovascular disease burden and disparities through national and targeted dietary policies: A modelling study. PLoS Med. 2017;14(6):e1002311. Accessed Jun. doi: 10.1371/journal.pmed.1002311.28586351
170 Lewallen TC, Hunt H, Potts-Datema W, Zaza S, Giles W. The Whole School, Whole Community, Whole Child model: a new approach for improving educational attainment and healthy development for students. J Sch Health. 2015;85(11):729–739.26440815
171 2018 Physical Activity Guidelines Advisory Committee. 2018 Physical Activity Guidelines Advisory Committee Scientific Report. Washington, DC: Department of Health and Human Services;2018.
172 Naci H, Salcher-Konrad M, Dias S, . How does exercise treatment compare with antihypertensive medications? A network meta-analysis of 391 randomised controlled trials assessing exercise and medication effects on systolic blood pressure. Br J Sports Med. 2019;53(14):859–869.30563873
173 Centers for Disease Control and Prevention. 2008 Physical Activity Guidelines for Americans: trends in meeting the 2008 Physical Activity Guidelines, 2008—2018 website. 2018; https://www.cdc.gov/physicalactivity/downloads/trends-in-the-prevalence-of-physical-activity-508.pdf. Accessed February 13, 2020.
174 Katzmarzyk PT, Powell KE, Jakicic JM, . Sedentary behavior and health: update from the 2018 Physical Activity Guidelines Advisory Committee. Med Sci Sports Exerc. 2019;51(6):1227–1241.31095080
175 Khan KM, Thompson AM, Blair SN, . Sport and exercise as contributors to the health of nations. Lancet. 2012;380(9836):59–64.22770457
176 U.S. Department of Health and Human Services. Step It Up! The Surgeon General’s Call to Action to Promote Walking and Walkable Communities. Washington, D.C.: U.S. Dept of Health and Human Services; 2015.
177 National Center for Safe Routes to School. Safe Routes website. http://www.saferoutesinfo.org/. Accessed April 6, 2020.
178 National Center for Safe Routes to School. Trends in Walking and Bicycling to School from 2007 to 2012 Chapel Hill, NC: University of North Carolina Highway Safety Research Center; 2013.
179 National Center for Safe Routes to School and Pedestrian and Bicycle Information Center. The Walking School Bus: Combining Safety, Fun and the Walk to School. Chapel Hill, NC: University of North Carolina Highway Safety Research Center; 2010.
180 Pelletier KR. A review and analysis of the clinical and cost-effectiveness studies of comprehensive health promotion and disease management programs at the worksite: update VIII 2008 to 2010. J Occup Environ Med. 2011;53(11):1310–1331.22015548
181 Pahor M, Guralnik JM, Ambrosius WT, . Effect of structured physical activity on prevention of major mobility disability in older adults: the LIFE study randomized clinical trial. JAMA. 2014;311(23):2387–2396.24866862
182 The Community Guide. Physical activity: social support interventions in community settings website. 2001; https://www.thecommunityguide.org/findings/physical-activity-social-support-interventions-community-settings. Accessed March 16, 2020.
183 Pollack KM, Bailey MM, Gielen AC, . Building safety into active living initiatives. Prev Med. 2014;69 Suppl 1:S102–105. Accessed Dec. doi: 10.1016/j.ypmed.2014.08.010.25117526
184 Sallis JF, Floyd MF, Rodríguez DA, Saelens BE. Role of built environments in physical activity, obesity, and cardiovascular disease. Circulation. 2012;125(5):729–737.22311885
185 Casagrande SS, Whitt-Glover MC, Lancaster KJ, Odoms-Young AM, Gary TL. Built environment and health behaviors among African Americans: a systematic review. Am J Prev Med. 2009;36(2):174–181.19135908
186 Foster S, Giles-Corti B. The built environment, neighborhood crime and constrained physical activity: an exploration of inconsistent findings. Prev Med. 2008;47(3):241–251.18499242
187 Gebauer S, Schootman M, Xian H, Xaverius P. Neighborhood built and social environment and meeting physical activity recommendations among mid to older adults with joint pain. Prev Med Rep. 2020;18:101063.32140385
188 U.S. Department of Transportation. Complete streets website. 2015; https://www.transportation.gov/mission/health/complete-streets. Accessed March 4, 2020.
189 The Community Guide. Physical activity: built environment approaches combining transportation system interventions with land use and environmental design website. https://www.thecommunityguide.org/findings/physical-activity-built-environment-approaches. Accessed March 16, 2020.
190 Centers for Disease Control and Prevention. About active people, healthy nation website. 2020; https://www.cdc.gov/physicalactivity/activepeoplehealthynation/about-active-people-healthy-nation.html. Accessed March 4, 2020.
191 Million Hearts. Million Hearts website. 2020; https://millionhearts.hhs.gov/. Accessed March 4, 2020.
192 The Community Guide. Physical activity: interventions to increase active travel to school website. 2019; https://www.thecommunityguide.org/content/tffrs-physical-activity-interventions-increase-active-travel-school. Accessed March 16, 2020.
193 Anand SS, Hawkes C, De Souza RJ, . Food consumption and its impact on cardiovascular disease: importance of solutions focused on the globalized food system: a report from the workshop convened by the World Heart Federation. J Am Coll Cardiol. 2015;66(14):1590–1614.26429085
194 Lim SS, Vos T, Flaxman AD, . A comparative risk assessment of burden of disease and injury attributable to 67 risk factors and risk factor clusters in 21 regions, 1990–2010: a systematic analysis for the Global Burden of Disease Study 2010. Lancet. 2012;380(9859):2224–2260.23245609
195 U.S. Department of Health and Human Services and U.S. Department of Agriculture. 2015–2020 Dietary Guidelines for Americans. 8th Edition. Washington, DC: U.S. Dept of Health and Human Services and U.S. Dept of Agriculture; 2015.
196 Chiavaroli L, Viguiliouk E, Nishi SK, . DASH dietary pattern and cardiometabolic outcomes: an umbrella review of systematic reviews and meta-analyses. Nutrients. 2019;11(2).
197 Richardson SI, Freedman BI, Ellison DH, Rodriguez CJ. Salt sensitivity: a review with a focus on non-Hispanic blacks and Hispanics. J Am Soc Hypertens. 2013;7(2):170–179.23428408
198 Zilbermint M, Hannah-Shmouni F, Stratakis CA. Genetics of hypertension in African Americans and others of African descent. Int J Mol Sci. 2019;20(5).
199 Quader ZS, Zhao L, Gillespie C, Al. E. Sodium intake among persons aged ≥2 Years — United States, 2013–2014 MMWR Morb Mortal Wkly Rep. 2017;66:324–238. doi: 10.15585/mmwr.mm6612a3.28358799
200 New York City Health. National salt and sugar reduction initiative website. https://www1.nyc.gov/site/doh/health/health-topics/national-salt-sugar-reduction-initiative.page. Accessed April 2, 2020.
201 Centers for Disease Control and Prevention. Healthy Food Service Guidelines website. https://www.cdc.gov/obesity/strategies/food-serv-guide.html. Accessed August 5, 2020.
202 Felipe RA, Plescia M, Peterman E, . A public health framework to improve population health through health care and community clinical linkages: the ASTHO/CDC Heart Disease and Stroke Prevention Learning Collaborative. Prev Chronic Dis. 2019;16:E124. Accessed Sep 12. doi: 10.5888/pcd16.190065.31517600
203 Omura JD, Watson KB, Loustalot F, Fulton JE, Carlson SA. Primary care providers’ awareness of physical activity-related intensive behavioral counseling services for cardiovascular disease prevention. Am J Health Promot. 2019;33(2):208–216.29962209
204 U.S. Preventive Services Task Force. Healthful diet and physical activity for cardiovascular disease prevention in adults with cardiovascular risk factors: behavioral counseling website. 2014; https://www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/healthy-diet-and-physical-activity-counseling-adults-with-high-risk-of-cvd. Accessed March 13, 2020.
205 Lefevre ML. Behavioral counseling to promote a healthful diet and physical activity for cardiovascular disease prevention in adults with cardiovascular risk factors: U.S. Preventive Services Task Force Recommendation Statement. Ann Intern Med. 2014;161(8):587–593.25155419
206 Centers for Disease Control and Prevention. Developing community-clinical linkages for WISEWOMAN Ppograms website. 2014; https://www.cdc.gov/wisewoman/docs/ww_brief_developing_community-clinical_linkages.pdf. Accessed March 13, 2020.
207 Centers for Disease Control and Prevention. What could be addressed in an evidence-informed state workplace health promotion law? Atlanta, GA: Division for Heart Disease and Stroke Prevention; 2017.
208 Joshi K, Smith S, Bolen SD, . Implementing a produce prescription program for hypertensive patients in safety net clinics. Health Promot Pract. 2019;20(1):94–104.29380633
209 Phillips LS, Branch WT, Cook CB, . Clinical inertia. Ann Intern Med. 2001;135(9):825–834.11694107
210 Allen JD, Curtiss FR, Fairman KA. Nonadherence, clinical inertia, or therapeutic inertia? J Manag Care Pharm. 2009;15(8):690–695.19803559
211 Milman T, Joundi RA, Alotaibi NM, Saposnik G. Clinical inertia in the pharmacological management of hypertension: a systematic review and meta-analysis. Medicine (Baltimore). 2018;97(25):e11121. Accessed Jun. doi: 10.1097/md.0000000000011121.29924011
212 O’connor PJ, Sperl-Hillen JaM, Johnson PE, Rush WA, Biltz G. Advances in patient safety clinical inertia and outpatient medical errors. In: Henriksen K, Battles JB, Marks ES, Lewin DI, eds. Advances in patient safety: from research to implementation (volume 2: concepts and methodology). Rockville (MD): Agency for Healthcare Research and Quality (US); 2005.
213 Johnson HM, Thorpe CT, Bartels CM, . Undiagnosed hypertension among young adults with regular primary care use. J Hypertens. 2014;32(1):65–74.24126711
214 Thomas SJ, Booth JN, 3rd, Dai C, . Cumulative incidence of hypertension by 55 years of age in Blacks and Whites: The CARDIA Study. J Am Heart Assoc. 2018;7(14).
215 Bellows BK, Ruiz-Negron N, Bibbins-Domingo K, . Clinic-based strategies to reach United States Million Hearts 2022 blood pressure control goals. Circ Cardiovasc Qual Outcomes. 2019;12(6):e005624.31163981
216 Go AS, Bauman MA, Coleman King SM, . An effective approach to high blood pressure control: a science advisory from the American Heart Association, the American College of Cardiology, and the Centers for Disease Control and Prevention. J Am Coll Cardiol. 2014;63(12):1230–1238.24246165
217 Kelley JM, Kraft-Todd G, Schapira L, Kossowsky J, Riess H. The influence of the patient-clinician relationship on healthcare outcomes: a systematic review and meta-analysis of randomized controlled trials. PLoS One. 2014;9(4):e94207. doi: 10.1371/journal.pone.0094207.24718585
218 Hoffmann TC, Montori VM, Del Mar C. The connection between evidence-based medicine and shared decision making. JAMA. 2014;312(13):1295–1296.25268434
219 L. Paget, P. Han, S. Nedza, . Patient-clinician communication: basic principles and expectations. NAM Perspectives Discussion Paper. 2011. doi: 10.31478/201106a.
220 Centers for Disease Control and Prevention. Hypertension control change package (2nd ed.). Atlanta, GA: Centers for Disease Control and Prevention; 2020.
221 Shaw RJ, Mcduffie JR, Hendrix CC, . Effects of nurse-managed protocols in the outpatient management of adults with chronic conditions: a systematic review and meta-analysis. Ann Intern Med. 2014;161(2):113–121.25023250
222 Kallioinen N, Hill A, Horswill MS, Ward HE, Watson MO. Sources of inaccuracy in the measurement of adult patients’ resting blood pressure in clinical settings: a systematic review. J Hypertens. 2017;35(3):421–441.27977471
223 Rakotz MK, Townsend RR, Yang J, . Medical students and measuring blood pressure: Results from the American Medical Association Blood Pressure Check Challenge. J Clin Hypertens (Greenwich). 2017;19(6):614–619.28452119
224 Muntner P, Shimbo D, Carey Robert M, . Measurement of blood pressure in humans: a scientific statement from the American Heart Association. Hypertension. 2019;73(5):e35–e66. doi: 10.1161/HYP.0000000000000087.30827125
225 Pickering TG, Hall JE, Appel LJ, . Recommendations for blood pressure measurement in humans and experimental animals: part 1: blood pressure measurement in humans: a statement for professionals from the Subcommittee of Professional and Public Education of the American Heart Association Council on High Blood Pressure Research. Circulation. 2005;111(5):697–716.15699287
226 Bartolome RE, Chen A, Handler J, Platt ST, Gould B. Population care management and team-based approach to reduce racial disparities among African Americans/Blacks with hypertension. Perm J. 2016;20(1):53–59.26824963
227 Mitchell P, Wynia M, Golden R, . Core principles & values of effective team-based health care. 2012.
228 American Academy of Family Physicians, American College of Physicians, American Osteopathic Association. Joint principles of the patient-centered medical home. Washington, D.C. 2007.
229 Proia KK, Thota AB, Njie GJ, . Team-based care and improved blood pressure control: a community guide systematic review. Am J Prev Med. 2014;47(1):86–99.24933494
230 Carter BL, Rogers M, Daly J, Zheng S, James PA. The potency of team-based care interventions for hypertension: a meta-analysis. Arch Intern Med. 2009;169(19):1748–1755.19858431
231 Bengtson A, Drevenhorn E. The nurse’s role and skills in hypertension care: a review. Clin Nurse Spec. 2003;17(5):260–268.14501307
232 Carter BL, Bosworth HB, Green BB. The hypertension team: the role of the pharmacist, nurse, and teamwork in hypertension therapy. J Clin Hypertens (Greenwich). 2012;14(1):51–65.22235824
233 Himmelfarb CRD, Commodore-Mensah Y, Hill MN. Expanding the role of nurses to improve hypertension care and control globally. Ann Glob Health. 2016;82(2):243–253.27372529
234 Mills KT, Obst KM, Shen W, . Comparative effectiveness of implementation strategies for blood pressure control in hypertensive patients: a systematic review and meta-analysis. Ann Intern Med. 2018;168(2):110–120.29277852
235 Overwyk KJ, Dehmer SP, Roy K, . Modeling the health and budgetary impacts of a team-based hypertension care intervention that includes pharmacists. Med Care. 2019;57(11):882–889.31567863
236 The Community Guide. Cardiovascular disease: tailored pharmacy-based interventions to improve medication adherence website. 2019; https://www.thecommunityguide.org/findings/cardiovascular-disease-tailored-pharmacy-based-interventions-improve-medication-adherence. Accessed January 28, 2020.
237 Viswanathan M, Kahwati LC, Golin CE, . Medication therapy management interventions in outpatient settings: a systematic review and meta-analysis. JAMA Intern Med. 2015;175(1):76–87.25401788
238 The Community Guide. Cardiovascular disease: interventions engaging community health workers website. Guide to Community Preventive Services 2015; https://www.thecommunityguide.org/findings/cardiovascular-disease-prevention-and-control-interventions-engaging-community-health. Accessed January 30, 2020.
239 Jacob V, Chattopadhyay SK, Hopkins DP, . Economics of community health workers for chronic disease: findings from community guide systematic reviews. Am J Prev Med. 2019;56(3):e95–e106. doi: 10.1016/j.amepre.2018.10.009.30777167
240 Uhlig K, Patel K, Ip S, Kitsios GD, Balk EM. Self-measured blood pressure monitoring in the management of hypertension: a systematic review and meta-analysis. Ann Intern Med. 2013;159(3):185–194.23922064
241 Community Preventive Services Task Force. Self-measured blood pressure monitoring improves outcomes: recommendation of the Community Preventive Services Task Force. Am J Prev Med. 2017;53(3):e115–e118. doi: 10.1016/j.amepre.2017.03.003.28818278
242 Tucker KL, Sheppard JP, Stevens R, . Self-monitoring of blood pressure in hypertension: a systematic review and individual patient data meta-analysis. PLoS Med. 2017;14(9):e1002389. doi: 10.1371/journal.pmed.1002389.28926573
243 Duan Y, Xie Z, Dong F, . Effectiveness of home blood pressure telemonitoring: a systematic review and meta-analysis of randomised controlled studies. J Hum Hypertens. 2017;31(7):427–437.28332506
244 Sheppard JP, Tucker KL, Davison WJ, . Self-monitoring of blood pressure in patients with hypertension-related multi-morbidity: systematic review and Individual patient data meta-analysis. Am J Hypertens. 2020;33(3):243–251.31730171
245 Siu AL. Screening for high blood pressure in adults: U.S. Preventive Services Task Force recommendation statement. Ann Intern Med. 2015;163(10):778–786.26458123
246 Fletcher BR, Hartmann-Boyce J, Hinton L, Mcmanus RJ. The effect of self-monitoring of blood pressure on medication adherence and lifestyle factors: a systematic review and meta-analysis. Am J Hypertens. 2015;28(10):1209–1221.25725092
247 Agarwal R, Bills JE, Hecht TJ, Light RP. Role of home blood pressure monitoring in overcoming therapeutic inertia and improving hypertension control: a systematic review and meta-analysis. Hypertension. 2011;57(1):29–38.21115879
248 American Medical Association. Controlling high BP. Self-measured blood pressure: best practices website. 2018; https://www.ama-assn.org/system/files/2019-01/smbp-best-practices.pdf. Accessed January 27, 2020.
249 Centers for Disease Control and Prevention. Self-measured blood pressure monitoring: actions steps for clinicians website. 2014; https://www.cdc.gov/dhdsp/pubs/guides/best-practices/smbp.htm.
250 The Community Guide. Cardiovascular disease: interactive digital interventions for blood pressure self-managment website. 2017; https://www.thecommunityguide.org/findings/cardiovascular-disease-interactive-digital-interventions-blood-pressure-self-management. Accessed February 21, 2020.
251 Ostchega Y, Berman L, Hughes JP, Chen TC, Chiappa MM. Home blood pressure monitoring and hypertension status among US adults: the National Health and Nutrition Examination Survey (NHANES), 2009–2010. Am J Hypertens. 2013;26(9):1086–1092.23604493
252 Ostchega Y, Zhang G, Kit BK, Nwankwo T. Factors associated with home blood pressure monitoring among US adults: National Health and Nutrition Examination Survey, 2011–2014. Am J Hypertens. 2017;30(11):1126–1132.28633432
253 Ayala C, Tong X, Keenan NL. Regular use of a home blood pressure monitor by hypertensive adults—HealthStyles, 2005 and 2008. J Clin Hypertens (Greenwich). 2012;14(3):172–177.22372777
254 Breaux-Shropshire TL, Brown KC, Pryor ER, Maples EH. Prevalence of blood pressure self-monitoring, medication adherence, self-efficacy, stage of change, and blood pressure control among municipal workers with hypertension. Workplace Health Saf. 2012;60(6):265–271.22658733
255 Poon IO, Etti N, Lal LS. Does the use of home blood pressure monitoring vary by race, education, and income? Ethn Dis. 2010;20(1):2–6.20178174
256 Viera AJ, Cohen LW, Mitchell CM, Sloane PD. High blood pressure knowledge among primary care patients with known hypertension: a North Carolina Family Medicine Research Network (NC-FM-RN) study. J Am Board Fam Med. 2008;21(4):300–308.18612056
257 Jackson SL, Ayala C, Tong X, Wall HK. Clinical implementation of self-measured blood pressure monitoring, 2015–2016. Am J Prev Med. 2019;56(1):e13–e21. doi: 10.1016/j.amepre.2018.06.017.30337237
258 Woolsey S, Brown B, Ralls B, Friedrichs M, Stults B. Diagnosing hypertension in primary care clinics according to current guidelines. J Am Board Fam Med. 2017;30(2):170–177.28379823
259 Van Durme DJ, Goldstein M, Pal N, Roetzheim RG, Gonzalez EC. The accuracy of community-based automated blood pressure machines. J Fam Pract. 2000;49(5):449–452.10836778
260 Bosworth HB, Granger BB, Mendys P, . Medication adherence: a call for action. Am Heart J. 2011;162(3): 412–424.21884856
261 Ritchey M, Chang A, Powers C, . Vital Signs: disparities in antihypertensive medication nonadherence among medicare part d beneficiaries - United States, 2014. MMWR Morb Mortal Wkly Rep. 2016;65(36):967–976.27632693
262 Ho PM, Bryson CL, Rumsfeld JS. Medication adherence: its importance in cardiovascular outcomes. Circulation. 2009;119(23):3028–3035.19528344
263 Flack JM, Nasser SA. Benefits of once-daily therapies in the treatment of hypertension. Vasc Health Risk Manag. 2011;7:777–787.22241952
264 Taitel M, Fensterheim L, Kirkham H, Sekula R, Duncan I. Medication days’ supply, adherence, wastage, and cost among chronic patients in Medicaid. Medicare Medicaid Res Rev. 2012;2(3). doi: 10.5600/mmrr.002.03.a04.
265 White ND. Pharmacy medication synchronization service works to improve medication adherence. Am J Lifestyle Med. 2016;10(6):385–387.30202298
266 The Community Guide. Cardiovascular disease: mobile Health (mHealth) interventions for treatment adherence among newly diagnosed patients website. 2017; https://www.thecommunityguide.org/findings/cardiovascular-disease-mobile-health-interventions-treatment-adherence-among-newly-diagnosed-patients. Accessed January 28, 2020.
267 National Quality Forum. Quality Positioning System (QPS): Measure Description Display Information Controlling High Blood Pressure website. 2013; http://www.qualityforum.org/QPS/MeasureDetails.aspx?standardID=1236&print=0&entityTypeID=1. Accessed June 2, 2020.
268 Million Hearts. Clinical quality measure alignment website. 2019; https://millionhearts.hhs.gov/data-reports/cqm/measures.html. Accessed January 27, 2020.
269 Health Resources and Services Administration. AHRQ Data Spotlight: hypertension control in Health Resources and Services Administration health centers. 2020. AHRQ Publication No. 19(20)-0069.
270 Wagner EH. Chronic disease management: what will it take to improve care for chronic illness? Eff Clin Pract. 1998;1(1):2–4.10345255
271 Kaboli PJ, Howren MB, Ishani A, . Efficacy of patient activation interventions with or without financial incentives to promote prescribing of thiazides and hypertension control: a randomized clinical trial. JAMA Network Open. 2018;1(8):e185017–e185017. doi: 10.1001/jamanetworkopen.2018.5017.30646291
272 Mensah GA. Commentary: hypertension phenotypes: the many faces of a silent killer. Ethn Dis. 2019;29(4): 545–548.31641321
273 Wozniak G, Khan T, Gillespie C, . Hypertension control cascade: a framework to improve hypertension awareness, treatment, and control. J Clin Hypertens (Greenwich). 2016;18(3):232–239.26337797
274 Chang TE, Ritchey MD, Park S, . National rates of nonadherence to antihypertensive medications among insured adults with hypertension, 2015. Hypertension. 2019;74(6):1324–1332.31679429
275 Mueller M, Purnell TS, Mensah GA, Cooper LA. Reducing racial and ethnic disparities in hypertension prevention and control: what will it take to translate research into practice and policy? Am J Hypertens. 2015;28(6):699–716.25498998
276 He J, Muntner P, Chen J, . Factors associated with hypertension control in the general population of the United States. Arch Intern Med. 2002;162(9):1051–1058.11996617
277 Carey RM, Muntner P, Bosworth HB, Whelton PK. Prevention and control of hypertension. J Am Coll Cardiol. 2018;72(11):1278–1293.30190007
278 Agency for Healthcare Research and Quality. About EvidenceNOW: background and stories from the field website. 2019; https://www.ahrq.gov/evidencenow/about/index.html. Accessed February 21, 2020.
279 Whelton PK, Einhorn PT, Muntner P, . Research needs to improve hypertension treatment and control in African Americans. Hypertension. 2016;68(5):1066–1072.27620388
280 Kitt J, Fox R, Tucker KL, Mcmanus RJ. New approaches in hypertension management: a review of current and developing technologies and their potential impact on hypertension care. Curr Hypertens Rep. 2019;21(6):44.31025117
281 Jones DW, Hall JE. The national high blood pressure education program: thirty years and counting. Hypertension. 2002;39(5):941–942.12019273
282 Frieden TR, Berwick DM. The “Million Hearts” initiative—preventing heart attacks and strokes. N Engl J Med. 2011;365(13):e27. Accessed Sep 29. doi: 10.1056/NEJMp1110421.21913835
283 Mccullough J. The Return on Investment of Public Health System Spending. AcademyHealth; June 2018.
284 Lackland DT, Carey RM, Conforto AB, . Implications of recent clinical trials and hypertension guidelines on stroke and future cerebrovascular research. Stroke. 2018;49(3):772–779.29467237
285 Okonofua EC, Simpson KN, Jesri A, . Therapeutic inertia is an impediment to achieving the Healthy People 2010 blood pressure control goals. Hypertension. 2006;47(3):345–351.16432045
286 Josiah Willock R, Miller JB, Mohyi M, . Therapeutic inertia and treatment intensification. Curr Hypertens Rep. 2018;20(1):4.29380142
287 Levy PD, Willock RJ, Burla M, . Total antihypertensive therapeutic intensity score and its relationship to blood pressure reduction. J Am Soc Hypertens. 2016;10(12):906–916.27856202
288 Campbell N, Ordunez P, Jaffe MG, . Implementing standardized performance indicators to improve hypertension control at both the population and healthcare organization levels. J Clin Hypertens (Greenwich). 2017;19(5):456–461.28191704
289 Smith CD, Balatbat C, Corbridge S, . Implementing optimal team-based care to reduce clinician burnout. NAM Perspectives. 2018. https://nam.edu/wp-content/uploads/2018/09/Implementing-Optimal-Team-Based-Care-to-Reduce-Clinician-Burnout.pdf doi: 10.31478/201809c.
290 Fendrick AM, Smith DG, Chernew ME. Applying value-based insurance design to low-value health services. Health Aff (Millwood). 2010;29(11):2017–2021.21041741
291 Orchard TJ, Temprosa M, Barrett-Connor E, . Long-term effects of the Diabetes Prevention Program interventions on cardiovascular risk factors: a report from the DPP Outcomes Study. Diabet Med. 2013;30(1):46–55.22812594
292 Sherrill B, Halpern M, Khan S, Zhang J, Panjabi S. Single-pill vs free-equivalent combination therapies for hypertension: a meta-analysis of health care costs and adherence. J Clin Hypertens (Greenwich). 2011;13(12):898–909.22142349
293 Berg S. New year, new CPT codes for self-measured BP website. 2019; https://www.ama-assn.org/practice-management/cpt/new-year-new-cpt-codes-self-measured-bp. Accessed February 24, 2020.
294 Casey DE, Thomas RJ, Bhalla V, . 2019 AHA/ACC clinical performance and quality measures for adults with high blood pressure: a report of the American College of Cardiology/American Heart Association Task Force on Performance Measures. Circ Cardiovasc Quality Outcomes. 2019;12(11):e000057–e000057. https://pubmed.ncbi.nlm.nih.gov/31714813. doi: 10.1161/HCQ.0000000000000057.
295 Walsh J MK, Shojania Kg, Sundaram V, Nayak S, Davies S, Lewis R, Mechanic J, Sharp C, Henne M, Shah B, Chan Jk, Owens Dk, Goldstein Mk. Hypertension Care. Vol. 3 Of: Shojania Kg, Mcdonald Km, Wachter Rm, Owens Dk, Editors. Closing the Quality Gap: A Critical Analysis of Quality Improvement Strategies. Technical review 9. Rockville, MD: Agency for Healthcare Research and Quality 2005. AHRQ Publication No. 04-0051-3.
296 Christianson JB. The role of employers in community health care systems. Health Aff (Millwood). 1998;17(4):158–164.
297 Saunders MK. Unleashing new data on health system readiness. Health Aff (Millwood). 2018;37(8):1331. 10.1377/hlthaff.2018.0791. doi: 10.1377/hlthaff.2018.0791.30080466
298 Thomas SM, Cassells HB. Quality improvement project for managing elevated blood pressure in a primary care setting. Integr Blood Press Control. 2017;10:25–32.29075138
299 Fremont A, Kim AY, Bailey K, . One in five fewer heart attacks: impact, savings, and sustainability in San Diego County Collaborative. Health Aff (Millwood). 2018;37(9):1457–1465. 10.1377/hlthaff.2018.0443. doi: 10.1377/hlthaff.2018.0443.30179541
300 Pearson TA, Palaniappan LP, Artinian NT, . American Heart Association guide for improving cardiovascular health at the community level, 2013 update: a scientific statement for public health practitioners, healthcare providers, and health policy makers. Circulation. 2013;127(16):1730–1753.23519758
301 Be There San Diego. Organizational approach to hypertension management using team-based care website. http://betheresandiego.org/storage/files/btsd-recommedations-01.pdf. Accessed February 24, 2020.
302 Robert Wood Johnson Foundation. Building a culture of health website. https://www.rwjf.org/en/how-we-work/building-a-culture-of-health.html. Accessed February 24, 2020.
303 Healthy Chicago. Healthy Chicago, Healthy Hearts: A local response to the national forum updated public health action plan to prevent heart disease and stroke website. https://www.chicago.gov/content/dam/city/depts/cdph/CDPH/CDPH_CardiovascularHealthBrochure_v4.pdf. Accessed February 24, 2020.
304 Ferdinand KC, Patterson KP, Taylor C, . Community-based approaches to prevention and management of hypertension and cardiovascular disease. J Clin Hypertens (Greenwich). 2012;14(5):336–343.22533661
305 Hoffman D, Murtzlufft J. Why Preventing Chronic Disease is Essential - Prevention Works. Decatur, Ga National Association of Chronic Disease Directors;2018.
306 The Community Guide. Cardiovascular disease: team-based care to improve blood pressure control website. Systematic Review 2012; https://www.thecommunityguide.org/findings/cardiovascular-disease-team-based-care-improve-blood-pressure-control. Accessed February 24, 2020.
307 Centers for Disease Control and Prevention. Collaborative practice agreements and pharmacists’ patient care services: a resource for pharmacists. Atlanta, Ga: US Dept. of Health and Human Services, Centers for Disease Control and Prevention; 2013.
308 Mckernan SC, Kuthy RA, Reynolds JC, Tuggle L, Garcia DT. Medical-dental integration in public health settings: an environmental scan. Iowa City, IA: University of Iowa Public Policy Center;2018.
309 Dzau VJ, Balatbat CA. Future of hypertension. Hypertension. 2019;74(3):450–457.31352827
310 Rehman H, Kamal AK, Morris PB, . Mobile Health (mHealth) technology for the management of hypertension and hyperlipidemia: slow start but loads of potential. Curr Atheroscler Rep. 2017;19(3):12.28210974
311 Morawski K, Ghazinouri R, Krumme A, . Association of a smartphone application with medication adherence and blood pressure sontrol: The MedISAFE-BP randomized clinical trial. JAMA Intern Med. 2018;178(6):802–809.29710289
312 Patel R, Chang T, Greysen SR, Chopra V. Social media use in chronic disease: a systematic review and novel taxonomy. Am J Med. 2015;128(12):1335–1350.26159633
313 Community Preventive Services Task Force. Tobacco use and secondhand smoke exposure: mass-reach health communication interventions. The Guide to Community Preventive Services website. 2013; https://www.thecommunityguide.org/findings/tobacco-use-and-secondhand-smoke-exposure-mass-reach-health-communication-interventions. Accessed July 12, 2019.
314 U.S. Department of Health and Human Services Food and Drug Administration. Voluntary sodium reduction goals: target mean and upper bound concentrations for sodium in commercially processed, packaged, and prepared foods: guidance for industry. Rockville, MD: U.S. Department of Health and Human Services; 2016.
315 Henwood BF, Stanhope V, Brawer R, . Addressing chronic disease within supportive housing programs. Prog Community Health Partnersh. 2013;7(1):67–75.23543023
316 Barrett MA, Miller D, Frumkin H. Parks and health: aligning incentives to create innovations in chronic disease prevention. Prev Chronic Dis. 2014;11:E63. 10.5888/pcd11.130407. doi: 10.5888/pcd11.130407.24742396
317 Pahkala K, Hietalampi H, Laitinen TT, . Ideal cardiovascular health in adolescence: effect of lifestyle intervention and association with vascular intima-media thickness and elasticity (the Special Turku Coronary Risk Factor Intervention Project for Children [STRIP] study). Circulation. 2013;127(21):2088–2096.23613255
318 Dudley DA, Cotton WG, Peralta LR. Teaching approaches and strategies that promote healthy eating in primary school children: a systematic review and meta-analysis. Int J Behav Nutr Phys Act. 2015;12:28.25889098