# Foreword from the Surgeon General, U.S. Department of Health and Human Services

U.S. Surgeon General Jerome Adams.

As a physician, I’ve seen firsthand the devastating effects of hypertension. Left uncontrolled, it leads to heart attacks, stroke, kidney disease, and cognitive decline in later life, and it can impact mother and baby during and after pregnancy. In addition, as evidenced from the global COVID-19 outbreak earlier in the year, we’ve seen the broad impact of preventable health conditions on worse outcomes.

Hypertension is unfortunately common, but there are interventions and programs that have been successful in improving control. Our country has many hypertension control champions—doctors, practices, communities, and health systems that have excelled at achieving high rates of hypertension control among their patients. We need to learn from their many years of “blood, sweat, and tears” and apply their principles in new settings.

While hypertension is more prominent among older adults, it is not simply a condition of the elderly. All ages are impacted, and early identification and long-term control can preserve cardiovascular health now and into the future. We know that lifestyle changes, such as being physically active and adopting a healthy diet, can promote hypertension control, yet many communities have significant barriers that prevent people from making these changes. We also know that many people with hypertension require medications to achieve control. Access to high-quality health care, prescription of appropriate medications, and clinical and community support are needed to prevent and treat hypertension, publicize local resources, and establish a plan for care supportive of long-term control.

The Surgeon General’s Call to Action to Control Hypertension summarizes recent data on hypertension control, identifies select goals and strategies, and provides recommendations for areas of focus when resources are limited. While the recent trends don’t look good—we’ve hit a plateau in hypertension control—I believe that with focus and collaboration, we can improve our trajectory.

Join me in taking control of hypertension across our nation. Together, we’ve got this!

- Jerome M. Adams, MD, MPH
  Vice Admiral, U.S. Public Health Service
  Surgeon General
  U.S. Department of Health and Human Services