# Message from the Secretary, U.S. Department of Health and Human Services

Health and Human Services Secretary Alex Azar.

As a nation, our ability to improve hypertension control requires focus. We must focus on better using the interventions that we already know work, and we must focus on conducting science that supports the creation of new, innovative interventions. As Secretary, I have a unique perspective across multiple sectors that influence hypertension control, including the roles that social services, health insurers, patient care, research, public health, and the pharmaceutical industry can play.

While we normally look to the health care sector to combat chronic diseases, the high burden of hypertension requires us to expand our partnerships across settings to maximize our collective influence.

I am excited about The Surgeon General’s Call to Action to Control Hypertension, because it includes specific hypertension control goals for our nation and provides proven strategies and relevant resources that multiple sectors can use immediately.

The data speak for themselves—nearly one in two adults have hypertension, and only about one in four people with hypertension have it under control. This places millions of Americans at heightened risk for heart disease and stroke, the first and fifth leading causes of death in the United States.

We must address this threat to our health. The time to act is now.

- Alex M. Azar II
  Secretary
  U.S. Department of Health and Human Services