# A Vision for the Future

In 2010, the Institute of Medicine declared that hypertension prevention and control in the U.S. were in a state of neglect.^27^ Since then, the prevalence of hypertension has remained relatively unchanged.^4,64^ In addition, recent progress in hypertension control has stalled, and a significant portion of people with hypertension do not have the condition under control, regardless of the threshold used.^1^

The good news is that lifesaving gains are possible. To improve hypertension control across the U.S. and for all populations, we need broadscale, multisector, culturally sensitive, and diverse interventions. This future can only be realized if significant changes are made at national, state, and community levels to support lifestyle behaviors that we know can improve hypertension control—including physical activity and a healthy diet. Community changes support improvements in the clinical setting. We can learn from providers who successfully control hypertension among the patients in their clinics and use this knowledge to replicate and expand effective interventions. However, changes in health care systems also require a supportive environment, including expanded reimbursement for management tools, enhanced links between community programs and clinical services, and the integrated use of health technology and data systems. Novel interventions and new research are also needed to reach all populations affected by hypertension.

Although hypertension control estimates at the national level have stagnated, our efforts cannot. Many strategic partners have devoted ample energy to advancing hypertension control across our nation. This Call to Action seeks to further support those efforts by presenting specific goals and strategies and making sector-specific recommendations for action.

Together, we’ve got this!