# Section 3 Sector-Specific Actions

Proven strategies to effectively manage hypertension are readily available, and groups throughout the country have had success implementing them.^6,7^ However, the efforts of many sectors are needed to ensure that these strategies reach people in every community and population group. This section provides an overview of the sectors that can work together to promote hypertension control. It describes each sector’s potential role in improving hypertension control nationally, as well as the benefit of bringing multiple sectors together in these efforts. One-page guides were developed for some sectors to highlight the health, economic, and societal reasons why hypertension control is important to each sector. These guides provide specific actions that sector members can take, as well as resources to support their efforts.

Multilevel and multisector interventions designed to improve chronic disease care are guided by a framework called the Chronic Care Model.^270^ When applied to hypertension control, the individual with hypertension is at the center of the model, because individuals must take an active role in managing their own condition to reduce their risk of heart disease, stroke, and other outcomes and maximize their quantity and quality of life.^271^ However, multiple intrinsic and extrinsic factors exist that can make it hard for individuals to control their blood pressure.^272,273,274^ Some groups may face particular challenges in achieving hypertension control. For example, younger adults have the highest percentages of underdetection and underdiagnosis of hypertension, as well as the highest percentages of nonadherence to recommended treatment, likely because of infrequent interaction with the health care system.^213,273,274^ Other demographic groups (e.g., non-Hispanic blacks) also have low rates of hypertension control for several reasons, many of which are potentially modifiable.^3,275,276^ Examples include being in clinical and community environments that are not conducive to getting guideline-recommended hypertension management care or supportive of healthy lifestyle behaviors.^275,277^

To help overcome barriers to care, the federal government, as well as state and local governments, can use the multiple sectors they work within to create environments that are conducive to helping people control their hypertension. For example, governments can fund and conduct research,^278,279,280^ support programs,^281,282^ and adopt policy and system approaches^27^ that help ensure that people with hypertension have access to community and clinical resources that encourage healthy lifestyle behaviors and provide the best care. Because governments have competing demands for finite resources, external groups seeking support for their efforts must make the health and economic case for investing in hypertension control, including what actions will have the highest return on investment if they are funded.^283^

Public health professionals, health care professionals, and their professional associations and societies can work together to make the case for investing in hypertension control by describing the problems associated with uncontrolled hypertension.^1,3^ They can also identify the groups at highest risk^1,3^ and highlight the resources needed in the communities and individuals they serve.^63^ However, each of these sectors can face challenges helping people control their hypertension. For example, health care professionals may be confused by conflicting clinical guidelines, including differences in the criteria recommended for diagnosis and treatment of hypertension.^284^ They may find it hard to prioritize hypertension management as part of the daily demands of providing comprehensive care during short visits.^213,285^ They may not use the correct techniques to measure their patients’ blood pressure^17,223,224^ or to initiate or intensify treatment as needed to achieve and maintain hypertension control.^286,287^ These problems may be addressed by encouraging clinicians to follow clinical guidelines^8^ that are cost-effective, evidence-based, and focused on achieving control across all populations, including patients with known disparities. Public health and health care professionals can also hold each other and the organizations they work with accountable for providing guideline-recommended care and achieving high rates of control, and they can celebrate their successes to raise awareness.^6,7^

Health care practices, health centers, and health systems can help their health care professionals overcome challenges and prioritize hypertension control. They can provide the necessary resources to ensure that patients with hypertension are accurately diagnosed, treated according to national guidelines, and able to control their condition. They can use system approaches that have been proven to deliver hypertension management services effectively, such as protocols to standardize patient care;^17,216^ timely, high-quality clinical data to track and encourage high performance;^14,288^ and multidisciplinary care teams that take advantage of the training and skills of various disciplines to provide comprehensive care.^229,235^ One challenge to establishing care teams, however, is that reimbursement models are not always in place to support their use, especially when teams include nontraditional members such as pharmacists and community health workers.^289^ Despite these challenges, system-level changes can better position care teams for success and result in sustainable change.

Health plans and managed care organizations can help address these and other potential barriers related to care reimbursement by implementing payment models that reinforce the use of guideline-based, high-value care.^8,290^ In addition to adequately reimbursing team-based care interventions, health plans and managed care organizations can reduce or eliminate patient costs for lifestyle change programs such as the National Diabetes Prevention Program^291^ and for medications that make adherence easier, such as fixed-dose combination pills.^21,292^ They can also adopt and promote the use of updated billing codes for reimbursement of services related to self-measured blood pressure monitoring to improve hypertension diagnosis and management.^224,240,293^ In addition, they can continue to use meaningful clinical quality measures that support hypertension control and provide incentives for high performance.^294,295^

To further reinforce use of these practices, employers and health plan purchasers can ensure that hypertension control is an important part of the health care benefits offered to their employees and members. These benefits can include comprehensive coverage for appropriate and affordable prescribed medications, lifestyle change programs, and blood pressure monitoring inside and outside of the clinical setting.^27^ Employers and health plan purchasers—either individually or through participation in community coalitions—can also actively support broad application of clinical quality improvement efforts in hypertension control in their communities to guide public policy and community development efforts conducive to chronic disease prevention and management.^296,297^

Academic institutions and researchers can identify areas in need of further study and conduct research to fill the gaps. These may include addressing research gaps in areas such as management of different hypertension phenotypes. They can then use their findings to develop relevant resources and tools that can be used by different sectors to improve hypertension control among the populations they serve. Nongovernmental health organizations can support many of the activities described in previous sections, including convening experts to develop clinical guidelines,^8^ identifying high performers in clinical management,^13,298^ and ensuring that hypertension control remains a national priority. Community-based organizations and public–private partnerships, including minority-serving and faith-based organizations, can ensure that the scientific findings and resources developed by other sectors are translated into useable tools that serve the unique needs of their communities.^299,300,301,302,303,304^ For example, community development corporations can help educate business and civic leaders about the importance of chronic disease prevention and management, including hypertension control, to both the physical and economic health of the local community.^57,305^ Foundations, at both the national and local levels, can support this work by providing the funds needed to identify and expand best practices across communities.^302^

Although Call to Action Guides were not created for the following sectors, they still play important roles in supporting hypertension control across the U.S. For example, pharmacies should not simply be considered a way to distribute medication. Community-based pharmacists can support hypertension management in meaningful ways, including being integral members of care teams through collaborative practice agreements with local health care practices and health systems.^235,236,237,306,307^ They can provide medication therapy management services to reconcile medication regimens, support adherence, and recommend or make adjustments to medications to help patients lower their blood pressure.^236,237^ Pharmacies may offer free use of blood pressure machines, placing them in a central position to offer hypertension education and link to clinical care teams. Dental practices can support the identification of those with hypertension who may not regularly visit a health care provider by integrating blood pressure assessment during intake. Practices should ideally be linked with diverse community health care providers to support access to health systems that can diagnose and manage hypertension.^308^ Health care technology companies can support adherence by developing interoperable technological solutions that encourage patients to follow their treatment regimens, encourage healthy lifestyle behaviors, integrate self-measured blood pressure monitoring into clinical management, and support other modes of care delivery through telehealth.^259,309,310,311^

The pharmaceutical industry can support many of the medication-related efforts described in previous sections, and it can continue to develop new medications and treatments that decrease blood pressure and lower cardiovascular disease risk across diverse populations.^307^

The media can also support hypertension control. For example, if used effectively, social media can provide experiential, emotional, and social support to improve management of chronic conditions such as hypertension.^312^ Simple, repetitive messages work best, which aligns with fact that hypertension can be reduced to a number that is easily and routinely measured. Large-scale mass media campaigns have been shown to improve healthy behaviors and connect people with resources that support healthy behaviors.^313^ This approach could be used to improve hypertension control, and campaigns could be tailored to specific communities at high risk.^301^ The food industry can work to increase the availability of healthy foods, including lower-sodium options for consumers. The gradual and voluntary reduction of sodium in commercially packaged and prepared foods may result in gradual gains, and proposed guidelines have been developed by the U.S. Food and Drug Administration.^314^

From a health and economic perspective, people need access to quality housing, transportation, education, and employment for communities to prosper.^57^ Housing organizations can support hypertension management by coordinating services for residents through community health centers, transportation services, and social services.^315^ Transportation systems can align with community land use and design interventions to make it safe and easy for people to be physically active and have access to quality health care services.^32,189,316^ Educational institutions, including primary and secondary education, can provide information about the harms of uncontrolled hypertension and how behaviors early in life can influence a person’s lifelong blood pressure trajectory and risk of heart disease, stroke, and other negative health outcomes.^9,317,318^ They can also help to promote participation in physical activity and create environments that foster healthy behaviors—for example, by providing healthy food options in their facilities.