# Section 1 Evidence and the Need for Action

## Hypertension in the United States

Hypertension is a major preventable risk factor for heart disease and stroke, which are the first and fifth leading causes of death in the U.S., respectively.^1^ Clinicians diagnose patients with hypertension, make decisions about treatment recommendations, and determine control status by comparing patients’ systolic and diastolic blood pressure readings to defined thresholds (e.g., ≥130/80 mmHg). If left uncontrolled, hypertension can also increase a person’s risk of developing other health conditions, including heart failure, kidney disease, pregnancy complications, and cognitive decline in later life.^8^ The negative health effects of hypertension may be avoided with the use of evidence-based interventions, and multiple sectors can play an active role in implementing, adapting, and expanding these interventions across the U.S.

Although many of the interventions described in this publication can help prevent hypertension, the focus of this Call to Action is on improving control among the millions of U.S. adults who already have hypertension. Applying the criteria from the most recent national hypertension guideline,^8^ nearly half of U.S. adults (108 million) have hypertension and are recommended to make lifestyle changes and, if appropriate, take antihypertension medication to lower their blood pressure (Figure 1). Among the 87 million U.S. adults with hypertension who are estimated to have received recommendations to make lifestyle changes and take medication, hypertension control rates are alarmingly inadequate. About 71% (61 million) have uncontrolled hypertension (≥130/80 mmHg).

Figure 1 Prevalence, Control Status, and Treatment of Hypertension Among U.S. Adults, National Health and Nutrition Examination Survey, 2013–2016

^a^ Based on the American College of Cardiology and American Heart Association’s 2017 Hypertension Clinical Practice guideline for adults aged 18 years or older who have blood pressure ≥130/80 mmHg or who are currently using prescription medication to lower their blood pressure.

^b^ Among those recommended to take prescription medication and make lifestyle changes.

A diagram illustrating statistics for hypertension among adults in the United States. The diagram begins with 100 generic human figures, 45 of which are highlighted. These are labeled, “U.S. adults with hypertension: 45% (108 million). Refer to footnote A. The rest of the diagram consists of three circle graphs. The first reads, “About 4 in 5 recommended lifestyle changes and prescription medication (87 million).” Refer to footnote B. The second reads, “About 1 in 3 untreated (30 million).” Refer to footnote B. The third reads, “About 3 in 4 uncontrolled. (61 million).” Refer to footnote B.

Source: Centers for Disease Control and Prevention (CDC). Hypertension Cascade: Hypertension Prevalence, Treatment and Control Estimates Among US Adults Aged 18 Years and Older Applying the Criteria From the American College of Cardiology and American Heart Association’s 2017 Hypertension Guideline—NHANES 2013–2016. Atlanta, GA: US Department of Health and Human Services; 2019.

To achieve control below the 130/80-mmHg threshold, many adults (31 million) who are already taking medication may need to have their prescription adjusted.^1^ Another 30 million adults whose blood pressure is at levels where medication use is recommended but who are untreated may need to be assessed for starting medication and making lifestyle changes. These estimates are derived from clinical guidelines and applied to a population health perspective. Individual treatment plans and target thresholds may vary due to age, co-morbidities, or other factors, and maintaining a consistent medical home can allow for specific tailoring of recommendations. The most recent national guidelines also include additional categories of blood pressure thresholds (Normal: <120 and <80 mmHg; Elevated: 120–129 and <80 mmHg; Hypertension Stage 1: 130–139 or 80–89 mmHg; Hypertension Stage 2: ≥140 or ≥90 mmHg), with lower blood pressure generally associated with improved outcomes.^8^

Improving management of hypertension has been traditionally described in terms of improving awareness (the percentage of people who have hypertension and know they have it), treatment (the percentage who have hypertension and are receiving recommended care), and control (the percentage who have hypertension and whose blood pressure has been lowered below specified thresholds). Assessing progress in each of these indicator areas can help identify potential gaps in care, and it offers opportunities for action.

Low awareness of hypertension in a population may indicate a lack of access to and engagement with the health care system, which may require interventions that draw on community and clinical resources to increase blood pressure screening and take action if high values are found. Low treatment rates in a population may indicate a lack of access to care, low rates of health literacy, cost barriers, or a lack of action by individuals (e.g., nonadherence to recommended treatment) or clinicians (e.g., clinical inertia) to address hypertension. Interventions that have proven to be effective in reducing treatment gaps in both community and clinical settings are those that provide individuals, families, clinicians, and community-based care coordinators and programs with the knowledge, tools, and resources needed to ensure that individuals receive guideline-recommended care. Hypertension control is key to reducing the risk of future cardiovascular events in a population. It is potentially the most important indicator to use to evaluate the overall effectiveness of interventions designed to manage blood pressure in a health care practice, health care system, or community.

Awareness, treatment, and control of hypertension are important across the lifespan. Although most of the goals and strategies identified in this Call to Action focus on improving hypertension control among adults because of the high rates in this population, hypertension—or the path toward developing hypertension—can begin in childhood or adolescence.^9^ Early identification of hypertension and related risk factors among young people can allow for early intervention to prevent progression of this condition and support successful transition from pediatric to adult care.^10,11^ Although many of the clinical and community approaches in this Call to Action are relevant across the lifespan, unique aspects of blood pressure management for young people would likely require additional strategies and resources beyond those presented in this publication.

In this Call to Action, the term “sectors” refers to groups that may use the information in this publication for action, including government entities, organizations, and industries that have a stake in the health of the communities they serve. For each sector we highlight, we recommend specific strategies they can use to take advantage of their unique resources and opportunities for intervention to collectively support achievement of local and national hypertension control goals.

## Control Is Possible

High levels of hypertension control can be achieved in clinical settings and communities.^5,6,12,13^ Many health care providers—from large integrated health care systems to community health centers serving different populations to individual health care providers—have demonstrated significant improvements in hypertension control in their patient populations and been recognized nationally for their efforts.^6,12,13^ They have done so by making hypertension control a priority, implementing evidence-based strategies, and being dedicated to monitoring improvement over time.^6,7,14,15,16,17,18,19,20^ These strategies include the following:

■ Enhancing electronic health record systems to improve clinical workflows and provide decision support tools.
■ Implementing treatment protocols.
■ Expanding the use of integrated care teams.
■ Providing clinician feedback on performance.
■ Prioritizing medication intensification and adherence.
■ Promoting shared management through self-measured blood pressure monitoring.

Some communities have also taken steps to develop policies and programs that implement many of the strategies included in this Call to Action and worked with partners in other sectors to amplify their efforts to make population-level improvements in hypertension control.^5^

## Barriers to Control

Despite the successes that many health systems and communities have had in achieving high rates of hypertension control, significant barriers still exist. These barriers include individuals having inadequate health insurance coverage, high deductibles and copayments, or limited access to health care services, which can limit their receipt of hypertension-related care.^21,22,23^ Individuals may have low levels of health literacy and complex medical management needs that may prevent them from accessing or using medications and technology (e.g., self-measured blood pressure monitors) to help them lower their blood pressure.^24,25^ Further, although advice from a clinician is a critical first step that empowers many individuals to attempt lifestyle changes to manage their blood pressure,^26^ it can be insufficient when not adequately supported by policy, systemic, and environmental interventions that make it easier for people to make healthy choices.^27,28,29^ For example, people may have limited access to safe areas to be physically active or to transportation to receive health care services, or they may have physical or mental disabilities or time limitations because of caregiver and work responsibilities.^30,31,32,33,34,35^ Mental health challenges can complicate hypertension management, and engagement of a mental health clinician may be needed to meet collaborative goals.^36,37^ In addition, these barriers may occur in tandem and can be either compounded or mitigated by people’s past or existing experiences, beliefs, biases, and cultures.^30,38,39,40^ Understanding these factors and the role they may play in limiting or supporting hypertension control is important for improving adherence to prescribed therapy and recommended lifestyle changes.

## Promoting Health Equity

“Achieving health equity requires valuing everyone equally with focused and ongoing societal efforts to address avoidable inequalities, historical and contemporary injustices, and the elimination of health and health care disparities.”

—National Stakeholder Strategy for Achieving Health Equity. National Partnership for Action to End Health Disparities.

Health equity has been defined as being achieved when every person has the opportunity to “attain their full health potential and that no one should be disadvantaged from achieving this potential because of their social position or other socially determined circumstance.”^41,42^ Health inequities may be demonstrated in differences in length and quality of life, rates and severity of disease, rates of death, and access to prevention and treatment.^43^ Health disparities have been defined by many groups and generally refer to differences that may adversely affect groups of people who have “systematically experienced greater obstacles to health based on their racial or ethnic group; religion; socioeconomic status; gender; age; mental health; cognitive, sensory, or physical disability; sexual orientation or gender identity; geographic location; or other characteristics historically linked to discrimination or exclusion.”^44,45^

In the U.S., certain groups of people have disproportionately high rates of hypertension and its related health consequences. Prevalence is higher among older adults and is also notably higher among certain racial and ethnic groups, especially non-Hispanic blacks.^46^ Although several modifiable and nonmodifiable factors are regularly recognized as contributing to hypertension, a “third arm of risk,” identified as the social determinants of health, should be prioritized.^47^ Social determinants of health, such as inequalities in the distribution of social, economic, and environmental conditions needed for health, have been associated with hypertension risk among non-Hispanic blacks and other minority groups.^47,48^ Psychosocial and socioeconomic stressors—such as low socioeconomic status, depression, job stress, financial stress, segregated neighborhoods, and neighborhood poverty level—also contribute to the risk of hypertension.^49,50,51,52,53^ In addition, past research has shown an association between racial discrimination and hypertension.^54,55^ Health inequities and disparities extend beyond prevalence and are present across all aspects of hypertension, from awareness to disease severity to treatment and control.^3,56^

To identify and address these health inequities and disparities and to promote health equity in communities and across various sectors, we need to better understand why these differences exist, identify success stories and areas where inequities or disparities have been reduced, identify and address barriers, and use community resources to initiate change. Surveillance or electronic health record data can be used to identify populations and communities with the highest rates so interventions can focus on those most in need. Human, technical, and financial resources can be allocated equitably to communities to address factors that contribute to disparities. Key partners, resources, and gaps in support can be identified in communities to address areas of need. Tailored policy, system, and environmental approaches, which are considered broad-scale, sustainable, and potentially scalable, are also needed to promote continued change within communities and to establish communities as places of opportunity for health and prosperity for all.^57^

The need for broadscale actions has never been more relevant. In 2020, disparities in the burden of disease—especially among minority populations—have been recognized during the COVID-19 pandemic. A growing body of evidence has shown that people with underlying health conditions, including cardiovascular disease, are at increased risk of worse outcomes related to COVID-19 infection.^58^ Infectious disease outbreaks can be amplified when they occur in populations with high rates of chronic disease, because they may affect the clinical course of the infectious disease or limit the ongoing management of the underlying chronic disease.^59^ Therefore, population health efforts that promote cardiovascular health, especially those that address social determinants of health, are needed now more than ever.

## Why Now?

Intervention is needed now because progress on reducing cardiovascular disease deaths, including among younger adults, has stalled.^60^ In addition, the U.S. population is aging,^61^ and there is more recognition of the negative health effects of uncontrolled hypertension.^62^ Fortunately, changes in health care systems, such as protocol-driven and team-based care, have been shown to improve hypertension control across many different populations groups.^6,7,14,15^ A growing number of success stories from across the country suggest that focused efforts can inspire rapid, far-reaching progress.^5,6,7^ Therefore, we have many of the tools and resources we need to accelerate progress in hypertension control. Now we need to apply them more widely. This Call to Action provides targeted strategies that different sectors can take to collectively improve hypertension control across the U.S. The time to act is now. Together, we’ve got this!