# Introduction

Hypertension, or high blood pressure, affects nearly one in two U.S. adults and is a major preventable risk factor for heart disease and stroke.^1^ Despite the common nature of this condition and a large amount of national attention,^2,3^ only about 24% (26 million) have their blood pressure controlled to ≤130/80 mmHg.^1^ Regardless of the threshold used to measure control, national rates have stagnated and disparities persist.^3,4^ The Surgeon General’s Call to Action to Control Hypertension seeks to avert the negative health effects of hypertension across the U.S. by identifying interventions that can be implemented, adapted, and expanded across diverse settings.

The Call to Action is divided into three sections. Section 1 summarizes the current state of hypertension control, including the economic costs and disparities between different population groups. It notes that progress in hypertension control has been demonstrated in communities and health care systems across the country.^5,6,7^ In many areas, we know what works, but we need to replicate and expand these efforts and continue to explore new interventions to achieve control across all population groups.

Section 2 presents three overall goals to support improvements in hypertension control:

- Goal 1. Make hypertension control a national priority.
- Goal 2. Ensure that the places where people live, learn, work, and play support hypertension control.
- Goal 3. Optimize patient care for hypertension control.

These goals take into account the need for national attention on hypertension control because of its broad adverse effects on health. They also recognize that community and clinical interventions designed to improve control must address the social determinants of health. Each goal is supported by strategies intended to accelerate actions to achieve success. The strategies were selected according to available scientific literature, identified promising practices, and expert opinion.

Section 3 identifies the sectors that can influence hypertension control. Diverse activities across many sectors are needed. Recognizing the importance of these sectors, Call to Action Guides were developed to provide sector-specific recommendations and resources. A significant amount of existing resources were identified during the development of this publication. Efforts were made to highlight these resources and not duplicate efforts.

To improve hypertension control across the U.S. for all populations, we need broadscale, culturally sensitive, and diverse interventions that address the social determinants of health. Although progress in hypertension control has stalled at the national level, our efforts must not. Many strategic partners have devoted significant energy to advancing hypertension control across our nation. This Call to Action seeks to further support and amplify those efforts. The challenge is significant, but the tools are plentiful. Together, we’ve got this!