# Acknowledgement

The Office of the Surgeon General would like to especially thank the leadership team from the Centers for Disease Control and Prevention, Division for Heart Disease and Stroke Prevention:

- CAPT Fleetwood Loustalot, FNP, PhD, FAHA
- Stephanie Bernard, PhD, MPH
- Jacquie Dozier, MLA
- Hilary K. Wall, MPH
- Erika Fulmer, MHA
- Alessandra Capriles, BA
- Michael Sells, PhD, MS
- CAPT Matthew Ritchey, PT, DPT, OCS, MPH
- LCDR Angela Thompson-Paul, PhD, MSPH

In addition, the Office of the Surgeon General would like to thank the many staff members who contributed to this report. Specifically, from the Centers for Disease Control and Prevention: Lauren Owens, MPH; Mary G. George, MD, MSPH, FACS; RADM Betsy Thompson, MD, MSPH, DrPH; Booker Daniels, MPH; and Susan Carlson, PhD. From the Office of the Surgeon General: Janet Wright, MD, FACC.