# Foreword From the Surgeon General

This report was largely written in fall 2019, when the economy was booming and unemployment was at an all-time low. Long before then, the United States was struggling with what many call the U.S. health disadvantage—that is, on average, the health of Americans is worse than the health of people in other wealthy countries, even as we spend more on healthcare than any other country. Within the United States, there are also clear differences in health status and access to healthcare across geographic settings and racial and ethnic groups. The original intent and message of our report was to communicate that health and the economy are inextricably linked, meaning we cannot have healthy communities without a prosperous economy, and we cannot have a prosperous economy without healthy communities. Strengthening the health of communities, in turn, requires eliminating the causes of the gaps in health status and gaps in access to care within and across our communities. We focused the report on the role of businesses in contributing to both community health and economic prosperity. We set out to make the case for greater business engagement with and investment in communities—especially those most vulnerable—not just because it is a good thing to do for the sake of others, but also because it is in the self-interest of businesses to do so.

Then the world changed. A novel coronavirus emerged in China and spread rapidly around the world. By early spring 2020, many Americans were staying home, and many nonessential businesses had closed their doors. Infection and death rates climbed, and the economic news turned grim. And yet, the message of our report endures and resonates even more profoundly: Health and the economy are inextricably linked. We cannot have one without the other. This interdependence—between health and the economy, and among all of us who make up society—has been neglected for too long. We now are seeing in very tangible and historic ways that our nation cannot maintain one without the other and cannot maintain either without including all of us.

Two trends characterize health in the United States. First, overall health in the wealthiest country on the planet is far from optimal and in many instances is getting worse, especially among the working-age population. Second, spending on medical care continues to go up. We pay more for healthcare than any other country in the world, but our health outcomes are not commensurate. Indeed, on some measures—like obesity, diabetes, infant mortality, and even life expectancy—outcomes are far worse in the United States than they are in many other nations.

The impetus for this report came from the observation that, even as they create suffering and hardship for individuals and families, the overall health of the U.S. population and the increasing cost of healthcare in the United States are also particularly burdensome to businesses. The success of businesses depends on a healthy and productive workforce, and businesses pay about 20% of the nation’s medical care costs by virtue of providing health insurance to employees and their dependents. Yet all this spending on healthcare by individuals, families, employers, and the government is not resulting in better health or longer life.

I am interested in what businesses can be doing to alter this reality—not just for the sake of improving health and controlling healthcare costs, but for the sake of improving their own long-term economic viability. How can businesses improve the health of their communities—including the health of current and future employees—while trying to control one of their largest business expenses, their growing and unsustainable healthcare costs?

Health and the economy are inextricably linked. We cannot have one without the other. This interdependence—between health and the economy, and among all of us who make up society—has been neglected for too long. We now are seeing in very tangible and historic ways that our nation cannot maintain one without the other and cannot maintain either without including all of us.

Exploring the role of business in health and society is not a typical topic for a Surgeon General’s report or a customary line of inquiry for public health. However, it brings into view a set of practical solutions that businesses can employ to help address the U.S. health disadvantage. This report explores

■ The U.S. health disadvantage and the burden it places on our businesses and our economy (in addition to our people and families);
■ How communities can become (or improve as) places that nurture health, wealth, and well-being and offer children and families opportunities to thrive; and
■ The meaning and role of businesses in the United States, and how businesses can create value for both themselves and their communities by helping to address the conditions that drive poor health and create the conditions that help people thrive.

This report describes the activities of community changemakers who can partner with businesses to engage stakeholders, create shared value, and steward systems that improve community health and increase economic prosperity. Finally, this report offers a vision for the future where businesses that wish to create value, enhance profit, and thrive over the long term, choose to invest in the health, wealth, and well-being of their stakeholders—employees, customers, suppliers, communities, investors, and shareholders—without whom those very businesses could not exist.

Businesses cannot prosper for long when society struggles. Certainly, the coronavirus pandemic of 2020 has made that clear. Businesses have had to adapt; many will recover, but some will not succeed. All should be concerned with strengthening our nation’s health and resiliency, so that any future economic downturn resulting from a health threat is less severe.

Some businesses have figured out ways to maintain, and even increase, profits while also addressing community needs and contributing to social progress. To succeed over the long term, businesses and those who invest in them have both a responsibility and a competitive interest to make money in ways that contribute to the health, wealth, and well-being of all. This report seeks to point the way for more businesses to do so, and to shine a light on specific strategies that are already showing results.

By integrating these approaches into business operations, many businesses have succeeded at what is the essence of capitalism—generating a profit while delivering the greatest societal gains—thus creating value for company and community. I believe doubling down on this purpose will improve community health and increase economic prosperity for all, help to right the U.S. health disadvantage, and help to control the costs of medical care.

I challenge business leaders and policymakers across the country to work toward ensuring business returns are commensurate with societal gains. That is what we should all envision as capitalism at its best.

- Jerome M. Adams, M.D., M.P.H.
  Vice Admiral, U.S. Public Health Service
  Surgeon General of the United States