# Acknowledgments

This report was prepared by the U.S. Department of Health and Human Services under the general direction of the Centers for Disease Control and Prevention, Office of the Director, Office of the Associate Director for Policy and Strategy.

- Vice Admiral (VADM) Jerome M. Adams, MD, MPH, Surgeon General, U.S. Public Health Service, Office of the Assistant Secretary for Health, Office of the Surgeon General, Office of the Secretary, U.S. Department of Health and Human Services, Washington, DC.
- Robert R. Redfield, MD, Director, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Robin M. Ikeda, MD, MPH, Associate Director for Policy and Strategy, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Richard W. Puddy, PhD, MPH, Director, Policy Research, Analysis, and Development Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Peter Briss, MD, MPH, Medical Director, Office of Medicine and Science, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- James E. Kucik, PhD, MPH, Deputy Director, Policy Research, Analysis, and Development Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Diane M. Hall, PhD, MSEd, Senior Scientist for Policy and Strategy, Policy Research, Analysis, and Development Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Martin J. Vincent, PhD, MBA, Health Scientist and Senior Advisor, Policy Research, Analysis, and Development Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.

## Senior Scientific Editors

- Ursula Bauer, PhD, MPH, Senior Advisor, Office of the Deputy Director for Non-Infectious Diseases, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Greg Fairchild, PhD, MBA, MPhil, Isidore Horween Research Associate Professor of Business Administration, Associate Dean for Washington, DC, Area Initiatives and Academic Director of Public Policy and Entrepreneurship, University of Virginia Darden School of Business, Charlottesville, Virginia.
- Doug Jutte, MD, MPH, Executive Director, Build Healthy Places Network; Associate Professor, University of California, Berkeley, School of Public Health; San Francisco, California.

## Contributing Authors

- Salma M. Abdalla, MBBS, MPH, Research Fellow, School of Public Health, Boston University, Boston, Massachusetts.
- Dolores Acevedo-Garcia, PhD, Professor of Human Development and Social Policy and Director of the Institute for Child, Youth and Family Policy at the Heller School for Social Policy and Management, Brandeis University, Waltham, Massachusetts.
- Lawrence Bowdish, PhD, Senior Director, Research and Issue Networks, U.S. Chamber of Commerce Foundation, Washington, DC.
- Antony Bugg-Levine, MPA, Chief Executive Officer, Nonprofit Finance Fund, New York, New York.
- Laura Choi, MPP, Vice President of Community Development, and Community Affairs Officer, Federal Reserve Bank of San Francisco, San Francisco, California.
- Elyse Cohen, MPH, Senior Director of Food, Health, and Wellness Programs, U.S. Chamber of Commerce Foundation, Washington, DC.
- Kimberlee Cornett, MA, Director, Impact Investments, Robert Wood Johnson Foundation, Washington, DC.
- Marc DeCourcey, Senior Vice President, U.S. Chamber of Commerce Foundation, Washington, DC.
- Karen B. DeSalvo, MD, MPH, MSc, Chief Health Officer, Google Health, New Orleans, Louisiana.
- Annie Donovan, MBA, Executive Vice President and Chief Operating Officer, Local Initiatives Support Corporation, New York, New York.
- Tory Flynn, MA, Vice President of Communications, Athene, West Des Moines, Iowa.
- Sandro Galea, MD, MPH, DrPH, Dean, Robert A. Knox Professor, School of Public Health, Boston University, Boston, Massachusetts.
- Marcela Hawn, MA, Senior Vice President, Chief Communications Officer, Centene Corporation, St. Louis, Missouri.
- Maurice Jones, JD, President and Chief Executive Officer, Local Initiatives Support Corporation, New York, New York.
- Sallie Keller, PhD, Director, Social and Decision Analysis, Distinguished Professor, Biocomplexity Institute and Initiative, University of Virginia Darden School of Business, Virginia.
- Bobby Milstein, PhD, MPH, Director of System Strategy, ReThink Health, Cambridge, Massachusetts.
- Tyler Norris, MDiv, Chief Executive, Well Being Trust, Oakland, California.
- Bich Ha Pham, JD, Manager, Communications and Policy, Healthcare Anchor Network/The Democracy Collaborative, Washington, DC.
- Jennifer S. Pitts, Senior Fellow, WE in the World, City of Industry, California.
- Mark Rukavina, MBA, Business Development Manager, Center for Consumer Engagement in Health Innovation, Boston, Massachusetts.
- Julia Ryan, MPA, Vice President, Health Initiatives, Local Initiatives Support Corporation, New York, New York.
- Somava Saha, MD, MS, Founder and Executive Lead, Well-being and Equity in the World, Executive Lead, Well Being In the Nation Network, Lexington, Massachusetts.
- Stephanie Shipp, PhD, Deputy Director, Professor, Social and Decision Analytics Division, Biocomplexity Institute and Initiative, University of Virginia Darden School of Business, Arlington, Virginia.
- Jennifer Talansky, MSc, Managing Director, Knowledge and Impact, Nonprofit Finance Fund, New York, New York.
- Nancy Turnbull, MBA, Senior Lecturer on Health Policy, Senior Associate Dean for Professional Education, Harvard T. H. Chan School of Public Health, Boston, Massachusetts.
- Charlie Vig, Former Chairman of the Board of Directors, Shakopee Mdewakanton Sioux Community, Prior Lake, Minnesota.
- Andrew Wicks, PhD, Ruffin Professor of Business Administration, Director, Olsson Center for Applied Ethics; Director, Doctoral Program, University of Virginia Darden School of Business, Charlottesville, Virginia.
- Kristin Williams, MA, Director of Community Initiatives, The Sherwood Foundation, Omaha, Nebraska.
- Steven Woolf, MD, MPH, Professor, Chair, Director Emeritus, and Senior Advisor, Virginia Commonwealth University, Richmond, Virginia.
- David Zuckerman, MPP, Director, Healthcare Anchor Network/The Democracy Collaborative, Washington, DC.

## Featured Authors

- Keith Anderson, Chairman, Shakopee Mdewakanton Sioux Community, Prior Lake, Minnesota.
- Carolyn Cawley, President, U.S. Chamber of Commerce Foundation, Washington, DC.
- Rebecca Crooks-Stratton, Shakopee Mdewakanton Sioux Community, Prior Lake, Minnesota.
- Governor Michael O. Leavitt, Founder, Leavitt Partners, Washington, DC.
- Cole Miller, Vice Chairman, Shakopee Mdewakanton Sioux Community, Prior Lake, Minnesota.
- Michael Frederic Neidorff, Chairman, President, and Chief Executive Officer, Centene Corporation, St. Louis, Missouri.
- Joe Anthony Raver, MBA, Board Member, President, and Chief Executive Officer, Applied Industrial Technologies, Batesville, Indiana.

## Reviewers

- Lieutenant Dennis Anderson-Villaluz, MBA, RD, LDN, FAND, Special Assistant to the U.S. Surgeon General, Office of the Surgeon General, U.S. Health Service, U.S. Department of Health and Human Services, Washington, DC.
- John Auerbach, MBA, President and Chief Executive Officer, Trust for America’s Health, Washington, DC.
- Catherine M. Baase, MD, FAAFP, FACOEM, Chair, Board of Directors, Michigan Health Improvement Alliance, Bay City, Michigan.
- Alina Baciu, PhD, MPH, Roundtable on Population Health Improvement, The National Academies of Sciences, Engineering, and Medicine, Washington, DC.
- Katharine Bierce, Senior Lead, Blog & Research Content, SalesForce, San Francisco, California.
- Lawrence Bowdish, PhD, Senior Director, Research and Issue Networks, U.S. Chamber of Commerce Foundation, Washington, DC.
- Peter Briss, MD, MPH, Medical Director, Office of Medicine and Science, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Rebecca Bunnell, PhD, MEd, Director, Office of Science, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Sajal Chattopadhyay, PhD, Economic Advisor, Community Guide Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Laura Choi, MPP, Vice President of Community Development, and Community Affairs Officer, Federal Reserve Bank of San Francisco, San Francisco, California.
- Bechara Choucair, MD, Physician and Chief Community Health Officer, Kaiser Permanente, Oakland, California.
- Dan Christenson, MA, Director of Government Relations, Pepsico, Purchase, New York.
- Sameera Fazili, JD, Director of Engagement, Community and Economic Development Department, Federal Reserve Bank of Atlanta, Atlanta, Georgia.
- Daniel M. Fox, PhD, President Emeritus, Milbank Memorial Fund, New York, New York.
- Edward Freeman, PhD, University Professor; Elis and Signe Olsson Professor of Business Administration, University of Virginia Darden School of Business, Charlottesville, Virginia.
- Rick Gates, Senior Vice President, Pharmacy and Healthcare, Walgreens Co., Deerfield, Illinois.
- Althea M. Grant-Lenzy, PhD, Captain, U.S. Public Health Service, Senior Science Advisor for Deputy Director for Non-Infectious Diseases, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Scott Grosse, PhD, Research Economist, National Center on Birth Defects and Developmental Disabilities, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Jeffrey E. Hall, PhD, MA, MSPH, CPH, Deputy Director, Office of Minority Health and Health Equity; Chief, Minority Health and Health Equity Activity, Office of Minority Health and Health Equity, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Connie Hallquist, MBA, Corporate Board Member, Medifast, Baltimore, Maryland.
- John Iskander, MD, MPH, Captain, U.S. Public Health Service, Senior Medical Advisor, Office of Science, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Vikas Kapil, DO, MPH, Chief Medical Officer and Associate Director for Science, Center for Global Health, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Pinar Karaca-Mandic, PhD, Director, Medical Industry Leadership Institute, University of Minnesota Carlson School of Management, Minneapolis, Minnesota.
- Rachel Kaufmann, MPH, PhD, Associate Director for Science, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Chinaro Kennedy, DrPH, MPH, Senior Health Scientist, National Center for Environmental Health/Agency for Toxic Substances and Disease Registry, Office of the Director, Office of Science, Centers for Disease Control and Prevention, Atlanta, Georgia.
- James E. Kucik, PhD, MPH, Deputy Director, Policy Research, Analysis, and Development Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Paula Lantz, PhD, Associate Dean for Research and Policy Engagement, Professor of Public Policy, Professor of Health Management and Policy, University of Michigan, Ann Arbor, Michigan.
- Kimberly Lochner, ScD, Deputy Associate Director for Science, Center for Preparedness and Response, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Megan McHugh, PhD, Assistant Professor, Northwestern University, Washington, DC.
- Lloyd Michener, MD, Professor, Department of Family Medicine & Community Health, Duke School of Medicine; Clinical Professor, Duke School of Nursing; Adjunct Professor, University of North Carolina Gillings School of Global Public Health, Durham, North Carolina.
- Bobby Milstein, PhD, MPH, Director of System Strategy, ReThink Health, Cambridge, Massachusetts.
- Karen Minyard, PhD, Executive Director, Georgia Health Policy Center, Atlanta, Georgia.
- Karen Mumford, PhD, Deputy Associate Director for Science, Center for State, Tribal, Local, and Territorial Support, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Sarah Norman, MPH, Director of Healthy Homes and Communities, Sheppard Pratt Health System, Baltimore, Maryland.
- Regina Pana-Cryan, PhD, Director, Economic Research and Support Office, Co-Manager, Healthy Work Design and Well-Being Cross-Sector Program, National Institute for Occupational Safety and Health, Centers for Disease Control and Prevention, Washington, DC.
- Richard W. Puddy, PhD, MPH, Director, Policy Research, Analysis, and Development Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Brian Rahmer, PhD, MS, Vice President, Health and Housing, Enterprise Community Partners, Wilmington, Delaware.
- Ela J. Rausch, PhD, MPP, Senior Advisor, Robert Wood Johnson Foundation Interdisciplinary Research Leaders Program, University of Minnesota; Principal and Consulting Scientist, Otto Rausch Consulting, Minneapolis, Minnesota.
- Kakoli Roy, PhD, Economic Advisor, Policy Research, Analysis, and Development Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Megan Sandel, MD, MPH, Board of Trustees, Enterprise Community Partners, Boston University School of Medicine, Boston, Massachusetts.
- Scott Santibañez, MD, DMin, MPHTM, Captain, U.S. Public Health Service, Associate Director for Science, Division of Preparedness and Emerging Infections, National Center for Emerging and Zoonotic Infectious Diseases, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Laura Seeff, MD, Senior Advisor to the CDC Foundation, Atlanta, Georgia.
- Benedict I. Truman, MD, MPH, Associate Director for Science, National Center for HIV/AIDS, Viral Hepatitis, STD, and TB Prevention, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Ritu Tuteja, MPH, Epidemiologist, National Center for Health Statistics, Centers for Disease Control and Prevention, Hyattsville, Maryland.
- Brian Tyler, PhD, Chief Executive Officer, McKesson Corporation, Washington, DC.
- Martin J. Vincent, PhD, MBA, Health Scientist and Senior Advisor, Policy Research, Analysis, and Development Office, Office of the Associate Director for Policy and Strategy, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Kamillah Wood, MD, MPH, Deputy Chief Executive Officer and Chief Medical Officer, Children’s Health Fund, New York, New York.
- Steven Woolf, MD, MPH, Professor, Chair, Director Emeritus, and Senior Advisor, Virginia Commonwealth University, Richmond, Virginia.

## Other Contributors

- Susan Armstrong, MPS, Graphic Design Specialist, American Institutes for Research, Washington, DC.
- Aynura Berdyyeva, Research Assistant, American Institutes for Research, Washington, DC.
- Susan Bratten, Senior Editor, American Institutes for Research, Washington, DC.
- Brian Calhoun, PhD, ORISE Fellow, Policy Research, Analysis, and Development Office, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Melissa Callaham, MSPH, Researcher, American Institutes for Research, Washington, DC.
- Suzanne Carmack, PhD, Researcher, American Institutes for Research, Washington, DC.
- Nevin Dizdari, Research Assistant, American Institutes for Research, Washington, DC.
- Kathleen Edmunds Cyr, Executive Assistant, American Institutes for Research, Washington, DC.
- Phil Esra, Editor, American Institutes for Research, Washington, DC.
- Jane Garwood, Senior Editor, American Institutes for Research, Washington, DC.
- Angela Jehle, Director, Publications & Creative Services, American Institutes for Research, Washington, DC.
- Clarence Johnson, Editorial Associate, American Institutes for Research, Washington, DC.
- Laura King, Senior Graphic Design Specialist, American Institutes for Research, Washington, DC.
- Martha Knuth, MLIS, Stephen B. Thacker CDC Library, Office of Library Science, Office of Science, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Anand Kumar, Principal Applications Architect, American Institutes for Research, Washington, DC.
- Devon LaPoint, Communications Associate, American Institutes for Research, Washington, DC.
- Dara Ledford, Senior Manager, Production Design, American Institutes for Research, Washington, DC.
- Katie Mallory, MA, Senior Production Design Specialist, American Institutes for Research, Washington, DC.
- Martha Mater, Senior Manager, Creative Services, American Institutes for Research, Washington, DC.
- Mari Moorhead, Advisor, Office of the Surgeon General, U.S. Department of Health and Human Services, Washington, DC.
- Dave Morton, MA, Editor, American Institutes for Research, Washington, DC.
- Don Mullins, MPH, Vice President, American Institutes for Research, Washington, DC.
- Stephanie Neuben, Editor, American Institutes for Research, Washington, DC.
- Leslie A. Norman, MBA, Public Health Analyst, Office on Smoking and Health, National Center for Chronic Disease Prevention and Health Promotion, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Andy Peterman, Senior Editor, American Institutes for Research, Washington, DC.
- Shoshana Rabinovsky, Research Associate, American Institutes for Research, Washington, DC.
- Sarah Rand, Communications Specialist, American Institutes for Research, Washington, DC.
- Jeanine Reed, Graphic Design Specialist, American Institutes for Research, Washington, DC.
- Lesa Rowe, Graphic Design Specialist, American Institutes for Research, Washington, DC.
- Carolyn Rugamas, Production Design Specialist, American Institutes for Research, Washington, DC.
- Elizabeth Scalia, MLIS, Library Specialist, American Institutes for Research, Washington, DC.
- Andrew Sell, Associate Director, Research Initiatives, Institute for Business in Society, University of Virginia Darden School of Business, Charlottesville, Virginia.
- Veeraj P. Shah, Intern, Office of the Surgeon General, Student, University of Maryland, College Park, Maryland.
- Zach Siegel, MA, Writer and Editor, Chicago, Illinois.
- Michelle Stergio, Digital and Social Media Strategist, American Institutes for Research, Washington, DC.
- Nancy Velasco, MHSA, Senior Technical Assistance Consultant, American Institutes for Research, Washington, DC.
- Sharon Wallace, Production Design Specialist, American Institutes for Research, Washington, DC.
- Karen Ward, Production Design Specialist, American Institutes for Research, Washington, DC.
- Lindsey Willis, Senior Communications Specialist, American Institutes for Research, Washington, DC.
- Gerry Yemen, University of Virginia Darden School of Business, Charlottesville, Virginia.

## Contributors to the Community Health and Economic Prosperity Initiative

Community Health and Economic Prosperity: Engaging Businesses as Stewards and Stakeholders—A Report of the Surgeon General was part of a broader initiative of the Office of the Surgeon General. The Community Health and Economic Prosperity (CHEP) Initiative included two components: (1) convenings of business, community, community development, and public health leaders from across the country who identified and shared examples of businesses that are engaging with communities to improve health and prosperity; and (2) communications and social media outreach that spread the word about the convenings and the topline messages of the CHEP Initiative to a broader audience. The following individuals are acknowledged for their contributions to the CHEP Initiative.

- Ursula Bauer, PhD, MPH, Senior Advisor, Office of the Deputy Director for Non-Infectious Diseases, Centers for Disease Control and Prevention, Atlanta, Georgia.
- Nazleen Bharmal, MD, PhD, MPP, Medical Director, Community Health & Partnerships, Cleveland Clinic, Cleveland, Ohio.
- Rafael D. Campos, MPS, Fellow, Office of the Surgeon General, U.S. Department of Health and Human Services, Washington, DC.
- Amber N. Channer, MS, Public Affairs Specialist, Office of the Surgeon General, U.S. Department of Health and Human Services, Washington, DC.
- Michelle Dennison, PhD, RD/LD, BC-ADM, CDE, Health Policy Liaison, Metabolic Care Center Grants Administrator, Oklahoma City Indian Clinic, Oklahoma City, Oklahoma.
- Courtney Emmett Gustin, DrPH, RN, CNM, Lieutenant Commander, U.S. Public Health Service, Office on Women’s Health, U.S. Department of Health and Human Services, Washington, DC.
- Laurie Konsella, MPA, Regional Health Administrator (Acting), Region VIII, U.S. Department of Health and Human Services, Denver, Colorado.
- Ellen T. Kurtzman, PhD, MPH, RN, FAAN, Associate Professor, School of Nursing, The George Washington University, Washington, DC.
- Mehran Massoudi, PhD, MPH, Captain, U.S. Public Health Service, Regional Health Administrator, Region VI, U.S. Department of Health and Human Services, Dallas, Texas.
- Kate Migliaccio-Grabill, MPH, Commander, U.S. Public Health Service, Director of Public Affairs, Office of the Surgeon General, U.S. Department of Health and Human Services, Washington, DC.
- Mari Moorhead, Advisor, Office of the Surgeon General, U.S. Department of Health and Human Services, Washington, DC.
- Rochelle Rollins, PhD, MPH, Senior Policy Advisor, Office of Minority Health, U.S. Department of Health and Human Services, Rockville, Maryland.
- Jenn Sherman, Director, Reservoir Communications Group, Washington, DC.
- Janet Wright, MD, FACC, Director of Science and Policy (Acting), Office of the Surgeon General, U.S. Department of Health and Human Services, Washington, DC.

Conflict of Interest Disclosures: All senior scientific editors completed and submitted conflict of interest disclosure forms. Unless noted below, no potential conflicts of interest were reported. Dr. Doug Jutte (Executive Director, Build Healthy Places Network; Associate Professor, University of California, Berkeley, School of Public Health) reports being a member of (a) the Board of Trustees for Mercy Housing, Inc.; (b) the Board of Trustees for Mercy Community Capital; (c) the Health Advisory Council for Enterprise Community Partners; (d) the New Markets Tax Credit Advisory Board for Primary Care Development Corporation; (e) the Socially Responsible Investing Advisory Group for Trinity Health; and (f) the Community Economic Investing Subcommittee of the Board of Trustees for CommonSpirit Health/Dignity Health.