# Welcome to Community Health and Economic Prosperity

At the U.S. Chamber of Commerce Foundation, we know that a healthy, productive workforce fuels vibrant communities. Businesses have long played an important role in promoting community health by investing in their employees and customers and by creating another essential building block to health: jobs. Healthy communities are essential to a strong economy that creates more opportunities for more people.

Our work with businesses in every corner of the nation confirms we are stronger when we work together—across government, nonprofits, academia, and the private sector. We saw this firsthand when our “Sharing Solutions” initiative took us on a national tour of communities hit hard by the opioid epidemic to host conversations about how employers can be a leading part of the solution. It is also why we have worked with groups like the National Academies of Science, Engineering, and Medicine to better understand businesses’ growing relationship to community health and share the significant return on those investments.

We welcome every opportunity to use our role as conveners of the business community to create solutions—both on the ground and through educational efforts like this Surgeon General’s report.

This report shines a light on the relationship between community health and economic prosperity. It encourages business leaders to continue to prioritize health and well-being as a key tenet of their community engagement. At the same time, it highlights the importance of an environment where businesses and community stakeholders can work together to deliver improved health outcomes.

It also underscores how employers are uniquely positioned to effect lasting change in their community’s health. Over decades, businesses have demonstrated their drive and commitment to fostering a culture of health in America. From using their reach to engage a broader group of citizens, to developing new and innovative strategies to empower healthy employees and customers, this report shows why continuing this momentum is more important than ever.

Whether addressing decades-old challenges or emerging crises, businesses are a vehicle for building healthy, sustainable, and strong communities that maximize everyone’s potential. The U.S. Chamber of Commerce Foundation is pleased to introduce readers to this Surgeon General’s Report on community health and economic prosperity, and we encourage businesses and other private sector leaders to celebrate the important contributions they have made, and find inspiration for the work that is to come.