# Report Development

This Surgeon General’s report was prepared by the U.S. Department of Health and Human Services (HHS) under the direction of the Centers for Disease Control and Prevention, Office of the Director, Office of the Associate Director for Policy and Strategy. This report was compiled using a peer-reviewed process designed to safeguard the scientific rigor and practical relevance of the content from influences that could adversely affect impartiality. This process helped to ensure that the report’s recommendations are defined by evidence and practice and not by the opinions of the contributors and editors.

In brief, under the leadership of a senior scientific editorial team, 30 experts wrote the initial drafts of the chapters. The experts were selected for their knowledge of the topics addressed. These contributions, which are included in Chapters 1–7, were evaluated by 22 peer reviewers. After this initial stage of peer review at the chapter level, the draft of the full report was reviewed by 24 peers, experts, and business leaders who examined the entire manuscript for scientific integrity, relevance to the business audience, and coherence. After each round of review, the report’s three senior scientific editors revised each draft based on reviewers’ comments. Chapter 8, which contains the Surgeon General’s recommendations based on the preceding content in the report, was written after the content in Chapters 1–7 completed the peer review process. Subsequently, the report was reviewed by various divisions of HHS. Throughout the review process, the content of each chapter was revised to include information, studies, and relevant context that were not available or had changed from when the chapters were first drafted; updates were made until shortly before the report was submitted for publication.

The statements and recommendations in this report are based on a review of the existing scientific, business, health, and community development literature and practices. Reflecting the evolving nature of the topic and the focus on business, the report cites a range of peer-reviewed journal articles, news articles and releases, industry publications, opinion polls, books, and tools and resources. This report also refers, on occasion, to unpublished work, such as presentations at professional meetings, personal communications from business leaders and practitioners, and information available in various media. These references are used when acknowledged by the editors and reviewers as being a critical addition to the emerging understanding of a topic.

This Surgeon General’s report was written for a business audience. In order to speak to and capture the attention of the business audience and to illustrate the actions that this report seeks to amplify, the report contains (a) examples of business enterprises investing in communities; (b) perspectives written by business leaders on the importance of business engagement with and investment in communities; and (c) various specific actions taken by named companies to address community health and economic prosperity.

The report contains five invited pieces that were authored by business leaders: an introduction by the president of the U.S. Chamber of Commerce Foundation; three business perspectives authored by the chief executive officers (CEOs) of Centene Corporation and Hillenbrand, Inc., and the business council members of the Shakopee Mdewakanton Sioux Community; and an afterword authored by the president and CEO of Leavitt Partners. These business leaders were asked to bring their unique business perspectives to particular aspects of the report and to share, through their pieces, their knowledge and experience of the work ahead to improve community health and increase economic prosperity.

Additionally, the report contains eight short case studies or “exemplars” that depict a particular company and particular actions taken by the company to solve a business problem while also addressing a societal challenge. These exemplars illustrate ways that businesses can strengthen their business operations while also strengthening communities. The exemplars comprise only a small subset of businesses and practices and are not meant to be a comprehensive or fully representative depiction of all businesses and practices. The business practices featured as exemplars came to the attention of the Surgeon General through engagements with colleagues in academia, business, public health, and other disciplines, as well as through the Surgeon General’s engagements in communities across the United States. Business leaders speaking to business leaders was considered an essential feature of this report. No business featured as an exemplar nominated itself for consideration as an exemplar.

Like most Surgeon General’s reports, this one was written by experts in the field who submitted content for chapters or sections. That content was edited and revised by three senior scientific editors, and then further refined and modified as a result of the extensive peer review and governmental clearance processes. In some instances, company leaders are named as authors in bylines of specific pieces in this report. These authors of the introduction, three business perspectives, and afterword wrote only their respective pieces and did not engage in or influence the writing of the report itself. The pieces submitted by company leaders were only lightly edited and reflect the views and opinions of the authors and do not necessarily reflect the views or opinions of the Surgeon General or HHS.