# Message From Alex M. Azar II, Secretary, U.S. Department of Health and Human Services

The past year was one of the most challenging that America has faced in modern times. The COVID-19 pandemic is one of the greatest public health threats ever to confront our country. It has devastated our economy and driven unemployment to record highs.

These challenges remind us that health and the economy are so often linked together. Congress passed historic levels of support to address the economic costs of the pandemic and to fund the public health response, but low-income Americans have not seen the full benefit of the economic recovery and continue to suffer more severe illness from COVID-19, in part because of preexisting health conditions they experience at rates that are higher than those among Americans who are better off.

Health disparities arise not just from unequal access to healthcare but also from unequal access to economic opportunity, meaningful work, stable families, livable housing, reliable transportation, quality education, and thriving communities.

Healthier people means a stronger economy, but a stronger economy also means healthier people. Those of us who care about both health and prosperity—in the public and private sectors—must recognize this connection and engage on both causes. That is the core insight of this historic publication, Community Health and Economic Prosperity: Engaging Businesses as Stewards and Stakeholders—A Report of the Surgeon General.

This effort emphasizes the inextricable and mutually reinforcing link between physical, mental, and community health and economic prosperity. It calls on private sector businesses, in particular, to engage with and invest in communities to improve health and foster prosperity.

Of the social determinants of health that our department focuses on, one of the greatest is simply access to economic opportunity. We know that economic opportunity—as well as the stable families, healthy environments, and strong communities it supports (what this report calls the “vital conditions”)—is good for health. But too many Americans are born into and grow up in low-opportunity neighborhoods. This creates costs for businesses and for society, as so many Americans never achieve their potential in the workforce, are unable to reach independence, and see their health and the health of their loved ones suffer as a result.

By working together, with deep engagement from the private sector, we can build a healthier society that is rich with opportunity for everyone. This Surgeon General’s report offers a way forward for the United States to recover from the COVID-19 pandemic and to build a healthier, more prosperous future for all Americans.