# CHAPTER 8 Report Recommendations

## OVERVIEW

This chapter recommends actions that businesses can take to strengthen community health and economic prosperity, develop a competitive business advantage, and build resilience for both community and business.

## Report Recommendations

The Surgeon General recommends the following actions to strengthen community health and economic prosperity, develop a competitive business advantage, and build resilience for both community and business. These approaches can help solve the U.S. health disadvantage and help companies account for the interdependence between business and society, and between community health and economic prosperity, when making business decisions. These strategies can help address the U.S. health disadvantage and help to ensure that the vital conditions are met for all Americans.

The Surgeon General notes that this is not an exhaustive list of all possible positive actions that businesses can take to strengthen community health and economic prosperity. Instead, this set of actions comprises a solid starting point based on real-world examples. Businesses will continue to innovate and collaborate together across sectors to discover, develop, and test ways to strengthen capitalism in the United States to the benefit of business and society, and community health and economic prosperity.

### 1 Learn More About Your Stakeholders

Stakeholders are all those who participate in a business and are essential to its success—including everyone from employees to suppliers to investors. Valuing the needs and interests of all stakeholders, and avoiding prioritizing one stakeholder at the expense of another, helps ensure success.

■ Fully understand the cost of poor health and other community challenges and the impact of these challenges on your company. Addressing challenging conditions in communities can improve opportunities for businesses, employees, customers, suppliers and other stakeholders and help create a thriving environment. Understanding the broader community you live in and developing business models that work to enhance that world help make explicit the connections among good business practices, profitability, and responsibility to community and society.
  Example—Businesses can help meet stakeholders’ needs through investments in quality affordable housing and education, by providing meaningful work and wealth, and by restoring or sustaining a thriving natural world. Box 4.5 in this report describes the negative impact of high housing costs on businesses’ ability to recruit, hire and retain employees. This creates an opportunity for business investment in affordable housing.
■ Join the dialogue on community health, wealth, and well-being. As this report goes to press, community dialogue abounds on bending the COVID-19 curve and addressing the impact of racism on health, wealth, and well-being. Even before the events of 2020, communities, businesses, and leaders were engaged in conversations about how to create a more equitable, just, and prosperous society—including addressing health, wealth, and well-being gaps across communities. A critical component of effective dialogue is viewing problems, policy options, and solutions from the perspective of the well-being of others.
  Example—Hillenbrand, Inc., established such a dialogue in their community of Batesville, Indiana. The Hillenbrand Community Leadership Series annually assembles 20 people from the company and community to engage in strategic discussions with business and civic leaders. The group is often used as a “think tank” for the community, studying and solving large issues facing the community, including diversity and inclusion, workforce skills, and the development of a vibrant downtown to build Batesville and Southeastern Indiana into attractive places to live and work.
■ Meaningfully engage all stakeholders on ways to optimize value. Many companies recognize the value that each stakeholder brings to the business enterprise. Meaningfully engaging each stakeholder—employees, customers, suppliers, communities, investors, and shareholders—brings innovative ideas to the fore, increases productivity and commitment to the enterprise, improves business practices, and creates more sustainable operations.
  Example—Sodexo creates value for its stakeholders by integrating actions that support health and wellbeing into the core of its business operations. By creating value for all of its stakeholders, Sodexo can grow in a way that is better, safer, healthier, and more sustainable for people and the planet.
■ Identify the interdependencies between your company and your stakeholders and between your business and society, and work toward ways of operating that benefit these stakeholders and society. Businesses depend on their stakeholders in order to exist and earn a profit. Businesses depend on society for essential infrastructure, such as a skilled workforce; a fair, transparent, and well-functioning legal system; education and training of the labor pool; community services like libraries and parks; and transportation and delivery infrastructure. Society and stakeholders likewise depend on businesses—for jobs, goods and services, and tax revenue and to bring innovations to the market. Paying attention to these interdependencies and delivering value to multiple stakeholders can help a business succeed.
  Example—BSR identified several trends and their implications for business’s engagement with stakeholders, including the growing expectation that business (a) has a role in driving an inclusive economy and reducing inequality; (b) should prioritize investment in ecosystems and deep local engagement; and (c) should develop collaborative solutions to systemic challenges.

### 2 Foster a Culture of Stewardship

Stewardship refers to a company managing its impact on society. System stewardship is the role of enterprises and organizations in solving problems that government alone cannot solve. The U.S. health disadvantage is such a problem, with roots in community conditions, inequality, and opportunity gaps. Stewards of systems will address these causes at a systems level: policy, taxation, investment, education, environment, healthcare, and more.

■ Embrace the positive role of business to strengthen communities. Businesses are perhaps the most powerful institutions on earth. Wielding that power for good has been a successful strategy for business.
  Example—Businesses have invested in programs to create local jobs (e.g., Starbucks) and in efforts to strengthen educational outcomes (e.g., Visa) and expand access to early childcare and education (e.g., Patagonia), all of which strengthen communities, especially when targeted to communities that are not thriving.
■ Support local, state, and federal policies that meaningfully increase economic opportunities and equitably improve the health of communities, employees, and families. Government policies (including spending) have the potential to strengthen communities, reduce inequality, and expand opportunity. Businesses have a powerful voice that can shape policy, including spending and implementing policies that have equitable impacts, with the most beneficial impacts on those most in need.
  Example—Health policies like smokefree air and community water fluoridation; tax policies that strengthen opportunity for all and reduce income and wealth gaps; and regulatory policies that optimize outcomes for the greatest number of stakeholders are some of the many ways in which businesses can advocate for outcomes that meet the needs of all stakeholders.
■ Use hiring and procurement tools to strengthen communities and explore opportunities to unleash untapped potential at the local level. Most businesses have relationships with other businesses, as suppliers and customers. Emphasizing local businesses in these relationships can help strengthen struggling communities and expand opportunities. By focusing on the needs of local communities and underserved populations and by investing in small businesses and entrepreneurs that may have difficulty accessing capital, businesses can solve hiring and supply-chain problems while strengthening communities. Disadvantaged communities and people with low incomes represent untapped potential to improve equitable access to the conditions that shape health, wealth, and well-being.
  Example—This report highlights several businesses (e.g., Greyston Bakery, Belden Inc., Bank of America, and Hyatt Hotels) that specifically hire individuals who may be passed over by other employers due to such barriers as lack of education, previous incarceration, and substance misuse. As these companies have discovered, such employees often prove to be highly effective, productive, dedicated, and loyal; and having jobs and incomes increase their potential as consumers.
■ Invest business profits in strengthening communities. Increasingly, both for-profit and nonprofit businesses are recognizing the potential to improve community conditions, especially affordable housing, while also receiving a financial return. Businesses can invest in other businesses, entrepreneurs, community development, and more while prioritizing investments that meet a community need and support commercial success.
  Example—UnitedHealthcare, a large for-profit health insurance company, provided a low-interest loan to a nonprofit partner to acquire nearly 500 units of rental housing. Up to 100 units are set aside for UnitedHealthcare clients at reduced rents and will include vital supportive services. In addition to loan repayment with interest, UnitedHealthcare already sees improvements in client health and associated cost reductions.

### 3 Develop Strategic Cross-Sector Partnerships

Businesses that wish to engage with and invest in communities need not go it alone or figure out what to do from scratch. Indeed, most efforts to improve community health, wealth, and well-being involve partnerships that bring a range of expertise and additional resources. Effective partners for business include community development organizations, philanthropic foundations, government agencies (including public health), and other businesses (including social enterprises).

■ Collaborate with local, regional, and national partners from across sectors to implement effective solutions. It is no coincidence that each of the exemplars presented in this report addressed a community problem while seeking a solution to a business problem—and did so in collaboration with local, regional, or national partners. That is because complex societal challenges—like opioid misuse, disengaged young people, and even lack of access to broadband Internet in rural areas—demand resources, knowhow, and creativity that multiple organizations working together provide.
  Example—See Exemplars after each chapter in this report.
■ Partner with community development corporations (CDCs) and community development financial institutions (CDFIs). CDCs and CDFIs have long been in the business of community building and providing financial and other services and supports to those most in need—both communities and people. Collaborating with these partners accelerates the work of increasing opportunity and brings specialized skills, financial expertise and resources, and deep community knowledge and trust.
  Example—Morgan Stanley, an investment bank and financial services company, partnered with Local Initiatives Support Corporation (LISC), a national CDFI, and the Kresge Foundation to create the $200-million Healthy Futures Fund (HFF), which supports financing of community health centers and affordable housing in underserved areas. So Others Might Eat (SOME), a nonprofit community development corporation, used funds from HFF to develop the Conway Center in Washington, DC, which provides homeless families with affordable housing, a health center, and job training—all adjacent to a transit station.

### 4 Measure Performance Using Meaningful Indicators of Community Health and Well-Being

Many companies have key performance indicators to evaluate performance in major areas of business operations. Consider whether your company’s performance metrics can be improved by including community health indicators.

■ Ensure that philanthropic giving strengthens community health and economic prosperity. Businesses can help to ensure that their charitable contributions benefit the community by focusing their investment portfolios and holding themselves accountable for outcomes.
  Example—To spur job creation in struggling communities after the Great Recession, Starbucks collaborated with the Opportunity Finance Network on an initiative called, “Create Jobs for the USA.” By carefully measuring and reporting loans made and jobs created or retained, Starbucks was able to assess the impact of its investment on communities.
■ Redefine productivity in the value chain to include the economic costs from societal problems. Societal problems create economic costs in a company’s value chain. Addressing problems in the value chain—for example, by using resources more efficiently or implementing stronger employee health and safety protections—can optimize productivity and benefit both business and society.
  Example—Hyatt Hotels and Bank of America each recognized the costly societal issue of young people being disconnected from education and employment. To successfully transition to employment, these individuals required additional training and support. By refocusing HR resources and supports and partnering with a nonprofit organization, both businesses were able to recruit and retain this untapped young talent. Monitoring inputs, outputs, and outcomes over time demonstrated the return on investment to the companies and the potential societal impact.
■ Align wages, salaries, and benefits with the needs of a healthy, equitable, and prosperous society. A job can be one of the most fulfilling aspects of life, bringing meaning and purpose to employees and their families. But jobs can also be dangerous, demoralize workers, and keep workers and families in poverty. Improving wages, salaries, benefits, and working conditions can turn an arduous and repetitive job into an opportunity and a livelihood.
  Example—The Wonderful Company, an agricultural company, recognized the value to people, community, and company of providing a $15 minimum wage to its farm workers. The more robust wage structure helps workers and their families meet basic needs for housing, healthy food, transportation, and quality childcare.
■ Create shared value for companies and communities by combining social purpose with business opportunities. Shared value happens when profitable business strategies produce real societal benefits. Business can uncover these opportunities by choosing to help solve a particular social problem and doing so in a way that creates or augments a business opportunity.
  Example—First Step Staffing is a social enterprise providing employment services for people transitioning from homelessness, including veterans and formerly incarcerated individuals. It serves business clients in need of reliable staff, is itself a successful business, and welcomes investments from other businesses as it grows. A more diffuse example is Intel’s investment in education, especially building the computer and technology skills of students and teachers across the country and around the globe, which further develops the market for Intel products.

As a powerful force for good, businesses have multiple opportunities to increase the health, wealth, and well-being of people and places, especially those that are not thriving; to expand business opportunity; and to increase business and societal value. These recommendations offer opportunities for business, working together with others, to more purposefully embrace their role as stakeholders in a society that works for everyone. With growing awareness of interdependence, greater engagement of all stakeholders, and an alignment of business earnings and societal gains, such partnerships and investments can ripen into healthier people and communities, a more equitable and just society, and a sustainably prosperous economy upon which everyone depends.

## GRADS OF LIFE: Helping Businesses Build a Talent Pipeline

| Community Challenge \| Before the coronavirus outbreak in spring 2020, an estimated 3 million young people (7.6%), 16- to 24-years of age, were not working and not in school. Known as “opportunity youth,” these young people are driven, motivated, and ready to work. But they often juggle many responsibilities, lack access to professional networks and higher education, and may be overlooked by traditional hiring methods. Although opportunity youth are an untapped talent pool of young adults, business managers must manage differently to attract and support the success of opportunity youth. Grads of Life helps managers seize these opportunities.
| Scenario \| Elyse Rosenblum has been in the business world long enough to know that many people equate a college degree with having credible skills for employment. She also knows that young adults without college degrees have tough times landing good jobs. Rosenblum founded Grads of Life, a national organization based in Boston, Massachusetts, to close this opportunity divide. Grads of Life works with employers and businesses to hire young adults without postsecondary credentials. “We bucket our work into two big categories,” Rosenblum said. “One is changing how employers think about opportunity youth and young adults without 4-year degrees as a valuable source of talent, and the other is changing their business practices to reflect that.” Rosenblum and her team designed a process that helps employers diagnose barriers to hiring and develop and deliver scalable and sustainable solutions to recruit, hire, and retain opportunity youth.; Small and large businesses are interested in opportunity youth as potential employees, but the reality is that frontline managers often fall short when working with this group of youth. “You can have a great initiative and successfully roll it out,” said Rosenblum. “But if the person interfacing with the talent is not prepared and supported in understanding how to retain and advance people who may not have been in that work environment, things tend to go awry.” This is one of many hiring difficulties that Grads of Life addresses for employers.
| Action Taken \| Recognizing patterns where the employment journey falls apart for opportunity youth, Grads of Life developed tools and made them widely available to employers. Grads of Life codified principles and practices around what it means to be a good opportunity employer, and then launched Opportunity Navigator (OPT-N). Built around five principles, OPT-N provides individualized recruitment, hiring, and retention blueprints for employers.; The first two principles of OPT-N set the stage for employers to organize their own internal affairs: articulating a commitment to inclusion and respect and having a data-driven opportunity employment strategy. “Employers may try innovative practices and pilots,” Rosenblum said. “But they are not necessarily tracking the pilot data to their norm to know whether they are getting a return on their investment.” Often the problem is that pilot champions do not have access to human resources data.; The third principle of OPT-N focuses on being proactive and intentional around the recruitment of opportunity youth. This means partnering with community organizations to source talent and offer work experiences, such as apprenticeships. Additionally, removing the requirement of a 4-year degree for entry-level and middle-skilled jobs also removes barriers to employment. The fourth and fifth principles of OPT-N focus on practices for employers after they have opened the door to opportunity youth: providing livable wages and benefits and offering career development to grow in the job.
| Key Takeaway \| Opportunity youth are an available, capable, and motivated pool of talent that is often overlooked in the workforce. Companies can leverage the talent of opportunity youth by implementing hiring strategies that create diverse and inclusive talent pipelines. Grads of Life continues to develop innovative tools and resources that help companies meet their hiring needs and remove employment barriers for opportunity youth. By investing time and resources to hire, develop, and retain talent from the communities they serve, companies can increase their community engagement and enhance their bottom line.