# CHAPTER 7 A Way Forward for Community Health and Economic Prosperity

## OVERVIEW

The health status of American workers and participation in the labor force have been declining for decades. Businesses can play an important role to reverse this trend by simultaneously expanding community health and economic prosperity. This chapter outlines a path toward a well-being economy that can reverse poor health outcomes and sustain hard-won gains. The path is built on business engagement with stakeholders to produce shared value, working together as stewards of health, wealth, and well-being in a common world.

KEY TAKEAWAYS

➤ Businesses and employers are stakeholders in their communities, and communities are stakeholders in businesses.
➤ To enhance community health and economic prosperity over the long term, businesses may choose to
  ■ Produce goods and services and operate in ways that expand the vital conditions that all people and communities require;
  ■ Create shared value for companies and communities by combining social purpose with business opportunities; and
  ■ Engage all stakeholders to achieve the best long-term value for those upon whom business success depends (i.e., stakeholders).
➤ Businesses of all types and sizes can execute one or more of seven concrete business strategies in the short term to engage with and invest in communities. Businesses may select the engagement and investment options that best suit the needs of their stakeholders and their business.
➤ Given the powerful role of business in the United States, even sweeping efforts to strengthen and sustain community health and economic prosperity will not be sufficient without associated actions by business.

## Introduction

To begin to address the U.S. health disadvantage (Chapter 1) and to strengthen communities to support vibrant employees, families, and residents (Chapter 2), businesses and employers must act to ensure a sustainable and equitable capitalist democratic future for themselves and for society.

Businesses and employers are stakeholders in their communities and also serve communities as one of the many stakeholders whose interests they seek to enhance as they strive to prosper (Chapter 3). In collaboration with community changemakers (Chapters 4–5), businesses have opportunities and responsibilities to create shared value (i.e., value for the business and the community), join with others to effectively steward systems (e.g., healthcare systems, service delivery systems, governmental policy making systems, tax and regulatory systems, banking and financial systems, ecological systems) in the interest of thriving communities and people and to produce prosperous business environments. Businesses have opportunities and responsibilities to do well by doing good, and to nurture systems to better align private value and public good to the benefit of all.

Americans know a great deal about what it takes to expand health, wealth, and well-being on a massive scale. Across the country and around the world, modern innovations have done more to add years of healthy life and lift millions of families out of poverty over the past two centuries than in the previous 19 centuries combined. But even after such impressive progress, all is not well. Past advances are insufficient, and many problems are getting worse. Hard-won gains remain fragile or are reversing; whole groups of people have been harmed or left behind while others have benefitted (see Box 7.1); and responses are slow to an increasingly complex set of intertwined threats that endanger both people and planet—and therefore, profit. As noted in Chapter 1, life expectancy in the United States is barely recovering from a downturn not seen since World War I, and for the first time in U.S. history, members of today’s youngest generation may not live longer, more prosperous lives than their parents.

BOX 7.1 LEGACIES OF UNTAPPED POTENTIAL

Most modern achievements have not benefitted everyone in the United States. Many advantages have been systematically denied to certain groups. For example, while racial segregation has been illegal for 65 years, America’s public education system continues to produce substantial disparities in educational achievement, largely driven by residential segregation and racial/ethnic differences in family socioeconomic resources. Such differences leave harmful effects on health and prosperity over generations.

Virtually every achievement in the modern era has been diminished by stark differences between those who benefit and those who do not. For example, although women make up an increasing share of the labor force and a majority of college graduates, they are underpaid, underrepresented in senior-level positions, and less likely to be members of boards of directors relative to men overall and men with similar education, experience, and work performance. African Americans, Hispanics, American Indians, and Alaska Natives of both sexes are underrepresented and undervalued in the workforce to an even greater degree relative to White men. Times have changed for many people, but a vast amount of human potential remains untapped that could contribute to full and fair inclusion for everyone in America.

## Businesses as Creators of Sustained Value

All people depend on vital conditions to reach their potential for health, wealth, and well-being (see Chapter 1, Box 1.1 and Table 7.1). However, these vital conditions are not shared equitably and are currently under threat in many communities across the country, as well as for future generations. Businesses, in partnership with others, can play a profound role in securing these vital conditions, which in turn would reverse the U.S. health disadvantage and help to ensure the fair opportunities that businesses and society need to survive and thrive. Businesses can (a) produce goods and services and operate in ways that expand the vital conditions that all people and communities require; (b) create shared value for companies and communities by combining social purpose with business opportunities; and (c) engage all stakeholders to achieve the greatest long-term value for all those upon whom business success depends. Each of these, alone and together, would enhance community health and economic prosperity. Businesses can integrate these activities into their business operations. Doing so, this report argues, will help businesses compete more effectively and generate value for businesses and society.

Table 7.1 Outstanding threats to health, wealth, and well-being that require combined efforts to resolve (2020–future)

Vital conditions | Outstanding threats^a^
Basic needs for health and safety | ■ Aging population, caregiver strain; ■ Addiction (tobacco, alcohol, opiates); ■ Adverse childhood experiences; ■ Antibiotic resistance; ■ Hunger, food insecurity, junk food; ■ Physical inactivity; ■ Gun violence; ■ Severe physical illness (heart disease, stroke, cancer, chronic obstructive pulmonary disease, diabetes, obesity, asthma); ■ Severe mental illness (anxiety, depression, dementia, trauma, toxic stress); ■ Emerging infectious diseases, pandemics, genetically engineered pathogens; ■ Lack of health insurance, inadequate care
Life-long learning | ■ Illiteracy; ■ Failing schools, high school dropout; ■ Unaffordable college tuition; ■ Mismatched skills vs. new kinds of work; ■ Inadequate early childhood development; ■ School-to-prison pipeline; ■ Disinformation, pseudoscience
Meaningful work and wealth | ■ Economic inequity, concentrated wealth; ■ Low wages, unfair pay, multiple jobs; ■ Unemployment, underemployment; ■ Poverty; ■ Household debt; ■ Insecure retirement; ■ Workforce automation
Humane housing | ■ Homelessness, unaffordable housing; ■ Residential segregation; ■ Displacement, gentrification
Thriving natural world | ■ Climate catastrophes (flood, fire, wind, drought, heat, cold, species extinction); ■ Pollution (air, water, soil); ■ Unsustainable energy, natural resource depletion; ■ Disconnection from nature
Reliable transportation | ■ Aging infrastructure; ■ Automobile-centric design; ■ Traffic congestion, long commute time; ■ Hazards for health, safety, environment
Belonging and civic muscle | ■ Modern slavery, human trafficking; ■ Racism, sexism, classism; ■ Authoritarianism, fascism, anarchy, lawlessness; ■ Refugee crises, immigration; ■ Violence, especially against vulnerable persons (women, people of color, poor, youth, elderly, immigrants, LGBTQ+, etc.); ■ Loneliness, isolation, distrust, disconnection; ■ Suicide; ■ Bullying, hate crimes; ■ Mass incarceration; ■ Invasion of privacy; ■ Low voter turnout; ■ Government and corporate fraud, ethics violations; ■ War, terrorism

Note: LGBTQ+ = lesbian, gay, bisexual, transgender, and all-encompassing representation of sexual orientations and gender identities.

a Many threats are intertwined, and different people experience different threats in different regions. While they undermine health, wealth, and well-being for everyone over time, the threats almost always inflict greater harm on the most vulnerable groups (e.g., people of color, people in poverty, women, immigrants, and other disadvantaged groups).

Recognizing that “a thriving company requires thriving communities” and that businesses play an important role in addressing shared societal challenges, businesses acting as stewards, creating shared value, and engaging stakeholders can be rewarded with a range of benefits or types of value, including

■ Healthier workers and lower healthcare costs,
  - For example, annual healthcare costs to employers for employees with diabetes are more than $4,000 higher than for employees without diabetes;
■ More productive on-the-job employees,
  - For example, workers who live in healthier communities are more likely to arrive at work on time and have fewer unplanned absences than workers who live in less healthy communities;
■ Greater ability to recruit and retain talent,
  - For example, four business exemplars described in this report (Belden, Inc., Greyston Bakery, Bank of America, and Hyatt Hotels) point to specific community-strengthening strategies that substantially reduce recruitment costs and increase retention rates;
■ Greater brand recognition and more loyal customers,
  - For example, in a Nielsen survey, 66% of respondents said they are willing to pay more for products and services from companies committed to positive social and environmental action; According to a Cone/Porter Novelli study, 88% of consumers would buy from and 66% would switch purchases to a purpose-driven company;
■ Greater profitability,
  - For example, according to one analysis, publicly traded companies with a stated purpose, generous compensation, and quality customer service that invest in their communities and minimize their adverse impact on the environment outperform less values-focused companies by a factor of 10.

Beyond the value that accrues to a company, the societal value, as business investment and engagement become more widely practiced, has the potential to advance the United States closer toward its founding ideals as a land of equality and opportunity. Unlike conventional leaders, those who choose to nurture healthy and inclusive systems—as “system stewards”—tend to think about purpose, power, and resources in distinctive ways:

■ Purpose is larger than oneself or one’s own organization;
■ Power is built and distributed with others, not consolidated; and
■ Resources are invested, not withheld, to create long-term value and to alleviate urgent needs.

Any person or organization can be a steward if they are willing to work with others to create conditions that expand health, wealth, and well-being. In a country as vast and diverse as the United States, stewards work through a mosaic of cultures, corporate climates, and local circumstances that stretch across boundaries and spheres of influence. Leaders and changemakers in business and society work across differences and collaborate with others, including other stewards, to build thriving communities and vibrant economies.

The belief that corporations have no inherent social responsibilities, popularized 50 years ago by Milton Friedman, has since broken down (as noted in Chapter 3), as approaches like social investing and corporate social responsibility emerged in the 1970s and 1980s and as companies became more attentive to metrics and rating systems focused on the environmental, social, and governance aspects of corporate performance. Environmental, social, and governance metrics are becoming more widely reported and examined by investors, consumers, and employees. As illustrated by several exemplars in this report, some businesses recognize—in their role as members of society and as stakeholders in communities—that their own success depends on strengthening the vital conditions on which businesses, employees, customers, and consumers all depend.

In fact, a broad coalition of the world’s largest companies, asset holders, and asset managers (together controlling more than $30 trillion) has publicly declared that all companies must show how they contribute to larger social goals, or risk losing financial support. As the flaws in Friedman’s logic become increasingly obvious, business leaders are repositioning their firms to compete on the basis of how well they generate sustained value for all stakeholders, not just a small group of shareholders. These business leaders could join together to become some of the strongest system stewards, advancing societal good, creating shared value, and meeting the needs of stakeholders.

Some companies are embracing the concept of creating shared value—that is, value gained by the company while serving a community need or solving a community problem (as described in Chapter 6). Specifically, creative and innovative business leaders are seeing business opportunities in achieving social goals and are solving social problems as a means of making money. Whether investing in local entrepreneurs to strengthen and increase efficiencies in local supply chains (thus creating local jobs and strengthening the local economy); establishing pathways to employment for the homeless, the formerly incarcerated, or those without a high school diploma (thus filling critical entry-level positions with career ladders less expensively and with less turnover); or developing a product that meets a community need and earns a profit, some companies are discovering shared value is a win for both business and community.

Although stakeholder theory (described in Chapter 3) is not new, it has sometimes been managed as not much more than a risk mitigation exercise. More recently, companies are recognizing that successful businesses tend to be those that (a) engage with all stakeholders required for the business to exist—employees, customers, vendors and suppliers, the communities in which they reside or conduct business, investors and shareholders, and others—and (b) ensure value for each stakeholder (e.g., Box 7.2). These are companies that integrate stakeholder engagement into business operations and company strategies, ensuring that relevant stakeholders provide input and feedback across all aspects of the delivery of goods and services. Although the goal may be to build a stronger, more successful, and more resilient business, the outcome may be progress toward a more equitable society.

BOX 7.2 PROFILE OF JUST CAPITAL

To build a more just marketplace that better reflects the priorities of the American people, JUST Capital

■ Asks people how they want companies to behave,
■ Rates and ranks firms to show how well they meet expectations, and
■ Offers investments in the most just companies.

Just companies not only make more money (about 6% higher return on equity), they also pay workers better, have safer workplaces, create more U.S. jobs, give more to charity, produce less waste, and yield other benefits.

As with system stewardship and shared value, stakeholder engagement contributes to a more collaborative, networked, and strategic business enterprise and more inclusive, resilient, and sustainable communities, where the interdependence between business and society is embraced and strengthened to mutual advantage.

## Advancing Business Goals by Meeting Stakeholder Needs and Creating Shared Value

Business have taken a variety of actions to improve community health and increase economic prosperity for their own benefit and the benefit of their stakeholders and society at large. This section provides nearly a dozen examples of businesses and the actions they have taken to meet stakeholder needs and create shared value while solving a business problem or securing a return of value to the business.

A common strategy is to consider the needs of the community when solving business problems and choosing and implementing solutions that also strengthen the community. Belden Inc., Greyston Bakery, and Bank of America have taken this approach as they sought to fill job vacancies with dependable employees and discovered a talented source of workers who thrived with an investment of support (see detailed Exemplars about each company elsewhere in this report).

Investing business profits in ways that strengthen communities is a similar strategy. Many communities need affordable housing for employees and families, retirees, and the unemployed; affordable care and learning facilities for young children; and grocery stores.

■ UnitedHealthcare provided a $22-million, low-interest loan to the nonprofit Chicanos Por La Causa to acquire nearly 500 units of rental housing in the Maryvale neighborhood of Phoenix, Arizona. Up to 100 units are set aside for UHC clients at reduced rents and will include vital supportive services. In addition to loan repayment with interest, UHC already sees improvements in client health. Joe Guadio, chief executive office of UnitedHealthcare, said, “We’ve seen emergency department visits reduce considerably. We’ve seen inpatient rates reduce considerably, which is what we’d expect to see. In the aggregate, we’re looking at healthcare costs being reduced by over 50 percent when you compare their cost pre-housing versus post-housing.”

A job can be one of the most fulfilling aspects of life, bringing meaning and purpose to employees and their families. But jobs can also be dangerous; demoralize workers; keep workers and families in poverty; and offer few, if any, opportunities. Improving wages, salaries, and benefits can turn even an arduous and repetitive job into an opportunity and a livelihood. Businesses are using this strategy to align business success with the needs of a healthy and prosperous society.

■ The Wonderful Company, an agricultural company based in California, sought an effective intervention to improve the lives and health of its employees and their families. Their solution: a $15 minimum wage. The company implemented this wage increase for all employees earning less than $15 per hour and created tiered increases for those making more than $15 per hour. By instituting a wage structure that helps workers and their families to meet basic needs for housing, healthy food, transportation, quality childcare, and recreation, The Wonderful Company anticipates healthier workers, lower turnover, and stronger communities.

“This substantial investment [in wage structure] in our workers will have an immediate and meaningful impact on their lives. In addition to providing our Central Valley employees and their families free healthcare and education, we are now able to help them achieve a significantly improved standard of living.”

—Lynda Resnick, Vice Chairperson and Co-Owner of The Wonderful Company

■ American Express, with a workforce about two-thirds younger than 35 years of age and about two-thirds female, knew it would have to strengthen its benefits package to attract and retain the best workers. The company implemented a policy that includes 6–8 weeks of maternity leave and 20 weeks of parental leave, adding up to about 6 months of paid leave for a new mother. American Express expects this benefit to improve its abilities to recruit and retain talented employees. Through this policy, American Express is also investing in the next generation of employees.
■ Patagonia^®^, a maker of outdoor gear, provides on-site child development centers (and subsidizes tuition for parents who are employees) at its headquarters in Ventura, California, and distribution center in Reno, Nevada. For children, quality early childcare can have positive social and health impacts that last into adulthood; parents can work and earn wages knowing their children are in good care. Patagonia calculates that, although expensive, this investment is almost fully recouped through federal tax benefits and higher employee retention and engagement. Caring for its employees in this way promotes better health in the long run—a win for the company, employees, and families.

Businesses can strengthen communities in need by supporting vendors and suppliers from local and distressed communities. Focusing on the needs of local communities and investing in small businesses and entrepreneurs who may have difficulty accessing capital, can help businesses solve supply-chain problems while helping to create jobs, build wealth, and support businesses locally.

■ Prudential Financial takes its community stakeholder role seriously in its hometown of Newark, New Jersey. The company more than doubled its purchasing from local businesses; built a new headquarters in Newark; kept 5,400 jobs in the city; and invested in pathways to employment for young people in the community. Prudential Financial is committed to “spreading economic and social opportunity across the city, creating meaningful and lasting change.”

Businesses may choose from a variety of enterprise design options, from for-profit and nonprofit corporations and limited liability companies to cooperatives and employee ownership structures. Some structures can be more beneficial to stakeholders and communities than others.

■ King Arthur Flour, founded in 1790, before Employee Stock Ownership Plans (or ESOPs) and B Corporations existed, has always been committed to stewardship, community, and its employees. As the fifth-generation owners considered how to sustain the company’s quality, mission, and values over time, selling the company to employees was an obvious solution. Employee ownership confers value to society, ensuring the company remains invested in its community and broadening and deepening local prosperity by sharing wealth with those who help create it.

Many businesses engage in philanthropy as a way to strengthen communities and strengthen business–community relationships. But not all businesses expect their philanthropic investments to deliver outcomes in the same way as they expect their business investments to do so. Businesses can help to ensure that their charitable contributions benefit the community by focusing their investment portfolios and holding themselves accountable for outcomes.

■ JPMorgan Chase aligns its philanthropic and business goals to deliver both community value and business opportunity. Its $500 million investment in Detroit and other distressed cities is half philanthropy and half low-cost lending, with a goal of enhancing inclusive growth (i.e., equitable growth across all races/ethnicities and income levels) for the business and the community. The philanthropy focuses on building jobs, skills, and financial health for workers; expanding small businesses; and revitalizing neighborhoods, and the bank develops and serves new markets in need of banking services, including the new Entrepreneurs of Color Fund, which provides low-cost loans to minority-owned business and start-ups.

Businesses are stakeholders in their communities and states and in the nation. As stakeholders, they are powerful advocates for advancing business interests. By turning their attention to advancing the laws, policies, and practices that strengthen vital conditions and expand health, wealth, and well-being for all, businesses can reinforce their roles as stewards and stakeholders and contribute to the improvement of community health and economic prosperity.

■ Greater Kansas City Chamber of Commerce coordinated activities across numerous local businesses in the Kansas City metro area in support of “Tobacco 21,” an initiative to raise the minimum age for purchase of tobacco products from 18 years of age to 21 years of age. Because of the coordinated approach, the policy was enacted in 22 jurisdictions in the metro area at the same time, which facilitated effective enforcement and promises to contribute to reductions in tobacco use across the metro area over time. Business engagement was based on the recognition that tobacco use among employees and families is a leading driver of healthcare costs and contributes to lower productivity on the job.

In these and other ways, businesses have acted to meaningfully increase economic opportunity and equitably improve the health, wealth, and well-being of communities, employees, and families.

## Unlocking America’s Full Potential

Individuals and families must always make personal choices about health, wealth, and well-being. These decisions are based on personal and familial motivations and on the options available in the surrounding community. Those options, in turn, are shaped by the combined activities and influences of government, business enterprise, and the community. That is why efforts to expand health, wealth, and well-being require collaboration and every stakeholder doing their part.

Given the central role and resources of business in the United States, even sweeping efforts to reframe narratives, redefine rules, redirect resources, and implement new public policies and practices may not be enough to create social change without associated changes in business. The kind of large-scale socioeconomic change needed to address the U.S. health disadvantage requires the support and collaboration of business. The business sector offers a powerful route to social change.

### Toward a Well-Being Economy

Despite an expansion of the modern American economy, happiness has remained flat or eroded. The problem is that markets often reward products that undermine health and well-being and do not place enough value on the vital conditions that actually enhance feelings of freedom, security, justice, connection, and self-determination. To get those benefits, values for health, wealth, and well-being must be brought into the market.

“… [A well] run, values-centered businesses can contribute to humankind in more tangible ways than any other organization in society.”

—John Mackey

Other nations have reached a similar conclusion and are transitioning toward a “well-being economy.” For example, in 2018, New Zealand introduced the world’s first national well-being budget backed by a detailed living standards dashboard. Focused on advancing the health and life satisfaction of its citizens, in addition to economic growth, the Government of New Zealand expects to use these tools to more effectively address the needs of the country’s citizens.

Some businesses, corporations, and capital markets are beginning to work more purposefully for the well-being of people and planet (as a way to enhance their own profit). In conventional competitive capitalism, corporate executives are caught in constant tension. They must make as much money as possible—as quickly as possible—for shareholders (who are often mistakenly portrayed as the only true obligation for companies), while also satisfying the interests of other stakeholders (including customers, employees, supply chain partners, communities, and even the natural environment) whose cooperation they require to be successful.

Regarding the new corporate imperative, “[p]rofits are in no way inconsistent with purpose—in fact, profits and purpose are inextricably linked.”

—Larry Fink, CEO, Blackrock

That balancing act can feel impossible, but it becomes irrelevant when a business’s or corporation’s purpose is to generate sustained value for all stakeholders over time. Under that theory (Chapter 3), the most competitive companies are those that deliver the best long-term value for their stakeholders. Shareholders profit when a company consistently meets the goals and needs of all those with whom it does business and on whom the business depends. In other words, “investing is for people in place, with profit the result, not the primary aim.” Balancing people, place, and profit is a tilt toward a well-being economy.

A list of people’s goals and needs might begin with the vital conditions. All people and organizations have vested interests in expanding the vital conditions because lives, livelihoods, and a sustainable and equitable prosperity depend on them. The achievements in Figure 7.1 affirm the possibility of making gains in every area; and the threats in Table 7.1 make clear that such gains are fragile and not universally distributed.

Each vital condition requires care to be sustained for current and future generations. If success in business depends on fulfilling an important social purpose and requires inputs of labor, talent, and supplies and of customers to purchase goods and services, then companies everywhere would be wise to channel their ingenuity and investments toward expanding one or more of the vital conditions, without excluding anyone. Any shortfall represents untapped human and economic value (Table 7.2). The best companies would devote themselves to this work as if their survival as a business—and ours as a people—depend on it.

### The Future in Three Possibilities

America’s future holds both promise and uncertainty. Figure 7.2 shows the relative trajectory of three possibilities (or pathways) that could play out over time. Each possibility has different near- and long-term consequences. Table 7.3 summarizes the main features of each.

Table 7.2 Businesses can benefit from strengthening vital conditions for all

Business priorities | Benefits from expanding vital conditions
Just behavior and sustained long-term value | ■ Greater ability to generate long-term value; less short-termism; ■ Greater ability to meet public expectations and accountabilities (i.e., practices related to workers, customers, products, environment, jobs, communities, company leadership, and shareholders)
Profitability | ■ Higher demand for healthier products and services; ■ Greater productivity from a healthier workforce and customers; ■ Lower absenteeism, presenteeism; ■ Less stress and addiction; ■ Greater funding for research, innovation, research and development; ■ Lower direct and indirect expenses (due to less demand for acute care for illness and injury, addiction treatment, criminal justice, environmental cleanup, homeless support, unemployment, and food assistance)
Safety | ■ Safer products and services; ■ Fewer workplace injuries, disabilities, and worker compensation claims; ■ Fewer lawsuits and liability expenses
Human capital | ■ More talented, literate, and resilient workers (current and future); ■ Competitive advantages from workplace equity, diversity, and inclusion; ■ Greater employee ownership and equity stake in business success; ■ Higher morale, job satisfaction, retention, and promotion; ■ Better match between jobs and skills (especially science, technology, engineering, arts, and mathematics), and greater flexibility to changing circumstances; ■ More stable succession planning, leadership transitions; ■ Lower costs for recruitment, retraining; ■ Greater retirement security
Sustainability | ■ Less waste; ■ Less costly, more reliable sources of renewable energy and other resources; ■ More efficient movement of goods and services; ■ Safer, more dependable transportation infrastructure; ■ Closer proximity between jobs, housing, food, transportation, and recreation; ■ Fewer violations of environmental protections
Reputation | ■ Stronger sense of community and connection as good corporate citizens; ■ Stronger network of supply chain partners; ■ Greater transparency, trust, and confidence in corporate governance; ■ Fewer scandals, less risk to intangible assets; ■ Greater potential to negotiate and resolve policy disputes; ■ Greater potential for public–private partnerships

Figure 7.1 Shifting prominence and landmark achievements in public health and healthcare, 1800–2008

^a^ Relative prominence reflects the frequency that each term appears in writing over time.

^b^ Many of the landmark achievements are not unqualified goods but entail risks or tradeoffs of their own.

From 1800 to 1900, the prominence of public health increased slightly but steadily over time as a result of achievements in sanitation, safety, surveillance, epidemic detection and control, abolition of slavery, nondiscrimination, voting rights, human rights, and civil, rights. However, from 1900 to approximately 1950, prominence of public health increased dramatically as a result of the aforementioned achievements, as well as achievements in libraries, pre-K and K-12 education, college and vocational training, automobiles, highway and rail systems, mass transit, conservation of parks and nature, social security, minimum wage, 40-hour work week, tax policies, home ownership, outlawed redlining, and subsidies. The prominence of public health remained steady throughout the latter half of the 20th century as a result of all aforementioned achievements, as well as achievements in vaccines, immunizations, fluoridation, reproductive health, tobacco control, cleaner air, cleaner water, and cleaner energy. The prominence of healthcare was very low from 1800 to the mid-1900s. The prominence of healthcare increased rapidly and dramatically in the latter half of the 20th century as a result of achievements in biomedical training and funding, healthcare insurance, antibiotics, DNA and genomics, transplants, prosthetics, replacements, drugs, devices, implants, procedures, and diagnostic imaging.

The first possibility continues the status quo by focusing on discrete problems and short-term gains and managing immediate obligations. The third possibility requires embracing new ways of doing business in pursuit of a visionary future that will take decades to emerge. The middle (or second) option moves away from the fragmented, transactional, and divisive conditions of today and moves closer to the equitable, productive, and just possibility in the future. This second possibility is both attainable and transformative. It focuses on improving the health of communities and increasing economic prosperity—equitably, commensurately, and inclusively.

Figure 7.2 Three options for expanding health, wealth, and well-being

As popularity of defining norms increases, fragmentation (business as usual) decreases over time; system stewardship (bridging innovations) increases, peaks, and then decreases over time; and interdependence (viable future) increases over time.

As the coronavirus pandemic of 2020 has demonstrated, threats to health are threats to the economy. The two are highly interdependent, and both must thrive together if either is to be strong. The current state is ineffective, inequitable, and inefficient for all parties. To move beyond the status quo requires stepping up to the second option as engaged stewards to expand health, wealth, and well-being together. In this possibility, a widening network of entrepreneurs, elected officials, community leaders, developers and changemakers, business leaders, and everyday people devise new ways to expand the vital conditions, especially among people and places that have been left out and are suffering, thus reversing the U.S. health disadvantage. As these endeavors become more common, the complexion of the U.S. economy and democracy changes such that everyone belongs and can contribute, and the interdependence of business and society is embraced.

More work, stronger partnerships, and greater collaboration across the public, private, and nonprofit sectors would be needed, over generations, to achieve the third possibility, where self-destructive struggles over who gets how much of a fixed pie finally give way to productive working relationships that simultaneously grow the pie and give everyone a fair chance to participate in a thriving commonwealth.

Table 7.3 Features of the three options for expanding health, wealth, and well-being

Features | Option 1: Fragmentation | Option 2: System stewardship | Option 3: Interdependence
Focus | Separate problems (diseases, body parts, issues, industries) | Connect clusters (community health and prosperity) | Underlying ambitions (equitable health, wealth, and well-being)
Objective | Short-term gain | Long-term value | Directed futures
Forum | Marketplace | Networks | Commonwealth
Investments | Uncoordinated, underfunded programs | Sound strategy and integrative activities | Next system design^a^
Exchanges | Transactional | Transformative | Adaptive
Politics | Divisive | Inclusive | Productive
Equity | Haves and have-nots | Belonging and civic muscle | Fair and just inclusion

a For more information about next system design, see The Next System Project.

The examples of companies and communities presented in this chapter and throughout this report describe discrete actions to move beyond the status quo of Option 1 and through the intermediate improvements of Option 2, en route to a future state of interdependence and mutuality (Option 3) where everyone has a fair chance to participate and thrive. Chapter 4 presented rich examples of businesses and organizations—public, private, and nonprofit—working with community development and community finance to invest in and develop people and communities, especially those that are not thriving, using concrete policies, tools, and know-how to help solve some of the barriers and challenges that hold back people and communities. Although the work is inspiring and the tools are effective, the scale is too modest to transform our world and launch us into a fully inclusive and prosperous future (as noted in Chapter 4). Add in the enhanced power of business to nurture and strengthen people and communities they themselves depend on to thrive over the longer term, and the pathway to a healthier, wealthier, and more prosperous future—together—comes into view. Adopting new models of business enterprise, designed for the 21st century, including stakeholder engagement, shared value initiatives, and system stewardship, can help tackle the problems that current enterprise models have fostered, such as income and wealth inequality, environmental harm, and the U.S. health disadvantage. Current models reinforce the status quo and stand in the way of community health and economic prosperity.

“We earn our profits from society and they should go back into society.”

—Shubhro Sen

## Conclusions

Three pathways present alternative futures that carry high stakes—for us, our children, our businesses, and our world. The choices are stark, but no one needs to act alone or start from scratch. No matter the situation, there are opportunities to rethink past practices and connect with others who are ready to do business differently—together. Innovators and changemakers today can write the next chapter in American history by dispelling illusions of separateness and replacing them with experiences of interdependence. That shift alone could help to unlock health, wealth, and well-being on a greater scale.

To harness those opportunities, governments cannot dictate the way; doctors cannot prescribe a quick fix; and businesses cannot stand on the sidelines or engage only in philanthropy. All efforts—as individuals, institutions, and industries—must combine in new ways if society wants to survive and thrive in a rapidly changing world. Fortunately, even amid despair and division, leaders across the country are stepping up as engaged stewards and forming new partnerships with stakeholders and changemakers, precisely because they want to accomplish results that cannot be accomplished alone and that produce benefits across people and communities. This trend is relatively young, and many partnerships are not yet as mature as they need to be. With a growing awareness of interdependence, greater engagement of all stakeholders, and stronger alignment of business earnings and societal gains, such partnerships and investments can ripen into healthy communities and a more sustainably prosperous economy, upon which all people depend.

When faced with uncertain futures, business leaders and community changemakers of today may be best poised to rely on a proud tradition of American pragmatism—knowing that the best way to predict the future is to create it, together.

APPENDIX A TOOLS AND RESOURCES

Appendix A identifies tools and resources addressing topics explored in Chapter 7. The tools and resources were created by such businesses and organizations as Business for Social Responsibility, Harvard Business School, Institute for Local Self-Reliance, Massachusetts Institute of Technology, and others.

## BANK OF AMERICA: The Path to Participation

| Community Challenge \| Companies need employees who understand their customers, but competition for talent is steep. How can companies recruit and retain employees who can effectively serve their customers?
| Scenario \| Headquartered in Charlotte, North Carolina, Bank of America (BOA) is a financial institution that serves individual consumers, small- and middle-market businesses, and large corporations. Many BOA financial centers conduct business in low- and moderate-income communities.; As demographics change in communities across the country, BOA wants to ensure that its labor force remains responsive to the needs of low-income communities. BOA builds its business on client relationships, so it needs employees who understand the financial challenges customers face. “BOA is keenly focused on recruiting, developing, and retaining talent,” said Jennifer Andrew, senior vice president of The Academy.^8^ “Not just hiring but seeking talent for meaningful and sustainable long-term careers.”; 8 The Academy is BOA’s coaching and development organization dedicated to the success of every employee.; As the United States climbed out of the Great Recession, BOA’s leadership grew concerned about future hiring and the prospect of losing employees in a tight labor market. There is a cost to hire and retain employees. BOA was an active recruiter at colleges and universities, but many employment opportunities were not being filled. How could BOA find good employees?
| Action Taken \| Looking for answers in early 2018, BOA managers started digging through data around open positions and applications. They discovered they were often not recruiting from the communities where jobs were available, and many positions at BOA did not require a college degree.; “We began reaching out to community partners to provide better perspective on the opportunities BOA offered and the skills we are seeking,” Andrew said. “We wanted people to realize that Bank of America has job opportunities for people with all different educational backgrounds.”; Andrew and her team at BOA launched the Pathways Program in 2018. Through this program, BOA is committed to hiring 10,000 people from low- to moderate-income neighborhoods by 2023. “As part of Pathways, we increased our recruiting from nonprofit partners who provide professional skills training,” Abigail Hollingsworth, senior vice president, BOA Foundation, said. “We found that nonprofits differ from one market to another, so we have to take a very localized approach to find organizations that are preparing talent for the jobs we have available.”; By the end of 2019, BOA employed 80% of new employees hired through the Pathways Program, and some of them had even been promoted. BOA also learned a lot about low- to middle-income workers. These learnings made BOA a better employer of all employees and prepared managers to be sensitive to the many hurdles employees face every day (e.g., problems finding professional attire, care for children, and transportation to and from work). Managers were given the flexibility to remove obstacles to successful employment. In 2020, BOA increased its minimum wage to $20 per hour. As a result, entry-level employees have more financial security than employees in similar roles at other companies. “By hiring from the communities we serve and helping our teammates develop their careers at the bank, we are helping our clients—and employees—lead better financial lives,” Andrew said.
| Key Takeaway \| By thinking differently about where to recruit talent, BOA discovered a group of potential employees capable of working in the financial industry. BOA now provides livable wages and financial literacy to employees who in turn can teach better money habits to their friends and neighbors in the communities in which they live and work.