# CHAPTER 6 Data Steps for Businesses and Partners to Address the U.S. Health Disadvantage and Monitor the Business Impact

## OVERVIEW

Businesses can use a data-driven approach to improve health and economic prosperity among employees and broader communities. Based on an environmental scan of validated outcome measures, this chapter explores processes and measurements that help businesses develop programs and policies to foster health and prosperity, with a focus on those most in need.

KEY TAKEAWAYS

➤ Businesses use data for their operations but often overlook the use of data to understand the impact of their business on the health, wealth, and well-being of employees, customers, and communities.
➤ A data-driven approach to community engagement and investment
  ■ Can help businesses identify strategies that (a) create a healthier workforce and more prosperous communities and (b) monitor their progress in achieving specific outcomes; and
  ■ Offers businesses and employers a pathway to make broader improvements and measure their contributions and returns in the context of the larger ecosystem of communities and society.

## Introduction

As the coronavirus pandemic of 2020 has made abundantly clear in the United States, business-as-usual is no longer an option. The solution to the U.S. health disadvantage—a disadvantage exemplified by the spread and lethality of the virus and exacerbated by unprecedented job losses (and the loss of employer-provided health insurance)—lies in expanding equitable health, wealth, and well-being for all people and places across America. Although some people were averse to the idea of shutting down parts of the economy in order to protect health, others saw an opportunity to strengthen health and the economy together. For businesses that are ready to invest in communities, this report recommends a data-driven course of action to rebuild community health and economic prosperity in the United States in ways that are good for business and good for the whole of society.

Although businesses are used to using data to inform and track their operations, they often overlook the use of data to better understand the impact of their business on the health, wealth, and well-being of their employees, customers, and communities and fail to use data to identify the best opportunities and strategies and to monitor their progress. Box 6.1 provides an example of using data to identify supply and demand for early child education, by neighborhood, to best seize business opportunities and meet consumer demand.

BOX 6.1 USING DATA TO EXPAND HIGH-QUALITY EARLY CHILDHOOD EDUCATION

Fund for Quality (FFQ) was launched in Philadelphia as an effort to expand quality childcare options in areas that are undersupplied. FFQ is a partnership between Reinvestment Fund and Public Health Management Corporation (PHMC) with support from the William Penn Foundation and the Vanguard Strong Start for Kids Program™. FFQ works to ensure that every child—no matter what neighborhood they live in or where their family works—has access to the best possible start in life through a high-quality early childhood education.

FFQ’s strategy is to invest in projects that increase the availability of high-quality childcare in the areas of the city where data show it is most needed. FFQ offers business planning support and facilities-related funding for the renovation of existing centers or expansion to new facilities. The high-impact investments are based on a neighborhood-level analysis developed by Reinvestment Fund. The analysis identifies the gaps between the supply and demand, neighborhood by neighborhood. FFQ then targets investments that give more children the opportunity to get the high-quality early childhood education needed for a strong start. FFQ’s strategy is driven by accurate information about unmet need in the community. Reinvestment Fund is replicating this model in Atlanta.

With additional support from the Vanguard Strong Start for Kids Program and Public Citizens for Children and Youth, Reinvestment Fund is expanding its analysis to provide more granularity on infant and toddler care—the time when important brain development takes place. Vanguard, an investment advisor based in Malvern, Pennsylvania, is increasing its childcare support by working with Reinvestment Fund and PHMC to create financial tools and resources for early childhood education providers to improve their financial stability and guide business decision making. Known as the Early Childhood Education Fiscal Hub, the program allows providers to compare themselves to their high-performing, high-quality peers and to use those benchmarks for their own operations planning and budgeting decisions. Thanks to this robust collaboration, more children in Philadelphia will get the safe, healthy, and engaging care they need and deserve during the most critical stage of their lives.

Businesses generally have not adopted a consistent process to integrate health measures into their core planning processes. Some possible reasons include a lack of consensus about what to measure and how to measure it, and whether investing in health, wealth, and well-being improves the bottom line and leads to a return of value. What does help: simplicity, connection, and rigor in the data businesses collect and the outcomes they choose to measure. A data-driven approach can help businesses identify strategies that create a healthier workforce and more prosperous communities and to monitor their progress in achieving specific outcomes.

Businesses are already using data to identify the needs and best interventions to improve employee (people) and community (place) health and well-being, and to monitor progress in doing so. Common uses of data by businesses include (a) understanding the health and well-being of people an employer is associated with (e.g., using Health Risk Assessments for employees and their families, and mapping data to understand the communities in which they do business); (b) selecting populations to work with or health conditions to address to improve employee health (e.g., mental health); (c) establishing measures to assess short-term impacts of improvement initiatives (including anecdotal evidence and quantitative measures); and (d) measuring system, workplace policy, and culture changes (e.g., HERO Scorecard and the WELCOA Checklist).

“What a society chooses to measure will in turn influence the things that it seeks. If a society takes great effort to measure productivity, people in the society are likely to focus more on it and sometimes even to the detriment of other values. If a society regularly assesses well-being, people will give it their attention and learn more about its causes.”

—Centre for Bhutan & GNH Studies

Several organizations help businesses analyze data in a place-based way (e.g., Geographic Information System [GIS] mapping and HERO Culture of Health). Businesses are using these data to

■ Map the value chain and understand total value or total return on investment of a set of initiatives (e.g., Shared Value Initiative, and Sustainability and Health Initiative for NetPositive Enterprise);
■ Develop a balanced portfolio of strategies to improve employee, community, and system well-being (e.g., Pathways to Population Health);
■ Measure impact over the short-, medium-, and long-terms using process outcomes related to specific initiatives (e.g., 100 Million Healthier Lives); and
■ Understand the overall impact on population health and well-being across people and places (e.g., Well Being In the Nation measures).

These emerging strategies expand the playbook for action to align with a broader array of core business practices and extend beyond employee benefits, which have been the historical provenance of wellness programs. One such strategy, the Shared Value Initiative, focuses on the following:

■ “Reconceiving products and markets: Meeting societal needs through products and addressing unserved or underserved customers
■ Redefining productivity in the value chain: Changing practices in the value chain to drive productivity through more efficient use of resources, employees, and business partners
■ Enabling local cluster development: Improving the available skills and supplier base and supporting institutions in communities where a company operates to boost productivity, innovation, and growth.”

Pathways to Population Health (P2PH), developed through 100 Million Healthier Lives and adapted as part of Well Being In the Nation for Business, brings these three types of action together in a connected strategic approach to improving the well-being of people and place, with a focus on those most in need. This framework supports employers to improve the health and well-being of people they directly reach (customers and employees) by improving their mental, physical, social, and spiritual well-being and the well-being of places the business relates to (in terms of location, operations, and customer base) through focused action addressing vital conditions. Importantly, P2PH focuses on ensuring resources are mobilized for those who aren’t thriving, both as a priority for businesses and an opportunity to unlock human, community, and economic potential.

The Well Being In the Nation or “WIN” framework, which was released in 2019, and its associated measures, which were developed with support from the National Committee on Vital and Health Statistics with more than 100 organizations, businesses, and communities, is organized around nine core measures related to people and place and focused on those who are not thriving. The P2PH and WIN frameworks offer businesses new opportunities and strategies to enhance their impact using levers already available to them. (See Appendix B for more information on these frameworks.)

## Five Steps to Identify Measures That Matter

Below is an implementation strategy for businesses seeking to create a practical and strategic measurement plan to identify and understand the impact of initiatives focused on improving community health, wealth, and well-being.

1 Develop a process for identifying measures that matter together with employees, customers, community partners, and people in places that are not thriving. The process of looking at one’s data, understanding the stories of people in the workforce or communities who are not thriving, and developing plans together with them can offer a powerful way to improve well-being and engage with the lives of employees and communities. Change efforts that do this are far more likely to achieve sustainable impact.
2 Choose a balanced set of process and outcome measures that change over the short, medium, and long term. Short-term process measures and intermediate outcome measures are essential for driving improvement cycles and better align with business operations. Longer term measures are essential for knowing whether there is progress over time by focusing on long-term change, not just quick wins. Box 6.2 presents additional criteria for selecting measures that might be relevant to businesses.

BOX 6.2 CRITERIA FOR SELECTING A MEASURE

#### “Overall (basic information for all nominated metrics)

■ Domain
■ Subdomain
■ Proposed metric
■ Source of metric
■ Link to website for more information
■ Level of data available (national, state, county, subcounty, ZIP code, community, etc.)

#### Important

■ Potential to drive improvement in health
■ Potential to drive improvement in social drivers of well-being
■ Potential to drive improvement in equity
■ Aligned with major national/global strategy
■ Potential to develop new knowledge about what creates well-being

#### Objective and effective

■ Strong evidence that this improves health, well-being, and equity
■ Valid
■ Reliable
■ Benchmarking available

#### Feasible

■ Data already collected, analyzed, and reported
■ Cost of additional collection/availability of resources to support collection
■ Burden of collection and reporting
■ Groups ready to adopt

#### Usable and useful

■ Timeframe data changes within (rating: 3 if less than quarterly, 2 if less than yearly, 1 if yearly, 0 if more than yearly)
■ Timeliness of data availability (rating: 3 if less than quarterly, 2 if less than yearly, 1 if yearly, 0 if more than yearly)
■ Usefulness to communities
■ Usefulness to researchers/national stakeholders
■ Meaningfulness to people with lived experience
■ Currently used by/could be used by? (Name initiatives/organizations actively using)
■ Level of data availability”

3 Choose outcome measures that matter to a wide range of stakeholders and apply across initiatives (this step is also known as a materiality assessment). The WIN measures offer a great place to start (see Box 6.3 for an example). In addition to being helpful in supporting collaboration across sectors, WIN heavily emphasizes the relationship between economic prosperity and health and well-being throughout the framework, considering the well-being of both people and place.

BOX 6.3 A MEASURE OF WELL-BEING OF PEOPLE

One scale, Cantril’s Ladder, asks people to rate their well-being by marking an “X” on a simple drawing of a ladder, where the bottom rung is their worst possible life and the top rung is their best possible life, today and 5 years from now. This measure has been tested for use by businesses via the Gallup-Sharecare Well-Being Index; has reliable, publicly available benchmark data by place in more than 150 countries and many counties in the United States; correlates to business outcomes that matter, such as workforce productivity; and also correlates with major population health outcomes, such as morbidity, mortality, and cost.

4 Identify process and intermediate outcome measures aligned with a balanced portfolio of initiatives and measures related to improving the well-being of people and places, especially for those most in need. The environmental scan (Appendix B) identifies ways businesses are working to improve each of these three areas. Process and intermediate outcome measures should be tied to the specific strategies and initiatives.
  ■ For example, suppose AnyBusiness, Inc., has, after conversations with employees and the community, identified access to safe and affordable housing as an urgent need in the community. AnyBusiness might consider a range of strategies to address the need, along with associated process and intermediate outcome measures.
    - Investing directly in affordable housing developments or providing rental subsidies to employees.
      ► Example process measure: Number of employees living in affordable housing or using a company subsidy.
      ► Example outcome measure: Percent of employee households paying 30% or more of their income on housing.
    - Offering wages to employees that are commensurate with the cost of safe, quality housing in the area and encouraging other businesses to do the same.
      ► Example process measure: Number of businesses offering commensurate wages.
      ► Example outcome measure: Percent of employees earning commensurate wages or higher (compared with baseline).
    - Investing in outdoor lighting and neighborhood peer safety groups in areas of the community (if residents have identified this as a potential solution)
      ► Example process measure: Number of outdoor lights installed.
      ► Example outcome measure: Percent of residents who feel safe walking in their neighborhoods after sunset.
    - Supporting afterschool leadership and job training programs for youth or other initiatives that help to build hope, community resilience, and belonging, such as the development and funding of neighborhood councils.
      ► Example process measures: Number of youth engaged in afterschool programming, number of neighborhood councils funded, or number of community-generated solutions implemented.
      ► Example outcome measures: Percent of community members responding “yes” to, “People around here are willing to help their neighbors,” and scores on a youth well-being scale.
    - Joining community revitalization efforts that preserve mixed-income and affordable housing.
      ► Example process measures: Number of affordable housing units created or preserved.
      ► Example outcome measures: Educational outcomes (e.g., high school graduation).
    - Hiring people from the community.
      ► Example process measure: Number of jobs and internships filled by people who live in particular neighborhoods.
      ► Example outcome measure: Total income created in the community.
  ■ Total return on investment, which calculates the overall impact on health, wealth, and well-being of interventions for both people and communities, offers another strategy for businesses to assess their progress over the course of their investment. Methods for valuing the well-being created by different initiatives and for modeling return over time are available. Using these methods to estimate total return on investment can help companies to select affordable strategies. Consideration should be given to investments that can leverage the contributions of others—to help drive collaboration and increase impact.
5 Prepare a measurement and learning system:
  ■ Identify a measurement and improvement team, and together with community partners, develop a strategy map, including a theory of change and a theory of implementation based on data about the well-being of people and communities. Baseline data on measures can be found in a wide array of places. Look to prior employee surveys and culture surveys for employees’ baselines. Most core measures and leading indicators in WIN are available online (http://www.winmeasures.org). The WIN Measurement Framework presents a wide range of measures related to the well-being of people and places for each of the vital conditions.
    - Set aims for major outcome and process measures and gather baseline data.
    - Decide what measures will be collected or obtained, and for each one, with what frequency, who will do the collection/gathering, and how often the data will be analyzed together with stakeholders.
    - Develop and implement a set of initiatives (small or large) to improve these goals.
    - Bring together stakeholders within the business and community to engage in collaborative sensemaking at least twice a year—that is, to look at the data, understand the stories behind the data, reflect, and generate insight. Be sure to include employees and community residents most affected by inequities.
    - Plan a path forward and reassess regularly. Leading organizations will set improvement goals within each quarter toward the longer term aim and reassess at least quarterly.

Box 6.4 describes the five steps applied to one company’s journey to live out its mission and benefit a community in need.

BOX 6.4 FIVE STEPS APPLIED TO THE JOURNEY OF NEHEMIAH MANUFACTURING CO.

The Nehemiah Manufacturing Company in Cincinnati, Ohio, was founded in 2009 with the mission to “build brands, create jobs, and change lives” (https://www.nehemiahmfg.com/). The for-profit company owns several brands of its own and also manufactures products for other companies. Nehemiah planned at the outset that it would contribute to the community and thrive as a business. The company focuses on hiring “hard to hire” people. Nehemiah’s journey is marked by each of the five steps to identify measures that matter.

Step 1. Develop a Process Together: Nehemiah partnered with the city of Cincinnati, community leaders, and social service organizations to select a neighborhood with people who most needed jobs and hope. They chose the West End and Over-the-Rhine areas of Cincinnati, which experienced high unemployment and few entry-level jobs.

Step 2. Choose a Balanced Set of Measures: The partners identified initial process and outcome measures that focused on manufacturing outputs, creating jobs, and hiring and retaining people from minority and low-income neighborhoods in West End and Over-the-Rhine.

Step 3. Choose Outcome Measures That Matter: As Nehemiah collaborated with local partners, it began to understand that chronic unemployment stemmed from structural and systemic inequities in people’s lives. One of the greatest barriers to employment was a history of incarceration. Nehemiah decided to focus on hiring people who had a prison record or a history of drug or alcohol misuse. Nehemiah refined its goals to recruiting, hiring, and retaining “second chance” workers and ensuring they comprised the majority of the company’s workforce.

Step 4. Identify Process and Intermediate Outcome Measures: Nehemiah’s first challenge was to identify a hiring supply chain. Nehemiah partnered with several nonprofit organizations—CityLink, St. Vincent DePaul, Jobs Plus, Beacon of Hope, and City Gospel Mission—to identify and develop potential workers with a special focus on creating supportive pathways for people to succeed. Nehemiah and its partners integrated social workers into the hiring process; created a weeklong training to help new hires get ready for work; and established biweekly check-ins with newly hired workers to build relationships and trust and to make sure the workers had the support they needed to be successful. Breaking down the steps and identifying specific process and intermediate measures showed the partnership exactly how they would accomplish the hiring goal. Nehemiah’s process measures include the number of nonprofits supported and the number of people placed in supportive housing or treatment for substance misuse.

Step 5. Prepare a Measurement and Learning System: Nehemiah and its partners learned much about change in the community:

■ Drug addiction is difficult to beat. With guidance from workers, the partners created a policy and allocated funds to support treatment and provide other types of support for workers who disclosed a relapse into drug or alcohol misuse.
■ Bad credit and poor financial decisions cause substantial stress. The partners established programs to help workers resolve financial issues.
■ Housing is not affordable. The partners worked with developers to build affordable housing for workers near their places of work.
■ Unresolved legal issues prevent people from attending work fully. The partners collaborated with legal service firms to offer legal support to workers who needed it.

As a result of these learnings and actions, Nehemiah has given people jobs and the support they need to succeed, and has created a stable workforce with an enviable 90% retention rate. All but 10 of 179 jobs have been filled by second chance workers. By providing these jobs and the associated support, Nehemiah helps to restore dignity, hope, and well-being to people in the community who need a second chance. Nehemiah describes its workforce as one of the hardest working and most loyal in the country.

Nehemiah has combined the well-being of its business with the well-being of the community and has partnered with investors who understand that Nehemiah’s mission is more than making money with a great bottom line. In addition, Nehemiah pursues its mission to impart an even stronger topline of impact on society. This combination of governance, community partnership, and continuous learning leads to a healthy business that is on the leading edge of creating well-being in the world.

## Conclusions

Businesses are essential to the lifeblood of communities. This chapter offers actions, measures, and frameworks for companies seeking to do more to improve the well-being of the people they reach and the places they serve. Businesses that engage in this kind of stewardship, using data to identify the people and places to engage, the best interventions to deploy, and the sharpest measures to assess impact, have the opportunity to be leaders and influencers improving the health of employees, families, and communities and influencing broader societal conditions in a community, region, and whole country. Data-driven approaches offer businesses and employers a pathway to make broader improvements and measure their contributions to that improvement, while understanding their current engagement in the context of an even larger ecosystem of communities and society.

Appendix A Tools and Resources

Appendix A identifies tools and resources addressing topics explored in Chapter 6. The tools and resources were created by such businesses and organizations as Health Enhancement Research Organization, Intel, Well Being In the Nation (WIN) Network, and others.

## GREYSTON BAKERY: Baking With Purpose

| Community Challenge \| Communities are healthier when people have jobs and steady income. Healthy communities enjoy less violence and substance misuse, more family stability, and better education for their children. Tax bases increase, civic participation grows, and the very people given a chance to work at a quality job tend to give back to the community and to others. But all too often, preconceived notions and rote hiring rules leave too many people without an opportunity to gain employment.
| Scenario \| Zen Master Bernie Glassman noticed the number of unemployed people in the Bronx and Yonkers (New York). Job prospects were thin because of limited education, work experience, and individuals’ past records of incarceration or substance misuse. In the early days of Greyston Bakery, Glassman literally pulled people off the street to help him bake cakes. When he later met and partnered with Ben Cohen and Jerry Greenfield of Ben & Jerry’s Ice Cream, Greyston bakers began to provide baked goods for two of the top five flavors of Unilever’s Ben & Jerry’s Ice Cream.; Greyston has more than 400 people on its waiting list to become bakers. With Greyston’s Open Hiring process, anyone who walks through the door can fill out a one-page questionnaire with their name, address, and phone number; affirm their willingness to work 12-hour shifts and lift 50-pound bags of flour and sugar; and confirm their eligibility to work in the United States. Applications sit on the waiting list for an average of 6 months. Once called, the new hire’s first day includes an orientation and full pay and benefits. Next, he or she is offered an apprenticeship that lasts 6–9 months. Upon completion, bakers have access to union membership. “We don’t care about folks’ past, we want to invest in their future,” said Joseph Kenner, president and CEO of Greyston.; The Open Hiring framework has been refined over time. For example, if an employee does not show up on time or stops showing up altogether, there is likely a reason—perhaps childcare issues, domestic violence, or housing eviction. Working with Westchester Jewish Community Services, Greyston created an Employment PathMaker position to provide support services to bakers. Thanks to this support, the turnover rate at Greyston was two points better than the industry average in 2019.; The Open Hiring concept pioneered by Greyston has benefited members of the southwest Yonkers community, and Greyston now wants to take this hiring approach to other businesses, with the goal of helping them make their hiring practices more inclusive.
| Action Taken \| Greyston launched the Center for Open Hiring in June 2018 to train and provide tools to businesses. Business leaders cite liability insurance and fears of violence among the most frequent barriers to adopting an open hiring concept. “Our premiums and liability rates are no different from any other manufacturer,” Kenner said. “It’s not total chaos at the bakery!” Another hurdle for businesses is the belief that the hiring practice hurts turnover rates. “Yet these very same managers will go through extensive interviews and costly background checks and some people don’t work out either,” said Kenner. “Wouldn’t it be better to invest in helping people succeed instead of keeping people out?” As a measure of early success, a 3,000-store beauty retailer adopted Open Hiring at its North American distribution center, generating a 60% reduction in employee turnover.
| Key Takeaway \| If given an opportunity and the training, large segments of the unemployed population will succeed in the workplace. But many of them are excluded because of their backgrounds or other factors that say nothing about their abilities to be successful on the job. “If you make these types of investments, you are going to learn new things about your employees,” Kenner said. “Folks want to feel like someone is invested in them, and that’s a huge piece of what open hiring is—everybody has a place.” Companies can start by Open Hiring one person for an entry-level position.