# CHAPTER 5 Working With Community Changemakers

## OVERVIEW

This chapter introduces four community changemakers with which businesses can partner to improve community health, wealth, and well-being. Stories describe effective partnerships and unique ways that businesses can create healthier, stronger communities. Examples in this chapter show how partnerships with businesses can solve both business and community problems and create opportunities for business in communities.

KEY TAKEAWAYS

➤ In addition to community development actors, businesses that would like to invest in or engage with their communities might also collaborate with social enterprises, public health departments, foundations and philanthropies, and anchor institutions.
➤ Social enterprises are in the business of knowing communities and effecting change to make them stable and help them thrive, all while operating a successful company.
➤ Public health departments collaborate with a variety of organizations to meet shared goals and address the vital conditions that shape health. These departments can be creative, dependable, and effective partners of businesses.
➤ Foundations and philanthropies are critical partners at the local, regional, and national levels. These entities bring rich community knowledge, long-standing relationships, and a range of resources, including investment resources, to achieve shared goals.
➤ Anchor institutions are place-based economic engines with an embedded social mission inextricably linked to the long-term, well-being of the surrounding communities. Businesses can join with—or become—anchor institutions as they work to increase local hiring and procurement and support equitable economic development.

## Introduction

Businesses seeking to invest in or engage with their communities may join with many partner organizations that are already working to improve community health and increase economic prosperity. As described previously, actors within the community development field, including community development financial institutions (CDFIs) and community development corporations, are proven partners for capital and service investments to improve the vital conditions that shape health, wealth, and well-being. This chapter briefly introduces four additional partners, with complementary strengths and skills.

■ Social enterprises are companies with socially driven missions that have discovered ways to align their profits with improving health, wealth, and well-being. These businesses meet a need in the community, such as preventing evictions and providing jobs, and meet the business imperative of being profitable.
■ Public health agencies provide critical services and infrastructure to protect and improve the health of people in communities. Partnerships between public health departments and local businesses address such issues as healthy behaviors, worker safety, food and nutrition, neighborhood livability, and criminal justice reform. Public health departments can serve as chief health strategists in their communities.
■ Foundations and philanthropies harness the power of wealth to tackle entrenched health and social problems. Business and foundation/philanthropic partnerships can spread prosperity and opportunity in struggling communities through programs, grants, and capital investments.
■ Anchor institutions are economic engines that power sustainability and long-term well-being in their communities. Businesses can partner with—or become—anchor institutions to strengthen and expand an inclusive local economy. Hospitals and universities are prime examples of anchor institutions that leverage their own assets to create economic opportunities for individuals, businesses, and communities.

## Social Enterprises

Many factors combine to make a business successful: a company’s strong, competitive products and services; market demand; a compelling brand and reputation; and well-trained staff and able leadership. Providing investments and services that make people and communities healthy, vibrant, strong, and resilient generally is viewed as a job for others and not part of a company’s core work. But an array of enterprises are in that business, including social enterprises. Companies can partner with social enterprises, whose core business is knowing communities and effecting change to make them stable and help them thrive, all while operating a successful business. Social enterprises are a hybrid of sorts; they

■ Are mission driven with an identified social issue they have set out to address,
■ Are commercial businesses (either nonprofit or for-profit) invested in addressing that issue,
■ Balance their goals of achieving societal impacts within the requirements of the market, and
■ Can be effective partners for businesses that similarly want both social and financial returns on their investments.

This approach has been termed “impact investing.”

Companies in the “business of doing good” are forging innovative partnerships with other businesses to create positive results for all parties, recognizing that health and prosperity are inextricably linked for both business and communities. Two examples describe how business and community organizations can partner to meet their goals for mutual benefit.

### A Real Estate Company and a Nonprofit Organization Build a Partnership

Beacon Communities, a privately owned real estate firm (https://www.beaconcommunitiesllc.com/), develops, invests in, owns, and manages multifamily housing properties, approximately 22,000 apartments—including affordable-, market rate-, and mixed income-housing—in the Northeast and Mid-Atlantic regions of the United States.

Beacon Communities’ renters are primarily people and families with lower incomes. A review of evictions for nonpayment of rent found above-average eviction rates in some of Beacon Communities’ developments. Evictions were bad for Beacon Communities’ business. Costs included lost income through vacancies, legal expenses tied to the eviction process, and negative effects on the morale of property managers charged with evicting families. Evictions were also bad for Beacon Communities’ goal of contributing to building stable communities for their residents. Beacon Communities reduced its eviction rate when it began working with HomeStart.

HomeStart, a nonprofit organization (https://www.homestart.org/), works to end homelessness in the Greater Boston, Massachusetts, area by helping individuals obtain housing and settle into the community. HomeStart observed that evictions for nonpayment are a primary driver of homelessness and that eviction is associated with a cascade of long-term consequences. Once evicted, a family’s credit is ruined, they lose their possessions, they plunge into debt, their employment becomes unstable, and family cohesion often dissolves.

HomeStart was historically a U.S. Department of Housing and Urban Development (HUD)-supported program to assist people experiencing homelessness in their search for housing. Frequently, people came to HomeStart with an eviction notice, seeking help with a housing search. HomeStart endeavors to prevent homelessness before it starts, so the organization began to test a new program. HomeStart would meet a family appearing in housing court for nonpayment of rent, and make a small payment to the property owner to prevent the eviction and buy time. Then HomeStart would work with the family to identify the causes of the eviction notice, help the family repay any debt, and develop a plan to cover the family’s rent. After 12 months, 97% of the families supported through this process by HomeStart could maintain housing on their own.

Because of HomeStart’s assistance, (a) families could avoid the long-term consequences of eviction; (b) housing owners could avoid costly evictions; and (c) employers could retain stable employees.

To quantify the impact of its efforts, HomeStart worked with the Boston Housing Authority (BHA) (http://www.bostonhousing.org/en/Home.aspx) to establish the costs of evicting a family and evaluate the efficacy of its program. The analysis was compelling: BHA’s cost to evict a family was about $10,000, but HomeStart’s cost was only $2,000 to prevent the eviction. HomeStart and BHA tracked 300 households that HomeStart had supported. After 48 months, only 5% of those families had been evicted for nonpayment. Based on these positive long-term social and financial results, HomeStart created the first-ever per-intervention reimbursement rate contract with BHA. BHA now pays HomeStart to prevent families from being evicted, which saves the city the costs of eviction and provides a lifeline to struggling families. HomeStart receives 75% of the payment upfront for each household supported and the remaining 25% at the end of 12 months, if families remain stably housed. Through this partnership, HomeStart helps BHA mitigate the government’s financial risk and negative social outcomes, and in 2017 alone, saved BHA more than $1,000,000 in eviction-related costs.

Based on HomeStart’s experience with BHA, Beacon Communities, the private firm trying to stem evictions, quickly agreed to HomeStart’s reimbursement rates and began a partnership to reduce evictions. Beacon Communities’ evictions have been dropping ever since, and Beacon Communities has initiated conversations to roll out the HomeStart partnership to other properties, reaching thousands of individuals and families.

“Our partnership with HomeStart is changing the trajectory of the lives of our residents while simultaneously reducing the number of families that experience homelessness. The value of this partnership goes beyond dollars and cents; it is change management at its core. It is the right thing to do, and the successful outcomes underscore the importance of this program.”

—Dara Kovel, CEO, Beacon Communities

Beacon Communities’ partnership with HomeStart is an example of marrying good business with community impact—for all residents and property managers—and serves as a model of how private industry can accelerate a positive, social impact.

### Corporations, Investors, and a Nonprofit Social Enterprise Do Business Together

In 2018, First Step Staffing (FSS) (https://firststepstaffing.com/) expanded operations from its Atlanta, Georgia, home to Philadelphia, Pennsylvania, replicating a successful model of purchasing a for-profit staffing agency and converting it into a workforce social enterprise—that is, an organization that helps people overcome barriers to employment and find and succeed in jobs. In its first year in Philadelphia, FSS retained 100% of the prior for-profit agency’s corporate clients and added 14 new clients.

FSS provides employment services for people transitioning from homelessness, including veterans, formerly incarcerated individuals, and others with barriers to employment. As an alternative staffing agency, FSS places men and women into temporary and temp-to-hire positions with local businesses, and provides supports, including job coaching and transportation to and from work, to make its employees successful. As a nonprofit social enterprise, FSS offers the support services at no additional cost to corporate clients. Rather, the organization reinvests the profits from the staffing agency into these services and obtains additional grant funding to cover the costs.

FSS serves both the business client that is paying for reliable and well-supported staff and the staff who are reentering the workforce and need support to succeed in the workplace and address other challenges, such as unstable housing, health issues, a criminal record, or other obstacles to employment. FSS makes several promises to its business clients:

■ Guaranteed on-time employees by providing transportation when needed and incentives for employees who consistently come to work on time and prepared;
■ Skills-matching, specialized training, life coaching, and extended job training hours for employees; and
■ Competitive pricing with all profits reinvested in the program, services, and people.

FSS also makes the case that working with people transitioning out of homelessness is beneficial to the entire community and local economy. FSS (a) helps people achieve the first step toward economic self-sufficiency and earning power sufficient to maintain stable housing; (b) pays wages to workers whose purchasing power will in turn support local businesses; and (c) potentially reduces the need for costly government services, creates employees who may become tax payers, and supports making the community a more attractive place for new business and investments.

Besides being a client of FSS staffing services, a business can invest in FSS through debt and philanthropic equity. For example, Nonprofit Finance Fund, a New York-based national CDFI, provided loans to support FSS’ expansion into Philadelphia. Additional investments and resources came from other CDFIs, philanthropy, the City of Philadelphia, and social investment funds. Opportunities for other businesses and individuals to invest will continue as FSS expands to other cities, as it recently did to Los Angeles, California.

### How Businesses Find Partners

Business partnerships with community organizations are good business. But how do businesses identify community partners and make collaborative arrangements? Various paths exist. Some partnerships come from a business’s deep knowledge of the local community and its relationships there. Others can be identified through such resources as the Build Healthy Places Network’s Partner Finder tool (http://www.buildhealthyplaces.org/partners/). This tool contains directories of many national networks of community development organizations, including the National Alliance of Community Economic Development Associations, the National Association of Latino Community Asset Builder, the National Coalition for Asian Pacific American Community Development, NeighborWorks America, and Opportunity Finance Network. The Democracy Collaborative also has an informative toolkit (https://hospitaltoolkits.org/investment/) for place-based investing. Although the toolkit focuses on healthcare partnerships, it provides several resources that are relevant to all types of businesses. Businesses that invest in people and communities will reap both social and financial rewards most readily when they invest in partnerships with community organizations and social enterprises whose businesses are the social good.

## Public Health

Collaborations often form when problems are complex, affect multiple stakeholders, and require shared, sometimes risky solutions. Individual organizations may not know where to start, may chip away at the edges of a larger structural problem, or may turn to other mitigation strategies (like relocation) that leave the problem either unaddressed or worse than before. Taking effective action to address longstanding and complex social problems requires multiple partners with a variety of perspectives and a host of tools, strategies, and know-how to drive solutions. Loose collaborations that share a clear vision and can operationalize a plan, with each partner contributing to the whole based on their specific strengths, connections, and opportunities, may be the most efficient approach. Such successful collaborations deploy an asset-based approach where community partners contribute their own micro assets to achieve macro solutions that are coordinated and more effective than the component parts. Public health departments are often at the heart of these community collaborations.

Public health departments collaborate with a variety of organizations to meet shared goals and address the conditions that shape health. They can be creative, dependable, and effective partners of businesses seeking to improve the health of employees (including future employees), families, and communities. Companies seeking to engage their communities and take actions to improve community health, wealth, and well-being can look to their local public health departments as effective partners.

As a part of city, county, or state governments, public health departments are tasked with an enormous responsibility: protecting the health of the people they serve. They do this by collecting and analyzing data to understand the health threats to a population and where diseases occur in a community. They provide tools and resources and broadcast critical messages to the public that help communities take precautions against a wide range of infectious diseases such as coronavirus, measles, influenza, HIV, and viral hepatitis. Public health departments also collaborate with the communities they serve to develop strategies for preventing and managing chronic conditions; adopting healthy behaviors; and even preparing for weather emergencies, such as hurricanes, tornados, and snowstorms.

Staff of public health departments are well aware of the vital conditions that contribute to favorable health outcomes and have long worked to increase access to community and clinical preventive services. Examples of community preventive services include smokefree air policies, active transportation, and supportive housing; and examples of clinical preventive services include immunizations, cancer screenings, and management of diabetes and hypertension. In addition to providing this technical expertise, public health departments often are well integrated into and respected by the community. In fact, one of the roles of the public health department in the 21st century is to be the chief health strategist of a community, joining with and at times leading community members and stakeholders to solve critical community problems.

Delivering on that role may be a challenge for health departments facing budget constraints, inability to hire critical talent, and the weight of bureaucratic demands. However, when public health departments successfully address community problems and improve community health, it is often because of strong leadership, a creative and talented workforce, essential infrastructure to meet community needs, and strategic partnerships with businesses and other community organizations, including healthcare delivery and academic institutions. The tools used to protect the public’s health are also used by businesses, such as robust data analytic capabilities and clear metrics to monitor progress. Flexible and sustained funding and a talented workforce are necessities to support effective public health initiatives. In short, the kinds of supports that foster success for health departments are familiar to every organization or business tackling high-stakes projects.

The following example from Oklahoma City, Oklahoma, highlights how public health departments and business leaders worked alongside mission-driven nonprofit organizations to address a complex community problem of critical importance to all.

### Criminal Justice Reform in Oklahoma City

The Oklahoma City County Health Department is recognized by peers and colleagues across the state as a “go-to” leader and partner to help solve a range of community challenges. The health department’s multi-agency data sharing framework provides a holistic understanding of a range of community issues, and its collective impact model to better serve the community’s most needy citizens had already caught the attention of area business leaders. When concern developed in the business community about overcrowding at the Oklahoma County Jail, attendant health and safety issues, and potential federal intervention, the local chamber of commerce approached the challenge as a business problem to solve, and the local health department brought its resources and expertise to bear on finding a solution.

Criminal justice reform may not seem like the obvious challenge to bring together business and health leaders. However, leaders in the business community were concerned about the image of having the highest incarceration rate in the nation (Figure 5.1) created for the city, as well as the moral issues around maintaining an overcrowded jail. For its part, the public health department was concerned about getting residents with mental health or substance use conditions into treatment (rather than jail), keeping families intact, and preventing seemingly modest violations, like a broken taillight, from derailing employment and landing a family in poverty.

Figure 5.1 Incarceration rates in Oklahoma and founding NATO countries

Incarceration rates (per 100,000 population) in Oklahoma (1,079) exceeded that of the founding countries of NATO: United States (698), United Kingdom (139), Portugal (129), Luxembourg (115), Canada (114), France (102), Italy (96), Belgium (94), Norway (74), Netherlands (59), Denmark (59), and Iceland (38).

Incarceration negatively affects the broader labor market by creating barriers to current and future employment, and is associated with high rates of death from drug overdose, lower median household incomes, and poor health outcomes. Incarceration also has long-term implications for families and children; even a few days in jail can result in the loss of a job, disrupt childcare arrangements, and affect school attendance and performance. In addition, children of incarcerated parents are six times more likely to become incarcerated themselves.

For businesses in Oklahoma City, cycling thousands of city and county residents through the jail was a workforce issue. For community members, the overcrowded jail reflected poorly on the city and county they called home and did not align with the future they were trying to build. Oklahoma City leaders recognized the business, community, and social dimensions at stake and the health, wealth, and well-being implications for the city and county.

Understanding why so many people were in jail in the first place led business, community, and health leaders to see the problems at the jail as a community-wide issue and both a symptom of and contributor to community concerns like workforce, education, safety, quality of life, civil rights, and justice. Although criminal justice issues are not typically considered health or business issues, business, health, and community leaders could see the connections between (a) pathways to jail, jail overcrowding, and disparities in treatment at the jail and (b) community health, wealth, and well-being and the potential to thrive. As business leaders weighed in on the levels of incarceration, other concerns became evident. H. E. “Gene” Rainbolt, founder of BancFirst said, “We’re running a felony factory. It requires so much state appropriation it takes money away from things that really make a difference such as education, mental health, rehabilitation, and family structure.”

The Greater Oklahoma City Chamber of Commerce convened the Oklahoma County Criminal Justice Reform Task Force and brought in the Vera Institute of Justice to help assess the problem. Findings from the analysis opened the community’s eyes to solutions beyond increasing jail capacity. For example, many incarcerated individuals would be better served, at lower cost, by other city and county programs; and most people in jail had not yet been found guilty of a crime. They were in the pretrial phase and unable to post bail. With a better understanding of how the justice system worked (or did not work) in Oklahoma City and County, community stakeholders, under the chamber’s leadership, turned their attention to reform. They worked with elected leaders; business, health, and education leaders; judges, prosecutors, and attorneys; law enforcement officials; and the public to change practices from the point of citing someone for a violation through jail admission and the court process. Judges started assessing offenders’ abilities to pay before imposing bail and fines. Law enforcement officers were offered alternatives to arresting low-level offenders. State laws were changed so that law enforcement and justice professionals could work with mental health professionals to provide alternatives to jail for those with mental health disorders. Within 14 months, the jail’s population had declined by one-third. By 2017, the number of people in jail fell below 2,000 for the first time in years. Studies suggest community members will be safer and healthier as a result, and crime rates trended down from historical highs in 2008 to 2010 and leveled off through 2017.

With local businesses and the public health department working together, along with other partners, under the auspices of the Greater Oklahoma City Chamber of Commerce, the City and County were able to address a real and perceived blight to the city’s image and the future it wants to create, in a way that builds value for people and place and increases opportunity for greater community health, wealth, and well-being.

### A Promising Partnership

While collaboration can be challenging and time-consuming, addressing entrenched community problems requires cooperation among stakeholders who may have limited experience working together and, in some cases, may represent competing interests. Including a range of stakeholders, however, brings more assets and greater “buy-in” to address the problem in the first place and to implement the identified solution in a sustainable manner. Public health departments, given their interdisciplinary nature and their broad mandate of protecting the public’s health, are a flexible and effective partner for businesses. With expertise in population health and health promotion, trusted relationships with the community and community organizations; knowledge of pathways to make policy- and system-level improvements; and expertise in data collection, analytics, and interpretation, public health departments can bring rich resources to the table.

Strengthening the vital conditions that produce health is a shared responsibility. Forming local collaborations and alliances that bring in the leadership, assets, financial resources, strategic thinking, and know-how from multiple entities and organizations in the public, private and nonprofit sectors is necessary to improve community health and increase economic prosperity.

With expertise in population health and health promotion, trusted relationships with the community and community organizations; knowledge of pathways to make policy- and system-level improvements; and expertise in data collection, analytics, and interpretation, public health departments can bring rich resources to the table.

## Philanthropy

Partnerships across sectors, including public, private, and nonprofit sectors, have traditionally been viewed as reserved for large capital campaigns (as described in Chapter 4). However, with increasing frequency, communities turn to these partnerships, on behalf of a variety of issues—including health, poverty, and child development—and do so in ways that advance community health, wealth, and well-being. Foundations and philanthropies can be critical additions to these partnerships. Whether operating at the local, regional, or national levels, foundations and philanthropies are often effective partners that increase impact, contribute innovative strategies, and help align investments. They can bring rich community knowledge, long-standing relationships, and a range of resources, including investment resources, to the table to achieve shared goals.

“Successful companies are asking themselves not whether charity donations would build their reputation but how they can make a lasting difference in the world.”

—Waterford.org

Working with foundations and philanthropies, as with any partnership, takes a commitment and can be challenging, even for business partners. Each foundation works differently and has its own set of guidelines and funding priorities. Expectations for open communication, follow through, and strategy alignment can become mired in stifling processes that slow progress. Successful partnerships with philanthropy require leaders who are aligned with each other, understand their shared goals, and have a clear understanding of how the assembled organizations can work together.

When aligned and focused on impact, philanthropies, like businesses and nonprofit organizations, invest to achieve efficient, effective actions that address societal problems and achieve shared goals. Indeed, partnerships and collaborations make success more likely. Philanthropies bring resources to the table, including funding, flexibility, adaptability, skills and experience, particular expertise (such as working with media) and high expectations. Additionally, philanthropies often have powerful networks and connections with donors, elected representatives, and community leaders that can contribute to the success of an investment.

Philanthropies operate in three ways to pursue goals and create value for the purpose of furthering a social change agenda aimed at improving communities:

1. Organization funders seek to nurture and drive additional funding toward specific grantee organizations that have high-performing leaders and can execute on business and philanthropic investments.
2. Field builders seek to grow community capacity to address community problems and focus on making that capacity resilient, sustainable, and effective.
3. Goal aligners are more loosely collaborative, identifying strategic overlap among philanthropic, corporate, and governmental goals and seeking to coordinate grants and investments that foster consistent progress toward an overarching goal.

Understanding which of these purposes the partnership is engaged in is essential to working effectively together, as is being clear about the value each partner brings to the table and expects to produce as a result of the partnership.

Effective partnerships and collaborations, especially in the service of complex community projects, almost always require a backbone organization to help maintain focus and provide essential convening functions, such as strategy sessions, administrative and office support, and fundraising for community programming. Overhead is essential to maintaining these kinds of routine but critical supports for community change efforts. When grantwriting to foundations or inviting foundations to the table, asking for 15–25% overhead on program grants can help to fund the administrative and office supports required to get these efforts off the ground and functioning well. Alternatively, businesses and philanthropies might step forward to serve in the backbone role or provide funding or offer space, staff, resources, and knowledge to ensure the backbone functions are delivered.

### The Collaborative Model

Collaborative philanthropy, also known as impact philanthropy (Box 5.1), involves working together with other funders, businesses, nonprofit organizations, and even investors to accomplish what none of the entities might be able to accomplish on their own. By pooling together financial, technical, and knowledge resources; time; and staff, these collaborations can chart a path to solve thorny societal problems. Especially when social initiatives are embedded in a foundation’s or company’s long-term strategy and core operations, the organization’s success may depend on the value the collaboration is able to deliver to society.

Value for businesses that engage in philanthropic collaborations can include improved employee morale, enhanced brand loyalty, expanded product reach, and financial returns on business investments, especially if the problem is addressed by way of a profitable venture. Philanthropies and nonprofit organizations accrue value as well, including greater resources for social innovation, mission fulfillment, strengthened reputation, and even strategic enhancements gleaned from business partners. For all collaborators, the achievement of the sought-after community improvement is the major value.

BOX 5.1 THE COLLABORATIVE MODEL IN ACTION

“Blue Meridian Partners [https://www.emcf.org/our-strategies/blue-meridian-partners/], launched in 2016, has raised more than $1.7 billion in investment capital from 14 funding partners and has approved a total of $350 million for its first nine recipients. ‘We are trying to identify the most promising strategies, with an evidence base, that can potentially move the needle for the most disadvantaged kids in poverty in the United States,’ said Nancy Roob, president and CEO [chief executive officer] of the Edna McConnell Clark Foundation and Blue Meridian Partners’ founding CEO. ‘We seek out leaders who have a vision for solving a national problem and help them achieve that goal by reaching the national scale required. So we measure our progress on whether or not our investments help leaders achieve that objective. And each one is different.’ Blue Meridian Partners grantees work to create large-scale change in a range of fields—including healthcare, child welfare, and criminal justice.”

“The core funder value proposition … includes surfacing promising investment opportunities, conducting due diligence, and, in many cases, building grantee capacity and monitoring grantee performance. Blue Meridian Partners, for example, supports its grantees to develop detailed scaling plans and uses these plans as a way to measure progress. George Pavlov, who directs philanthropic giving for the Sergey Brin Family Foundation and participates as a general partner in Blue Meridian Partners, explained that there is ‘no way we could build the same capability for our share of the annual expenses. [Being part of this collaborative] gives us best-in-class capabilities and flexibility’.”

Financial investments are a critical part of collaborative philanthropy (Box 5.2), but much more than grantmaking and gift-giving is required to achieve the desired impact (also see Chapter 3). Thus, while collaborative philanthropy demands more of the collaborators—more than just money—it is the collaboration among participants that helps to ensure the additional contributions of time, knowledge, strategic thinking, accountability, and support are spread across the participants who can remain focused on their main priority of running a business (corporate, philanthropic, nonprofit, or otherwise).

BOX 5.2 REJUVENATION OF THE HIGHLANDER NEIGHBORHOOD: A PHILANTHROPY-LED PARTNERSHIP

Highlander neighborhood is situated on 34-acres just north of downtown Omaha, Nebraska. The neighborhood, a former public housing site, consistently experienced the highest rates of crime in the state. The local housing authority partnered with Seventy Five North to redevelop the area into a mixed-income neighborhood, tying it to the turnaround of nearby Howard Kennedy Elementary School. Seventy Five North is a nonprofit organization established by The Sherwood Foundation, an Omaha-based private foundation, for the purpose of redeveloping the neighborhood. Highlander neighborhood is bordered by a local federally qualified health center and the Urban League of Nebraska, setting the stage for a rich collaboration to strengthen the neighborhood.

An award-winning community accelerator forms the heart of the revitalized Highlander neighborhood. Community accelerators are convening places for people and organizations to find project support, build networks, and develop collaborations. The accelerator hosts several amenities for residents and surrounding neighborhoods. The local private college and the community college hold courses, from basic literacy to computer science, at the accelerator. A technology center gives students and residents access to wi-fi and shared working space.

During the summer months, the Highlander neighborhood is filled with public markets, movie nights, and weddings at the event hall. Three restaurants and a bar have also opened. As a result of the evident progress, the U.S. Department of Housing and Urban Development awarded Seventy Five North and the City of Omaha a $25 million Choice Neighborhood Implementation Grant to redevelop another public housing site nearby. To date, the local philanthropic partners have committed more than $35 million to these associated redevelopment efforts, adding their funding to government funding to help produce the best possible outcomes. In addition to the capital expenses, foundation support includes program grants to a variety of local nonprofit organizations that focus on food security, education, child welfare, financial wellbeing, arts, health, and mental health.

Omaha’s corporate community contributed time, expertise, and financial resources to redevelop the Highlander neighborhood. For example, a local restaurateur advised on the design and management of the restaurants at the accelerator; a senior vice president from a local business served on the board of directors of Seventy Five North; and an area developer assisted with contract negotiations for the project.

Although many foundations and philanthropies were established by business leaders, corporate philanthropy is a subset of philanthropy overall. Corporate philanthropy continues to evolve as the practice becomes more focused, more outcomes-oriented, more specifically aligned with business strategies and goals, and more deeply integrated into business operations. As part of this evolution, businesses are responding to the demands of customers while employees and shareholders are (a) seeking a competitive advantage, greater reach, and richer brand loyalty and (b) recognizing the need to share the benefits of the company—the value created—with the communities they call home or service. The rich partnerships forged through collaborative philanthropy can create success in each of these areas, for all collaborators. Philanthropy is almost always an exceptional partner when contemplating efforts to help a community thrive, to increase economic opportunity, and to unleash human potential.

## Anchor Institutions

Healthcare systems and educational institutions are some of the largest employers in many states and regions of the United States. These businesses spend more than $1 trillion a year on employees and goods and services, have endowments in excess of $750 billion, and employ 8% of the U.S. labor force. These businesses have significant effects on local economies and are powerfully positioned to improve the health and economic ecosystems of the communities in which they reside.

Anchor institutions are place-based economic engines with an embedded social mission that is inextricably linked to the long-term well-being of their surrounding communities. They can be public, private, or nonprofit businesses and employers. Hospitals and universities are leading examples of anchor institutions and can play critical roles in strengthening the communities they serve by better aligning institutional resources with the needs of those communities.

An anchor mission framework is a systems approach whereby institutions use their resources—like hiring, purchasing, and investing—to intentionally improve the financial security of area residents, strengthen the local economic ecosystem by making it more economically and racially equitable, and address the community conditions that shape health. The anchor mission framework strives to build wealth for the community and meaningfully address the vital conditions of health in a community.

For example, the University of Massachusetts Memorial Health Care (UMMHC) is an anchor institution that implements the anchor mission framework. In 2017, executives at UMMHC noted the significant toll of poor social and economic conditions on community health outcomes.

UMMHC embraced the anchor framework to tackle poverty and unemployment, poor housing, lack of access to care, food insecurity, safety and violence, and other problems. After thoroughly assessing the impact of adopting and implementing the anchor mission framework, UMMHC’s board of directors voted to proceed with several anchor mission strategies:

■ Allocate 1% of its investment portfolio to targeted community investments with an expected return;
■ Provide targeted technical training for entry-level positions for current and prospective employees;
■ Intentionally recruit trainees from targeted neighborhoods; and
■ Build an effective system for local purchasing.

With these strategies for anchor institutions in place, UMMHC implements best practices for sustained community impact.

The following section explore several strategies for anchor institutions and include examples from healthcare, higher education, and other businesses.

### Inclusive Local Sourcing

To increase the income and economic health of local neighborhoods, anchor institutions seek to do more business with local businesses. Hospital systems nationwide spend $472 billion on goods and services annually, and institutions of higher education spend more than $43 billion annually on goods and services. Shifting even a small fraction of this spending to local, minority-owned, women-owned, or employee-owned businesses is a powerful way to improve community health and address racial, social, and economic inequities.

■ Cleveland Clinic, located in Cleveland, Ohio, is increasing its procurement and construction purchasing from minority- and women-owned businesses and facilitating a mentor–protégé program to build the capacity of those businesses. Cleveland Clinic supports the Evergreen Cooperative, a network of start-up, worker-owned businesses in the community. Through this support, the Cooperative expanded the capacity of its laundry services business, creating 100 local jobs and building community wealth by allowing employees to share business ownership in the hospital’s supply chain.
■ Metropolitan State University in Minnesota is a member of the Central Corridor Anchor Partnership, a group of education and medical institutions aggregating demand to support local suppliers in low-wealth neighborhoods along Metro Transit’s Green Line between Minneapolis and Saint Paul. The university implemented a pilot program to connect farmers in the Hmong American Farmers Association (HAFA) with the university’s catering vendors. HAFA is a cooperative in Minnesota that promotes locally produced foods. A local healthcare anchor, Fairview Health East, also has a partnership with HAFA for Community Supported Agriculture programs to increase access to healthy, affordable produce for patients at several of its clinics.
■ Virginia Commonwealth University (VCU) is committed to diversifying its procurement supply chain as part of the Commonwealth of Virginia’s Small, Women- and Minority-owned Businesses (SWaM) Procurement Initiative. VCU solicits diverse businesses to participate in its procurement and encourages contractors to look for opportunities to engage SWaM firms as subcontractors. To track and assess progress on the SWaM goals, VCU maintains a public dashboard that documents outreach and participation.

### Inclusive Local Hiring

To increase the income of neighborhood residents, anchor institutions often hire local employees and create pathways to turn entry-level jobs into careers, especially for those with barriers to employment and advancement. These are ways through which anchor institutions create economic opportunities for the communities they serve.

■ RWJBarnabas Health, a network of independent healthcare providers in New Jersey, is a founding member of the Newark Anchor Collaborative. The collaborative seeks to grow economic opportunities and well-being in the City of Newark. For example, the Newark 2020 initiative aims to hire 2,020 additional Newark residents by 2020. By January 2020, RWJBarnabas Health had hired 466 residents of Newark, exceeding its goal of 350 hires.
■ Fairview Health Services in Minnesota has an internal workforce development team to develop hiring pipelines and career pathways for employees, students, and community residents. Fairview Health Services has funded apprenticeships, on-the-job training, and tuition support for 4-year degrees and other credentials for 220 nurses and healthcare workers, including recruitment of women and members of minority groups. In addition, Fairview Health Services sponsors 200 paid internships and career pathways annually. As a result of the developmental work of Fairview Health Services, 43 residents have been hired through the Cedar Riverside Opportunity Center, 75 students have been hired through the Central Corridor College Fellows program, and 99% of participants in the work-learn program have been retained for work.
■ Rutgers University–Newark’s (RU–N’s) anchor mission is one of the highest priorities of its strategic plan launched in 2014. The plan calls for RU–N to invest in kindergarten through high school, associate, bachelor, and graduate degree educational pipelines and pathways; strong, healthy, and safe neighborhoods; arts and cultural districts and initiatives; regional economic development; and science and the urban environment. RU–N has partnered with the City of Newark and other local anchor institutions, like RWJBarnabas Health, on Hire.Buy.Live.Newark initiative to reduce poverty and unemployment and strengthen the city’s economy.

### Equitable Economic Development and Place-Based Investing

Anchor institutions, particularly healthcare anchors, play a unique role as place-based investors—using their long-term financial reserves locally and strategically tapping underutilized assets to fill market gaps in lending and investment. By allocating a portion of their investment portfolios to projects and aligning them with other discretionary funds, investors can combine stable returns with social impact and create long-term solutions.

■ CommonSpirit Health (legacy Dignity Health) has an organizational policy to allocate up to 5% of its investment portfolio for low-interest loans to nonprofit organizations that are supporting community health and well-being. In 2016, CommonSpirit Health provided a $3.1-million loan to support the construction of a transit-oriented complex in central Los Angeles. The complex includes 50 permanent and 450 transitional housing units for more than 500 people experiencing homelessness.
■ Bon Secours Mercy Health is investing up to 5% of its long-term reserve fund in community development financial institutions that serve low- and moderate-income communities. (Chapter 4 provides more details about community development financial institutions.) Bon Secours Mercy Health has worked toward achieving this target by annually increasing its asset allocation by approximately $3 million. Since instituting this policy in 2008, the health system has shifted $34 million, or about 3% of its $1.1 billion long-term reserve fund, to support affordable housing, economic development, community facilities, and other projects that benefit the health and well-being of members in the communities it serves.

Inclusive planning can improve the development of workforce pipelines and strengthen local and diverse business development. Collaborating with community residents helps to build trust with community members, allows for deeper partnerships, and shifts the anchor institution from “doing for” to “doing with” the community.

■ University Hospitals Rainbow Center for Women and Children in Cleveland, Ohio, is a 40,000-square-foot, three-story facility designed with the help of a community advisory board to better meet the needs of the community. The board comprised about 60 members of the community, including neighborhood residents and individuals working in areas connected to community health and well-being, such as public health, education, and employment. Because of the community advisory board, a significant design element was added that provides residents with a one-stop center for their essential needs: co-locating multiple services, including health services; legal services; Women, Infants, and Children (WIC) Program office; and a pharmacy.

### A Role for Businesses

Businesses of all types can serve important roles as anchor institutions, as investors, and as part of anchor collaboratives to support locally targeted job training and hiring, local procurement, and equitable development. Like health systems and universities, other businesses have relationships with the communities in which they operate, understand the reciprocal nature of healthy environments (i.e., when the community thrives, businesses thrive), and are often committed to supporting their communities. However, many businesses have not yet learned about the anchor mission framework and how they can be more socially engaged and intentionally align their resources to strengthen neighborhoods to be healthy and wealthy for the long term.

Other businesses have already engaged as anchor institutions (or joined with anchor institutions) to be part of the solution.

■ Quicken Loans, the nation’s largest mortgage lender, took an all-in stance in its headquarters in Detroit, Michigan, and found new life. In 2011, the company moved its entire Michigan workforce to downtown Detroit, including some 17,000 employees of Quicken and related companies. In the neighborhoods, Quicken’s philanthropic arm has initiatives to prevent foreclosures and rehabilitate blighted homes, seed new businesses, and prepare workers to take part in the growth of specific industries.
■ Prudential Financial is deeply rooted in the community, having conducted business for more than 140 years in Newark, New Jersey. Prudential Financial is one of several partnering organizations in Hire.Buy.Live.Newark and Newark 2020—both of which are part of an economic development vision designed to connect city residents to job opportunities. Prudential Financial is a founding member of the Newark Anchor Collaborative, which launched in 2018 to grow economic opportunities and well-being for the City of Newark. Other founding institutions include Audible.com, RWJBarnabas Health, New Jersey Institute of Technology, New Jersey Performing Arts Center, RU–N, and Rutgers Biomedical and Health Sciences. By working with diverse and committed partners to do more purchasing, hiring, and investing at the local level, more resources can be leveraged for the benefit of the local community.
■ New Orleans Business Alliance (NOLABA) provides another model of private sector involvement and engagement with anchor institutions. NOLABA oversees the city’s strategic plan for economic growth. Industry councils and working groups implement many of NOLABA’s recommendations. NOLABA strives “to unite a diverse community of stakeholders to catalyze job growth, create wealth, and build an equitable and sustainable economic future for New Orleans.” LCMC Health; such corporations as JPMorgan Chase, Entergy Corporation, Harrah’s New Orleans Hotel & Casino, and Shell Oil Company; and such foundations as Surdna Foundation and W.K. Kellogg Foundation have invested in the strategic plan.

“Anchor institutions are unique in the strength that they bring to the city where they’re housed, whether it’s our purchasing power, the power of our employees, or the resources that we have at our disposal. This three-pronged approach is a very comprehensive way of using what’s best about our institutions to create good by helping to drive inclusive economic growth for Newark’s residents. Hire local—how do we think about training and employing Newark residents? Live local—how do we think about encouraging and incentivizing our employees and associates to live in the city where they’re working? And buy local—how do we direct our dollars to support local businesses, which in turn are hiring local residents?”

—Lata Reddy, Head of the Office of Corporate Social Responsibility at Prudential Financial

Finally, new models of business enterprise are emerging that support community health, wealth and well-being through other frameworks and mechanisms, including employee ownership (Box 5.3).

BOX 5.3 AN EMERGING MODEL OF THE BUSINESS ENTERPRISE IN COMMUNITIES

Some mission-led, employee-owned private companies are taking other approaches to help strengthen their communities and employees. This emerging model embodies a powerful enterprise design: businesses that benefit society and larger living systems of the earth. The Democracy Collaborative calls these firms “next-generation enterprises.” More than 50 of these companies operated in the United States in 2019. Employee ownership of these firms takes one of many forms, such as Employee Stock Ownership Plans (or ESOPs), worker cooperatives, or employee ownership trusts. The common best practice is that employees own at least a 30% stake in the company. These companies often have a clear and authentic mission to benefit the public, which often includes environmental and social benefits.

Next-generation enterprises range in size from only a few employees to thousands of employees. Recology, a San Francisco-based waste management and recycling firm with revenues of $1.2 billion, has 3,500 employees and is 100% employee owned. Next-generation enterprises operate across a variety of industries and include such nationally known brands as Eileen Fisher and the King Arthur Flour Company, as well as lesser known companies.

“Many CEOs of these firms are leaders in sustainability and workplace democracy. All of these companies are experimenting with multiple approaches—participatory management, multi-stakeholder governance, alternative leadership models—to create businesses that are good for employees, good for the environment, grounded in the community, and governed by a mission.”

This new mission-led, employee-owned business model promotes environmental sustainability and social equity, providing a glimpse into how businesses might operate in an economy that truly embodies the values of equity, sustainability, and community.

Anchor institutions are some of the largest employers and businesses in their areas. As significant economic engines, they play an important role in catalyzing local economies and building community wealth that, in turn, improves health and economic opportunities for residents. For-profit businesses can help to build the economic ecosystems of their surrounding neighborhoods by becoming anchor institutions or supporting anchor mission strategies and engaging with anchor institutions and anchor-involved collaboratives. This is an opportunity for companies to align their values, corporate culture, staff volunteerism, and customer and community expectations with strategies that build healthy, sustainable, and thriving communities.

APPENDIX A TOOLS AND RESOURCES

Appendix A identifies tools and resources addressing topics explored in Chapter 5. The tools and resources were created by such businesses and organizations as American Institute of Certified Public Accountants; Centers for Disease Control and Prevention; The Democracy Collaborative; Public-Private-Partnership Legal Resource Center, World Bank Group; and others.

## THE CHICKASAW NATION: Investing in Community

| Community Challenge \| Imagine living in an area described as a severely distressed census tract—meaning few jobs, plenty of high school dropouts, poor housing options, high rates of incarceration, large swaths of prime-age adults not working, and a poverty rate greater than 31%. The struggle to achieve a satisfactory quality of life can be overwhelming in such a place.; Now, imagine being a part of the Chickasaw Nation, which has made extraordinary progress to lift its people out of poverty and improve opportunities in severely distressed communities. Leaders of the Chickasaw Nation have created businesses to support the tribal government and offer opportunities to tribal citizens and community members. Despite such success, the lack of broadband Internet access limits opportunities for members of the Chickasaw Nation and the larger community.
| Scenario \| As a sovereign nation, the Chickasaw Nation has built a broad portfolio of businesses to generate revenues that support tribal programs and services. These economic development efforts have accelerated dramatically under the leadership of Bill Anoatubby, governor of the Chickasaw Nation since 1987, with the development of a number of businesses across several industries, including technology, entertainment, hospitality, media, and health. With a reliable revenue stream, the Chickasaw Nation began to diversify its business and social program portfolios. However, strengthening economic development, education, and healthcare throughout the Chickasaw Nation depended on reliable broadband Internet connectivity.
| Action Taken \| More than 60% of people who live in the Chickasaw Nation’s 13-county service area in Oklahoma did not have access to broadband Internet service. Recognizing the need to address the poor infrastructure for quality Internet service, the Chickasaw Nation Secretary of Commerce, Bill Lance, requested $14–$20 million from Governor Anoatubby to install a 250-mile fiber optic cable that would encircle the Chickasaw Nation’s territorial boundaries. “To ensure we would be able to meet demand for future generations,” the Chickasaw Nation Deputy Secretary Dakota Cole said, “the decision was made to install three pieces of conduit to supply three times our estimated long-term needs.”; With the governor’s support, Trace Fiber Networks, LLC, launched in 2016. The name pays homage to Natchez Trace—a forest trail and trade route in Chickasaw’s historic homeland in Mississippi and Tennessee. With the limited liability company, the Chickasaw Nation worked with financial institutions, undertook competitive bidding for contracts, developed a team of contracting partners, and began conversations with stakeholders. The State of Oklahoma assisted with gaining rights of way and other technical aspects of the project. The Chickasaw Nation bartered with the Oklahoma Community Anchor Network, which already had 1,000 miles of high-speed fiber across Oklahoma, to swap out fiber in places with redundancies, and learned that the Federal Communication Commission had given tribal entities the right to claim, free of charge, whitespace spectrum for high-speed Internet access. As a result, the Chickasaw Nation expected to (a) provide more than 180 locations with high-speed Internet connectivity by the end of 2020 and (b) obtain a return on investment within 7 years.; “This is just as much a story of equity as it is a story of connectivity. You can’t begin to level the playing field if you don’t have access to the same information,” the Chickasaw Nation Undersecretary of Technology & Innovation Commerce Chris Shilling said. “This will provide a transformative opportunity for the group of citizens and individuals in rural Oklahoma that will chip away at capital inequity and education inequity that we see across the country.”
| Key Takeaway \| For the Chickasaw Nation to succeed, its businesses have to succeed. In today’s economy, a gap in broadband services can leave people behind. Leaders of the Chickasaw Nation are determined to close that divide. “Access to broadband Internet is becoming increasingly essential … to enhance education, economic development, housing, and career opportunities of the Chickasaw people,” said Governor Anoatubby. “Enhancing these opportunities builds a foundation of prosperity that plays an important role in promoting community health.”