# CHAPTER 4 Bringing Opportunity to Communities Through Partnerships With Community Development and Community Finance

## OVERVIEW

No single business or sector can create lasting change on its own. This chapter tells the story of community development and how it brings public, private, and nonprofit resources together to fight poverty and advance health. Numerous agencies and approaches that create opportunities and improve quality of life are explored, finding common ground and financial alignments that benefit everyone. Access to capital is the lifeblood of the U.S. economy, and financial resources are essential to the health of communities and the livelihood of families. This chapter gives special attention to community development financial institutions (CDFIs)—which are well positioned to address the lack of available capital, credit, and financing expertise in many communities—and describes “win-win” ventures, such as business investments in affordable housing and creatively financed projects that improve the health of employees and communities.

KEY TAKEAWAYS

➤ The need for a healthy, skilled labor force remains a top priority for individual businesses and the broader economy. People are more likely to be healthy and skilled and participate in the labor force when they grow up and live in thriving neighborhoods where the vital conditions are met.
➤ The human capital potential that could be unleashed if every person had access to thriving neighborhoods would be transformational for America’s communities, businesses, and economy.
➤ Resource alignment for this transformational work is already underway in the field of community development, a mission-driven enterprise that fosters vibrant economic, social, and health conditions to increase opportunities for people with low incomes.
➤ Community development
  ■ Requires investments and partnerships across the public, private, and nonprofit sectors; and
  ■ Leverages public, private, and philanthropic investments to develop real estate, promote small businesses and entrepreneurs, and strengthen human capital.
➤ Businesses and other investors seeking careful, knowledgeable investors in underserved areas can partner with community development financial institutions to raise capital for specific community investments.
➤ The community assets that comprise the vital conditions for health, wealth, and well-being create an excellent environment for private enterprise. Strengthening these assets through community development enables employees to come to work prepared and engaged and promotes a thriving local network of businesses, suppliers, employees, colleagues, customers, and clients.
➤ Despite sizeable investments, the current scale of community development is not sufficient to address the many complex causes of poverty and the negative impacts of poverty on health, wealth, and well-being.
➤ New business models are needed to align the financial interests of those who benefit from a healthier, more productive population with those who create the conditions that promote human flourishing.

## Introduction

Like any complex system, the U.S. economy evolves in unpredictable ways. Despite these ongoing shifts, the need for a healthy, skilled labor force remains a top priority for individual firms and the broader economy. Chapters 1 and 2 noted the magnitude of the U.S. health disadvantage; the vital conditions that shape the health of Americans (and harm their health, when unmet); and the ways in which neighborhoods and communities expand or limit opportunities for health, wealth, and well-being. People are more likely to be healthy and to prosper when they live in thriving neighborhoods that include high levels of social capital and community cohesion, high-quality and affordable housing, regional connectivity through transit, vibrant educational and workforce opportunities, and access to healthy food and recreation.

The human capital potential that could be unleashed if every person had access to this kind of opportunity—regardless of his or her race/ethnicity, disability, or income—would be remarkable: Such access would be transformational for our communities, businesses, and the economy. Because no single sector can realize this vision in isolation, the transformation requires investments and partnerships across the public, private, and nonprofit sectors. Nationwide, this transformative work of aligning financial resources from across organizations to address unmet vital conditions is already underway through the field of “community development.” Actors working in this field are essential partners for businesses seeking to engage with and invest in communities.

## What Is Community Development in the United States?

Community development in the United States is a mission-driven enterprise that fosters vibrant economic, social, and health conditions to increase opportunity for people with low incomes. The approach recognizes the inseparable connection between people’s economic (and increasingly, health) outcomes and the opportunities available in the places where they live. Community development leverages public, private, and philanthropic investments to support a variety of activities that strengthen historically marginalized and disinvested communities and expand opportunities at the individual, family, and neighborhood levels, including

■ Promoting and bolstering community engagement to identify and address local barriers to opportunity;
■ Developing real estate, such as quality, affordable, and accessible housing and community facilities;
■ Promoting small business and entrepreneurship;
■ Strengthening human capital, from early childhood education to workforce training; and
■ Supporting neighborhood residents in the areas of financial health and asset development, such as personal savings and credit repair.

Community development comprises organizations that specialize in real estate, city planning, law, social work, public policy, public health, affordable housing, and finance. The work is inherently interdisciplinary; requires diverse resources and skills; and needs to be deeply informed by local residents and community voices. As a result, successful community development entails strong and collaborative partnerships across multiple stakeholders—from the public, private, and nonprofit sectors to neighborhood residents and local leaders. Box 4.1 presents more information about the history of community development in the United States.

BOX 4.1 THE ORIGINS AND EVOLUTION OF COMMUNITY DEVELOPMENT IN THE UNITED STATES

The modern field of community development in the United States has its historical origins in the War on Poverty programs of the 1960s, which introduced a constellation of federal programs designed to provide education and job training to expand employment opportunities, as well as government support for community planning and organizing. In 1966, Senator Robert F. Kennedy and his aides worked with local residents to create the first “community development corporation” (CDC) in the Bedford-Stuyvesant neighborhood in Brooklyn, New York, which combined locally driven community action with the market-based principles of private enterprise.

This first CDC, founded in 1967 as the Bedford Stuyvesant Restoration Corporation, coordinated programs focused on the creation of housing, jobs, health facilities, recreation, and more in the defined geography of the neighborhood, fulfilling Kennedy’s vision for holistic and locally driven approaches for alleviating poverty. “An effort in one problem area is almost worthless,” Kennedy said in a speech announcing the first community development project. “A program for housing, without simultaneous programs for jobs, education, welfare reform, health, and economic development cannot succeed.” This movement spread nationwide, with low-income communities creating the thousands of CDCs that exist nationwide today.

During subsequent decades, major cutbacks in federal funding for housing and other neighborhood investments spurred more innovation at the state and local levels and led to the establishment of new nonprofit entities dedicated to antipoverty work, such as Local Initiatives Support Corporation (LISC) and Enterprise Community Partners, two of the largest community development intermediaries in the United States. Eventually, these networks skillfully organized, became politically active, and lobbied successfully for more federal resources to sustain antipoverty efforts. Today, as an established field with significant technical expertise in a variety of functions, community development serves as critical infrastructure for deploying public and private resources into actions that improve the health and prosperity of low-income communities.

## Critical Actors in the Community Development Field

As Robert F. Kennedy suggested in 1966 (Box 4.1), successful community development requires simultaneously addressing the complex web of social and economic factors that underlie poverty. Consequently, a variety of partners have engaged in a range of community development activities. The following sections describe some of the field’s essential actors who implement community development activities.

### Community Development Corporations

The National Alliance of Community Economic Development Associations describes community development corporations (CDCs) as nonprofit organizations that are typically based in low-income communities and work to improve the future of the neighborhood for the benefit of the people who live there, through such activities as real estate development, economic development, and community organizing. Approximately 4,600 CDCs exist in the United States. The East Bay Asian Local Development Corporation (EBALDC) in Oakland, California, is an example of a CDC that has adopted a “healthy neighborhood approach” to address the interconnected social, economic, and environmental factors that shape neighborhood health and well-being, specifically working to ensure that people of all classes and incomes can live where they work in the Bay Area.

### Affordable Housing Developers

Although many CDCs develop affordable housing as part of their suite of local activities, larger regional and national organizations also dedicate their work solely to the development of affordable housing. For example, Stewards of Affordable Housing for the Future (SAHF) is a national network of the 13 largest nonprofit affordable-housing developers, including BRIDGE Housing, Homes for America, Mercy Housing, National Housing Trust, and National Church Residences. SAHF members collectively provide more than 140,000 affordable rental homes nationwide.

### Community Development Financial Institutions

Community development financial institutions (CDFIs) are mission-driven financial institutions that provide access to affordable capital and financial services for low-income communities. CDFIs leverage federal resources, awarded through the U.S. Department of the Treasury’s Community Development Financial Institutions Fund (CDFI Fund), to attract private sector investment, which they use to provide flexible financing for projects like affordable housing development, small business creation, and community facilities. The CDFI industry manages more than $150 billion among the more than 1,100 certified CDFIs nationwide (Box 4.2); CDFIs are headquartered in all 50 states, the District of Columbia, Puerto Rico, and Guam (Figure 4.1). Industry performance is strong. In 2017, CDFIs had a net charge-off rate of 0.4%, which was lower than the net charge-off rate of 0.5% among banks insured by the Federal Deposit Insurance Corporation.

BOX 4.2 OVERVIEW OF CDFI CERTIFICATION

CDFI certification ensures that a CDFI:

■ “Is a legal entity at the time of Certification application;
■ Has a primary mission of promoting community development;
■ Is a financing entity;
■ Primarily serves one or more target markets;
■ Provides development services in conjunction with its financing activities;
■ Maintains accountability to its defined target market; and
■ Is a nongovernment entity and not under the control of any government entity (Tribal governments excluded).”

Figure 4.1 Locations of certified CDFIs

CDFIs are located in every state and in Guam and Puerto Rico. High concentrations are located along the west coast of California, along the mid-Atlantic and northeastern seaboard, and in the southern Mississippi River region of the United States.

This combination of solid financial performance and deep commitment to mission enables CDFIs to serve as trusted conduits between traditionally risk-averse sources of capital and impactful projects in low-income communities.

### Nonprofit Service Providers

Besides revitalizing low-income neighborhoods through real estate development, the community development field also works to develop human capital. Nonprofit service providers play a critical role in the field by building relationships with and offering direct services to low-income clients, from young children to older adults. These services can be grouped loosely into two types of service activities: (1) providing support to address immediate needs, such as a food bank or homeless shelter, and (2) focusing on longer term development that contributes to economic stability and wealth creation, for example, through activities that target educational readiness, workforce skills, or financial capability. Together, nonprofit service providers across the community development field address the wide range of complex barriers that people with low incomes face in achieving financial well-being.

### Community Members

Despite its early origins as a community-based, resident-driven movement, the increasing technical complexity and professionalization of the community development field has made it less accessible to community members and residents. Nonetheless, many community development projects have successfully engaged community members in a variety of ways, including as board members of involved organizations, as members of advisory committees, and through community meetings. Importantly, many CDCs rose from and represent communities through their history and leadership “rooted in and rooting for struggling communities.” Indeed, creating lasting change will require more intentional and meaningful partnerships with community members.

For example, Building Healthy Communities (BHC) is a comprehensive community initiative of The California Endowment, which is one of the country’s largest health-focused philanthropies. BHC is designed to transform communities facing major health inequities into places where all people and neighborhoods thrive. It focuses on decreasing violence, increasing healthcare coverage among children, and improving transportation, among others. BHC takes an inclusive engagement approach that “[strengthens] the fabric of our democracy by investing in the social, economic, and political power of the very residents who have been the targets of exclusion, stigma, and discrimination.” This movement across the field emphasizes the longer term need to build relationships and support the lasting power in the community as a means of transformative change.

## Working With Community Development Financial Institutions

CDFIs are financial institutions concerned with creating an inclusive economy, in which opportunity is widely accessible and prosperity is broadly shared. Because CDFIs recognize that access to capital is the lifeblood of our economy and essential to the economic health of families and communities, their shared mission is investing in people and places that otherwise lack access to safe, affordable financial products and services.

More than 38 million Americans (11.8%) lived below the federal poverty line in 2018. About 6% of Americans—21 million people—lived in counties characterized by persistent poverty, with poverty rates at least 20% for 30 years or more and as high as 32% for minority populations. Although median household income has increased nationally over the past several years, the net worth of the median household is still about 7% lower than it was in 2000. Given the well-documented link between economic distress, especially geographically concentrated poverty, and poorer health, investing in the most under-resourced American communities may help achieve better outcomes overall. CDFIs are experienced in such investments.

In a market economy, investors of capital channel money to where it can secure the highest rate of return for commensurate risks. Communities that are deemed too risky, or not profitable enough, are often bypassed by traditional financial institutions and as a result do not have access to the credit and capital they need to thrive. CDFIs focus on communities that have suffered the long-term effects of chronic and systemic disinvestment, such as urban areas where discriminatory “redlining” was once practiced and still casts a shadow, rural areas experiencing persistent poverty, and tribal communities that are often isolated from local and regional economies. CDFIs also focus on communities experiencing more recent economic stress, such as towns that have lost manufacturing businesses.

CDFIs finance entrepreneurs to develop small businesses; homeownership for first-time buyers; affordable housing for cost-burdened families and individuals; community facilities, such as schools, daycare centers, and health centers; and commercial enterprises, such as healthy food retail and small manufacturing companies. They offer bank accounts to the unbanked and under-banked and technical assistance that boosts families’ financial capability.

The public and private sectors have come to recognize CDFIs as effective and vital intermediaries that function in the spaces between public policy and market forces. In 1994, with bipartisan support, the United States Congress created the CDFI Fund and placed it within the U.S. Department of the Treasury. CDFIs use public resources from federal tax credits (described below) and the CDFI Fund to leverage investments from a variety of private sources, including corporations. Figure 4.2 shows the composition of a balance sheet for a typical community development loan fund organized by a CDFI.

Figure 4.2 Fictional example of typical sources of capital for a CDFI loan fund

Typical sources include banks (37%), government (20%), internal funds (15%), corporate (10%), philanthropy (10%), other (6%), and individuals (2%).

### What Businesses Should Know About CDFIs

#### CDFIs Are Diverse

CDFIs come in many forms, including regulated banks and credit unions as well as unregulated loan funds, microlenders, venture capital funds, and socially responsible financial service firms (Figure 4.3). Some are for-profit, and others are nonprofit. Regardless of their business model, CDFIs share a common mission of reaching the people and places underserved by traditional financial institutions.

Figure 4.3 Types of certified CDFIs (among 1,112 certified CDFIs as of September 30, 2018)

Types of certified CDFIs include internal funds (50%), credit union (28%), bank or thrift (12%), depository institution holding company (8%), and venture capital fund (2%).

CDFIs come in many sizes. The largest CDFIs manage several billion dollars in capital; the assets of small CDFIs may be only a few million dollars. Larger CDFIs tend to have better access to resources and bigger footprints; smaller CDFIs may have deeper local roots and a better understanding of local markets.

#### CDFIs Are Businesses

Though CDFIs are mission driven, they must attend to the bottom line. CDFIs manage the tension between earning enough income to cover costs and support growth and innovation while also achieving their mission of providing affordable financial products and services to underserved communities. CDFIs earn income from the fees and interest they charge borrowers. Some earn income from advisory services and contracts. CDFIs also raise grants from a variety of sources, including the CDFI Fund and other government programs, banks, and foundations. For many firms, a CDFI can be a partner with operations in communities and in specific areas, such as health clinics, with which interested businesses may be less familiar.

Businesses and other investors seeking careful, knowledgeable investors in underserved areas can partner with CDFIs to raise capital for a particular community investment.

CDFIs make their business models feasible by raising investment capital from a variety of sources—some at market rates of return and others below market—and blending them together to make their financial products and services affordable. Businesses and other investors seeking careful, knowledgeable investors in underserved areas can partner with CDFIs to raise capital for a particular community investment.

### The Impact and Performance of CDFIs

CDFIs have stood the test of time. At the end of 1997, there were 196 certified CDFIs with total assets of $4 billion. Today, more than 1,100 certified CDFIs hold total assets of over $150 billion.^7^ Since its establishment, the CDFI Fund has awarded over $3.3 billion to CDFIs, community development organizations, and financial institutions through its funding programs. In addition, it has allocated $57.5 billion in tax credits through the New Markets Tax Credit (NMTC, described below) Program and issued guarantees on $1.51 billion in bonds through the CDFI Bond Guarantee Program. Both programs are public initiatives that incentivize private investment in businesses and large-scale development projects to revitalize distressed communities. Finally, the Healthy Food Financing Initiative (HFFI), administered by the U.S. Department of Agriculture with support from the U.S. Departments of Treasury and Health and Human Services, provides grants and loans to improve access to healthy foods in urban and rural areas of need by financing grocery stores, farmers’ markets, co-ops, and other food access businesses. With CDFIs as an intermediary, HFFI has provided more than $220 million in grants and leveraged an additional $1 billion in private financing to nearly 1,000 groceries and healthy food retailers in 35 states (see Exemplar about Reinvestment Fund).

7 Except where otherwise noted, figures on CDFI Fund activities are based on CDFI Fund’s 2018 annual report and on financial audits for fiscal years 2017 and 2018, using internal data from the Office of Inspector General.

The CDFI Fund’s investments are leveraged many times over. The leverage ratio varies from program to program, but most, like the NMTC, attract about $8 of private capital for every $1 of federal spending. This creates a win-win for investors: CDFIs use public resources to mitigate risk for private investors, and the public benefits by achieving social outcomes that exceed the value of its investment. For example, the public may receive a new grocery store that offers food and employment opportunities; or it could get help with affordable housing that allows people to stay close to jobs. By serving as financial intermediaries, CDFIs can connect investors with needs and help improve the conditions that shape health in a community.

CDFIs have a positive impact on communities. For instance, under the Fund’s CDFI Program, which gives financial and technical assistance directly to qualifying CDFIs to sustain and expand their work, “award recipients reported originating loans or investments in FY 2018 totaling over $11 billion, including

■ $2 billion for 19,000 home improvement and purchase loans,
■ $2 billion for 17,963 business and microenterprise loans,
■ $3.4 billion for over 207,000 consumer loans, and
■ $1.3 billion for 2,800 residential real estate transactions.”

CDFI Fund award recipients also financed over 33,600 affordable housing units and served more than 343,000 individuals with financial literacy and other training. These products and services are delivered to underserved people and communities and allow struggling individuals and families to afford rent; own or upgrade a home; start a business, grow a business, or gain a job at a local business; establish a credit score; finance a car or an education; and live near employment opportunities, thus contributing to the strengthening of individuals, families, and communities and contributing to health, wealth, and well-being.

CDFIs are reaching hard-to-serve places. CDFI Program award recipients invested over 80% of their assets in low-income communities in 2018. Indeed, CDFIs receiving awards outperform the baseline certification guidelines, which require 60% or more of assets be invested in low-income communities. In the NMTC Program, allocatees (i.e., people and programs that receive funds) exceed the baseline requirement of serving low-income census tracts by driving 75% of transactions to highly distressed communities. Another CDFI Fund program, the Bank Enterprise Award, gives monetary awards to banks and thrifts that increase lending and services to communities that need them most. In this program, all transactions are in communities with poverty rates of 30% or higher and unemployment rates 1.5 times higher than the national average. In communities with these characteristics, the additional support—whether for small business expansion, construction of a federally qualified health center, or investment in job training and skills—can have a lasting impact on quality of life and community health outcomes. Box 4.3 offers examples of the reach of CDFIs.

BOX 4.3 EXAMPLES OF THE REACH OF COMMUNITY DEVELOPMENT FINANCIAL INSTITUTIONS

■ “Former manufacturing communities. More than 400 counties are affected by manufacturing job losses, and these counties have simultaneously experienced economic decline and population loss. CDFIs have lent and invested $2.7 billion through more than 49,000 individual transactions. In addition, over $5 billion in NMTCs have been invested in these counties.
■ Coal-impacted communities. CDFIs are working in areas experiencing economic challenges due to contractions in the coal industry. [CDFIs] are supporting economic diversification and community revitalization initiatives. Sixty CDFIs across 14 states have lent or invested more than $100 million, and 24 community development entities [which are organizations certified by the CDFI Fund] have deployed nearly $230 million in NMTC investments in nine states.
■ Areas of persistent poverty. While over 6% of the U.S. population lives in areas of persistent poverty, nearly one-fifth of CDFI investments and transactions and 18% of CDFI headquarters are located in these areas. CDFIs have invested more than $640 million in persistent poverty counties.
■ Small towns, rural communities, and Native communities. CDFIs have provided $6.1 billion in loans and investments in small towns and rural communities and over $757 million in investments in Native communities.
■ Small business finance. Financing entrepreneurs and small business owners remains a challenge in America, but CDFIs are making inroads. [In 2018], CDFI Program awardees provided financing to nearly 16,000 businesses nationwide.”

Overall, CDFIs have tremendous impact in some of the hardest to serve places across the country, have lower rates of loan losses, and are more efficient than traditional lenders. According to the Opportunity Finance Network, although CDFI loans have higher delinquency rates than loans by traditional banks, their loss rates are in fact lower (0.65% versus 1.05% in 2001 through 2015). Since lending in distressed communities is their core business, CDFIs are experienced at managing risk by offering technical and other assistance to borrowers, including individuals and their communities, entrepreneurs and small businesses, and even large institutional actors. An analysis by Fairchild and Jia found that CDFIs perform on par with mainstream banks when it comes to operational efficiency and are at no greater risk of institutional failure.

### Options for Working With CDFIs

Businesses can invest in CDFIs in a variety of ways based on the outcomes they are seeking to achieve, such as improving the health, wealth, and well-being of the labor force or ensuring availability of affordable housing in their communities. The following section describes three options frequently used by CDFI investors.

#### “On Balance Sheet” Investments

Many investors choose to invest in the CDFI rather than directly into a project the CDFI will eventually finance, like affordable housing, a community facility, or a small business. These are referred to as “on balance sheet” investments and can be an effective option for an investor interested in the entire range of activities undertaken by a given CDFI. The investment can be spread across many transactions over a period of time, giving the CDFI maximum flexibility.

#### Structured Funds

CDFIs often structure special funds for an investor, or investors, interested in more targeted outcomes; for example, making healthy food more accessible in low-income, low-access areas. Structured funds can also be designed to target specific geographic areas. Structured funds are usually set up “off balance sheet,” meaning that investments are made into a separate legal entity created solely for the purpose determined by the investor(s). The CDFI typically plays the role of the fund manager and often invests its own capital as well. A business interested in potentially contributing to community investments can (a) leverage their capital by pooling with other investors and (b) lower their risks by working with institutions that have experience in these types of investments and communities (see, for example, Funds for kickstarting affordable housing preservation and production: Lessons for new investors by Elizabeth Mattiuzzi).

#### Transaction Level

CDFIs are skilled at facilitating project-level investments from investors. If an investor has an interest in a single project, they can invest in that project through the CDFI or together with the CDFI. If a company is planning to invest in or contribute to a project, it should consider working with a CDFI that can potentially lower risk and attract other market-rate or below-market-rate investments into the project.

Communities that meet the needs of families—safe neighborhoods, childcare, affordable housing, and good schools—ultimately produce healthier and more productive workers, now and into the future, with attendant returns of value to the business. Partnering with CDFIs to invest in communities is a well-developed strategy for realizing this vision.

CDFIs are working to close wealth gaps across America by investing in the engines that create mobility from poverty, such as good schools, safe and affordable housing, access to healthy food, and quality healthcare. By reducing or closing gaps in wealth and increasing economic opportunity, improvements in health and well-being will be more attainable. Examples in other sections of this report demonstrate tangible ways that the business community is already advancing this work. But more is needed. Businesses can contribute in even greater ways to creating a society in which health and prosperity are more broadly shared. Communities that meet the needs of families—safe neighborhoods, childcare, affordable housing, and good schools—ultimately produce healthier and more productive workers, now and into the future, with attendant returns of value to the business. Partnering with CDFIs to invest in communities is a well-developed strategy for realizing this vision.

### Main Sources of Community Development Funding

Because of the overall insufficiency of any single funding source dedicated to low-income communities, the practice of community development requires a combination of multiple funding streams from across the public, private, and philanthropic sectors. These varied sources have different motivations for investing in community development efforts. The most common types of funding are described below, but the field is constantly evolving in its ability to connect new sources of capital to efforts that strengthen low-income communities.

#### The Community Reinvestment Act

The Community Reinvestment Act (CRA) is a regulatory statute that helps ensure depository banking institutions provide capital and financial services to the low-income communities in which they operate, consistent with safe and sound practices. CRA was enacted in 1977 in response to decades of disinvestment in low-income communities and, most notably, to lend and invest in the communities in which they are chartered. Estimates indicate that CRA-motivated banks made aggregate loans of more than $400 billion in 2016 to support housing, small businesses and farms, and community development efforts in lower income communities. Of the multiple sources of community development funding, CRA-motivated bank lending and investment represent the largest share.

#### Low-Income Housing Tax Credit and New Markets Tax Credit

To incentivize additional private sector actors to invest in low-income communities, the federal government allocates tax credits that can be purchased by private entities to offset their tax liabilities. The largest such program is the Low-Income Housing Tax Credit (LIHTC), which was created in 1986 to encourage private investment in affordable housing. Under the terms of the LIHTC program, states receive an annual allocation of federal tax credits based on population size (nearly $9 billion in 2017), which are then awarded through a highly competitive process to developers that construct, rehabilitate, or preserve affordable housing. The developer then sells the credits to a corporation that can apply them toward future tax liability, and the proceeds of the sale generate equity for the housing endeavor. Since its inception, LIHTC has financed more than 3 million units and served more than 7 million households, supporting 3.4 million jobs while generating $323 billion in local income. Congress enacted a related program, NMTC, in 2000 to attract private capital for small businesses and community facilities that operate in low-income communities. Since 2001, the NMTC program has provided $49 billion in incentives ($3.5 billion in 2018), creating or retaining nearly 750,000 jobs and supporting the construction of 190 million square feet of manufacturing, office, and retail space.

#### Public Sector Investments

The public sector also provides significant funding in the form of loans or grants from sources, such as tax revenue and municipal bonds, across all scales of government. At the federal level, the U.S. Department of Housing and Urban Development (HUD) administers multiple grant programs, such as the Community Development Block Grants, from which funds are then allocated at the state and local levels. State and local governments also administer their own funding programs, such as California’s Affordable Housing and Sustainable Communities Program, which uses revenue from the proceeds of the state’s cap-and-trade program ($402 million in 2019, more than $1 billion since 2016) to fund housing, transportation, and land-use projects that reduce greenhouse gas emissions. In addition, multicounty or regional bodies, such as metropolitan planning organizations, also can provide funds to support community development efforts at the regional level. Businesses can tap into some of these resources or join with public-sector partners to lower the costs of their community investments.

#### Foundations

Charitable foundations are known most widely for their grant-making efforts, which have no expectation of repayment or investment return. Many foundations, however, also make investments from their asset portfolio through “program-related investments” and “mission-related investments” that are designed to further the organization’s social mission while earning some level of financial return. These philanthropic investments can take multiple forms, such as below-market-rate loans, loan guarantees, or equity investments. Philanthropic investment complements grant funding and often provides the flexibility needed to pursue innovative new projects and financial structures. Chapter 5 presents more information about partnering with philanthropy.

#### Direct Private Sector Investment

Private firms have begun to invest directly in community development efforts, separate from any regulatory requirements or tax credit incentives. For example, technology companies—such as Microsoft, Google, and Facebook—have made commitments to fund affordable housing in the regions in which their offices are located, in response to the growing pressure their presence has created on local housing markets. In addition, health systems—such as UnitedHealthcare, ProMedica, Bon Secours Mercy Health, Nationwide Children’s Hospital, and Kaiser Permanente—have also invested directly in community development efforts, recognizing that such issues as housing stability and access to healthy foods improve health outcomes.

## Putting It All Together: The Practice of Community Development

The same community assets that boost population health also create an excellent environment for private enterprise. The combination of these assets and their ongoing development and enhancement in the community through the practice of community development (a) helps employees across a variety of skill levels; (b) enables employees to come to work prepared and engaged; and (c) promotes a thriving local network of businesses, suppliers, colleagues, customers, and clients. The assets of a healthy community ecosystem help underserved and disadvantaged populations realize economic prosperity, which in turn promotes their engagement as consumers. Indeed, communities enriched with the vital conditions for health, wealth, and well-being are economically resilient—that is, they are better able to withstand the blow of a recession without spiraling into depopulation, blight, and crime and to build wealth broadly in times of plenty.

A “one-size-fits all” approach to the practice of community development does not exist, and the range of actors, activities, and funding sources varies depending on the local context. Community development approaches, however, traditionally have fallen into two categories—“people” and “place”—defined by the scale of the intervention. Effective community development addresses people and place simultaneously; the work must be grounded in the lived experience of people with low incomes, which cannot be separated from the places in which they live. Thus, community development is not a singular exercise carried out by any one organization. Instead, community development is a collective effort to harness resources and strengths across multiple organizations and sectors, including the private sector.

### People: Improving Economic Outcomes for People With Low Incomes

Improving economic outcomes for people with low incomes involves the expansion of skills and assets at the “person level,” such as job training, savings programs, and youth development. These approaches are designed to improve household financial health, which in turn positively affects physical and mental health, labor force attachment, and educational attainment. For example, children’s savings accounts—often implemented through partnerships involving the public, private, and nonprofit sectors—are long-term savings accounts that help families with low incomes build savings for postsecondary education. Even small amounts of savings can affect a child’s life trajectory. Children who live in families with low- and moderate-level incomes and have savings designated for college (even less than $500) are three times more likely to enroll in and four times more likely to graduate from postsecondary school or from a certificate program than children with no savings account. Another approach is the bundling of multiple services into a single program, such as Financial Opportunity Centers (FOCs), which integrate job training for workers with low incomes with financial coaching and connections to income supports. FOCs provide employment counseling, one-on-one financial coaching, and low-cost financial products that help build credit, savings, and assets. FOCs also connect clients to food assistance, utilities assistance, and affordable health insurance. Compared with people in programs offering employment assistance alone, members of FOCs are more likely to be employed year-round, reduce consumer debt, and build positive credit histories.

Children’s savings accounts, FOCs, and other services are not structured to provide financial returns to investors, and thus rely heavily on grant funding. One exception is “social enterprise,” which is a business model that generates revenue while fulfilling a social mission. (Social enterprise is described fully in Chapter 5.) A growing movement in the community development field seeks to expand the availability of capital beyond grant funding for strategies that improve person-based outcomes. This shift toward “outcomes-based financing” aims to help coordinate the financial interests of multiple stakeholders into integrated interventions that focus on the whole person, recognizing that “[o]utcomes arise from complex interactions that can never be under the control of any one organization.” Businesses can participate in these efforts by providing grants and capital for loans that generate a return while producing an outcome.

### Place: Fostering Investment in Low-Income Neighborhoods

Increasing investment and resources in a specific neighborhood generally includes improvements to the built environment or the physical structures and amenities present within a community, and involves real estate development projects—such as affordable housing, health clinics, charter schools, or community centers—that are designed to serve people with low incomes. Funding for these projects is scarce and requires community developers to form diverse partnerships across the public, private, and nonprofit sectors. The project developer, often a nonprofit CDC, works with a financial institution, typically a CDFI, to layer multiple sources of debt and equity financing into a single structure known as the “capital stack” (Figure 4.4). Each layer in the stack reflects a different type of capital that assumes a different level of risk and return. As a helpful conceptual framework, the capital stack lays out how different partners with different incentives and levels of risk tolerance can be brought into a shared purpose, ultimately for the benefit of low-income communities. CDFIs often pool capital from a range of partners into a single loan fund that invests in multiple projects, “providing the nimble, patient [i.e., long-term] financing” that is especially crucial in the early stages of development (Box 4.4).

Figure 4.4 Example of a capital stack

Notes: This example of a capital stack depicts the totality of capital invested in a project. The most risk is at the top, and the least risk is at the bottom, with higher positions in the stack expecting higher returns. CDFIs = community development financial institutions; MRIs = mission-related investments; PRIs = program-related investments.

Example might include 10% equity; 20% public and quasi-public capital (first tier capital); 30% philanthropic capital, such as mission-related investments and program-related investments (second and third tier capital); and 40% banks and CDFIs (senior capital).

Investing to ensure an adequate supply of quality affordable homes in residential neighborhoods with access to businesses and employment is critical to building healthy and well employees, families, and communities. Historically, businesses and residential neighborhoods have developed in tandem, simply because employers need access to a stable labor pool, and workers need access to their jobsites. When the local housing market changes and employees can no longer afford to live near employers, both the community and the businesses suffer (Box 4.5).

BOX 4.4 EXAMPLES OF CAPITAL POOLING

■ Local Initiatives Support Corporation (LISC) partnered with Morgan Stanley and The Kresge Foundation to create the $200-million Healthy Futures Fund (HFF). The Fund supports financing of community health centers and affordable housing in underserved areas. HFF combines tax credit equity, loan guarantees, debt, and grants into a single fund that finances a variety of projects. So Others Might Eat (SOME), a nonprofit community development corporation, accessed funds from HFF to develop the Conway Center in Washington, DC, which serves formerly homeless families with affordable housing, a health center, and job training—all adjacent to a transit station.
■ Enterprise Community Partners worked with a range of public, private, and philanthropic partners to launch the Denver Regional Transit-Oriented Development Fund. The fund provides financing to create and preserve affordable housing along transit corridors in the Denver area, helping to ensure that residents with lower incomes have access to transit for employment opportunities across the region. To date, the fund has made 16 loans, which have created or preserved more than 1,300 affordable apartments, a new public library, and more than 100,000 square feet of commercial and nonprofit space—all near public transit.
■ Public transit and family-friendly communal spaces, such as libraries, are essential ingredients of thriving, high-opportunity neighborhoods that foster economic mobility.
■ Partnership for the Bay’s Future: A High-Impact Model for Investment (see Exemplar).

BOX 4.5 IMPACT OF HIGH COST OF HOUSING ON BUSINESSES AND EMPLOYEES

In a survey of employers in the Greater Boston area, nearly half of the respondents said they had failed to recruit or retain employees because of the high cost of local housing. About 40% said they had to increase salaries or benefits to account for rising housing costs.

In another survey of employers, nearly three-quarters of 14 major employers representing 200,000 jobs in Los Angeles affirmed that they face challenges retaining workers because of high housing costs, and most employers said that more than one-quarter of their workers faced one-way commutes of at least 45 minutes. These employers cited certain categories of employees—including single-earner families, part-time and lower wage workers, and those planning to buy a home—as being particularly vulnerable to the lack of quality affordable homes in the local housing market.

This presents an opportunity for local companies. A variety of businesses can step into this breach by investing in their own neighborhoods to tackle specific housing and health priorities that affect their communities. To facilitate these investments, emerging creative funding models layer public and philanthropic dollars with for-profit and mission-driven investments at various rates of return. Fine-tuning a fund’s capital stack (Figure 4.4) enables local companies to attract more capital and to deploy those resources in ways that adjust flexibly to current needs.

### A Caution: Improving Neighborhoods While Preserving Affordability

Investing in or adding amenities to historically disinvested neighborhoods can offer valuable benefits to residents. Improvements, however, raise the risk of gentrification, a process of neighborhood change that includes economic shifts, such as real estate investment and new residents with higher incomes moving in, as well as demographic shifts, such as changes in the racial composition and education level of residents. Gentrification results in the involuntary displacement of long-time residents, particularly people with low incomes and people of color, who cannot afford to stay and do not benefit from new investments into the area. The newly developed “606” recreational trail in Chicago is an example. Here, a historically low-income neighborhood sits on the west side of the trail, but within 3 years of breaking ground on the linear park, home prices in the neighborhood increased 48%, more than double the rate for the entire city. Local community development groups, such as Latin United Community Housing Association, are responding to the housing market pressures by working with partners to add to the stock of new affordable housing units and advocating for city ordinances to increase funding for affordable housing.

The availability of affordable housing is critical to preventing displacement. The community development field is deeply engaged in affordable housing strategies to address displacement through an approach widely referred to as the “Three P’s”:

■ Protection for current tenants, such as policies related to rent control and evictions;
■ Preservation of existing affordable units (e.g., a nonprofit could acquire and rehabilitate an older apartment building to take it off the speculative market and keep rents permanently affordable); and
■ Production of new affordable units, such as a new LIHTC development that would add rent-restricted affordable units to the existing stock of housing.

Preventing displacement due to gentrification requires proactive policies, innovative development practices, and deep community engagement and empowerment. Community partners need to plan and take preventive measures to preserve affordability well before gentrification begins.

Early strategies for promoting affordability can include coalition building, community land trusts, and inclusionary zoning policies. Such strategies as employer-assisted housing programs and affordable housing trust funds can also help communities in later stages of gentrification. Groups like EBALDC also provide a model for community development that aims to ensure affordable housing while preventing displacement.

## Looking to the Future

From its origins in the federal War on Poverty in the 1960s, to its modern multisector networked approach, the community development field has evolved as a mature industry that is highly skilled in connecting low-income communities to the capital and resources necessary for expanding economic opportunities. However, despite the sizeable investments that flow through public and private channels, the current scale of the field is not sufficient to address the many complex causes of poverty and the negative impacts on health, wealth, and well-being.

Addressing poverty is in the direct interest of many more stakeholders beyond community development, including government, businesses and business owners, educators, and healthcare providers and payers. The challenges ahead require rigorously pursuing a new business model that more closely aligns the financial interests of those who stand to benefit from a healthier, more productive population with the capacities of those who create the conditions that promote human flourishing. A wide range of actors across all sectors must be committed to increasing the productive capacity of every person in the United States—that begins with robust and strategic investments in community health and economic prosperity. Our shared future as a nation depends on it.

APPENDIX A TOOLS AND RESOURCES

Appendix A identifies tools and resources addressing topics explored in Chapter 4. The tools and resources were created by such businesses and organizations as Bank of America, The Brookings Institution, Opportunity Finance Network, U.S. Department of the Treasury, and others.

## REINVESTMENT FUND: A CDFI Uses Data to Expand Food Retail in Ohio

| Community Challenge \| Despite gains over the past decade, limited access to healthy food continues to affect residents of urban and rural communities across the United States. Reinvestment Fund’s Limited Supermarket Access (LSA) analysis estimates that 17.6 million people live in communities without easy access to healthy, nutritious food options. This analysis goes beyond simply identifying areas with limited access; it also measures the extent to which LSA areas can support new or expanded food retail.
| Scenario \| Dayton, Ohio, ranks in the worst quartile of cities in the nation for rates of food hardship in households with children. The Salem Avenue corridor in Dayton is an LSA area with limited healthy food access. Approximately one-third of households in this area receive benefits from the Supplemental Nutrition Assistance Program. The neighborhood has several dollar stores and only two grocery stores—neither of which serves the community adequately. Market analysis reveals that the area is “understored” with less grocery square footage than the Ohio and national averages. As a result, residents spend their grocery dollars in pharmacies, convenience stores, and dollar stores in the local area, or they are travelling to suburban areas to shop at larger stores, like Aldi and Meijer.
| Action Taken \| Since 2015, members of the Dayton community have worked to improve local access to food. They started with a community needs assessment, which resulted in a steering committee led by community residents. Thanks to their work, the community is opening a worker- and member-owned grocery store. The Gem City Market will be a full-service store focusing on affordable products and will also include a teaching kitchen, space for nutrition classes and wellness programming, a mini-clinic, cafe, and community room. The project brings together Greater Dayton Union Cooperative Initiative; Miami Valley Community Action Partnership, a long-standing nonprofit in the region; and Greater Dayton Premier Management, an arm of the Dayton city government. Reinvestment Fund, along with Dayton Regional New Markets Tax Credit Fund and PNC Bank, are providing financing for the project.; The store will be open to everyone; shoppers do not need to have a membership. The cooperative is designed to serve its community with traditional grocery products; discounted pricing for consumer-owners with lower incomes; and an employee equity program. Residents with low incomes can become consumer-owners at discounted rates. More than 2,400 Daytonians have already purchased memberships. Gem City Market will also be owned by its employees, improving the (a) quality of the work above industry standards and (b) outcomes for the store by educating employees in business finance and operations and giving them an equity stake.
| Key Takeaway \| Aside from data, community need and support are critical to driving investment and developing viable solutions. Although business engagement can be critical to success, sometimes the solution is just creating a business.