# CHAPTER 3 The Meaning, Purpose, and Opportunity of Business in 21st Century America

## OVERVIEW

Perceptions and expectations of businesses in America constantly evolve. This chapter explores new opportunities for engagement by business in society. Theories of management that address societal issues are examined throughout the chapter, which lists five actions that businesses can take to begin to support healthier communities.

KEY TAKEAWAYS

➤ Business is a force for good in American society and around the world. Business and society are mutually dependent and best thrive together.
➤ The growth in transparency, the increase in interdependence and mutuality, and the public’s attention to values pose potential threats and opportunities to a business’s reputation, brand, and long-term success.
➤ Businesses are looking harder at these threats and opportunities and increasingly choosing to align business values, policies, investments, and actions with the expectations of consumers and the public.
➤ Stakeholder theory provides a framework for this alignment. According to stakeholder theory, businesses exist to create value for the groups who make the business “a going concern”—that is, groups that are part of the cooperative scheme that allows a firm to come into being and to be successful over time.
➤ Stakeholder firms are those that have implemented the principles of stakeholder theory. These firms tend to achieve better business outcomes, including greater innovation and higher profits.

## Introduction

Business has been, on balance, a force for good in American society and around the world. Business produces wealth, creates value, provides jobs, pays taxes, offers goods and services, and brings innovation to the marketplace. Business in the United States also reflects American values. To succeed, business depends on the rule of law; respect for individual and property rights; and a government that enforces the law, builds and maintains infrastructure, and strengthens and defends the common good. Of particular importance for business are property rights, the freedom of individuals to negotiate the terms of doing business, and the understanding that a government’s regulation of commerce is limited and fair. Business also encapsulates a uniquely American idea of the “self-made” individual in a “land of opportunity” who rises from humble beginnings through hard work, new ideas, and good business sense to become a prosperous and generous citizen. In short, the story of business in the United States is about more than just wealth—it embodies and perpetuates values that form the core of the American identity.

“[W]hat improves the circumstances of the greater part can never be regarded as an inconveniency to the whole. No society can surely be flourishing and happy, of which the far greater part of the members are poor and miserable.”

—Adam Smith

The story of business in the United States is about more than just wealth—it embodies and perpetuates values that form the core of the American identity.

At the same time, the role of business in society can be contentious. Some business practices have caused (and continue to cause) harm to both business and society, as harmful products are brought to market, and damaging production processes contaminate air, land, and water and harm the environment. The interdependence between business and society has not been fully recognized or embraced. Today, the United States is emerging from several decades during which, for some business leaders, the priority principle for corporations was “shareholder primacy.” This principle asserts that the core—and perhaps sole—responsibility of business is to maximize profits for shareholders.

Increases in returns to shareholders have not been the rising tide to lift all boats, as once expected. From the 1970s to the early 21st century, income inequality increased in the United States as real incomes for employees stagnated. Some of these trends were facilitated by (or occurred despite) government regulation or deregulation. For example, Fortin and Lemieux analyzed the role of three systemic changes—the decline in the real value of the minimum wage, deunionization, and economic deregulation—on the rise in wage inequality in the United States during the 1980s. They found that about one-third of the increase in wage inequality (for both men and women) can be traced to these system-level changes. These kinds of developments in the United States, along with the widening gap in pay between company leaders and managers and lower-level workers, have caused people to question business-as-usual. In turn, corporations have begun to respond to inside questions and outside pressures and to recognize that their success also depends on engaging all those upon whom the company’s success depends, measuring their quarterly earnings and financial risk and also their impact on society.

“[T]here is one and only one social responsibility of business—to use its resources and engage in activities designed to increase its profits so long as it stays within the rules of the game, which is to say, engages in open and free competition without deception or fraud”

—Milton Friedman

A “reversal of fortune” among working Americans is one of many factors at play in the current shift of attitudes and expectations toward corporations in society. The reversal of fortune refers to the adversities—such as a diminished quality of life, environmental impact, and poor health—that are changing the way people think about business and companies think about conducting business in the 21st century. Many businesses have begun to reevaluate their role in society and see opportunities in becoming partners in creating healthy, inclusive, and prosperous communities. Many U.S. communities are facing threats to their health (as described in Chapters 1 and 2) and future from addiction, loneliness, chronic illness, incarceration, gun violence, and more. In public health terms, these issues stem from the fact that for many people living in America today, vital conditions—like housing, education, income, and transportation—are not being met (Box 1.1a, Box 1.1b, and Box 3.1), for example, in low-opportunity neighborhoods (as described in Chapter 2). While some Americans have never been wealthier and healthier, others live in distressed communities with little opportunity and feel a loss of hope when they look toward the future. As depicted in Figure 3.1, the gap in wealth between high-, middle-, and low-income families has increased substantially since the 1980s.

Many businesses have begun to reevaluate their role in society and see opportunities in becoming partners in creating healthy, inclusive, and prosperous communities.

BOX 3.1 THE SEVEN VITAL CONDITIONS

1. Basic requirements for health and safety
2. Continuous learning, education, and literacy
3. Rewarding work, careers, and standards of living
4. Humane, consistent housing
5. Thriving environment
6. Reliable, safe, and accessible transportation
7. Belonging and civic muscle (also see Chapter 1, Box 1.1)

More recently, the recognition that business and society are mutually dependent and best thrive together has generated new ideas about the meaning, purpose, and responsibility of business. Ideas such as conscious capitalism, creative capitalism, stakeholder capitalism, capitalism 2.0, corporate social responsibility, shared value, community investing, and social entrepreneurship have increased expectations—on the part of businesses, investors, consumers, and employees, among others—that businesses will “do well by doing good.” Both scholarly and practical voices have encouraged mutualism between businesses and the communities in which they operate.

Figure 3.1 Gaps in wealth among upper, middle, and lower income families

Note: Families were assigned to income tiers based on their size-adjusted incomes.

The median family wealth (in 2018 dollars) increased from 1983 to 2001 across three levels of income. In 1983, the median family wealth was $12,300 for lower income families, $102,000 for middle income families, and $344,100 for upper income families. And in 2001, the median family wealth was $20,600 for lower income families, $144,600 for middle income families, and $636,000 for upper income families. However, when compared with 2001, median family income decreased in 2016 to $11,300 for lower income families and to $115,200 for middle income families, but in 2016, the median family income increased, compared with 2001, to $848,400 for upper income families. Overall, from 1983 to 2016, the percentage of U.S. aggregate family wealth decreased slightly for lower income families, from 7% to 4%; decreased significantly for middle income families, from 32% to 17%; and increased dramatically for upper income families, from 60% to 79%.

In addition, businesses are being asked to take responsibility for the consequences of their actions and to engage valuable stakeholders in their communities, all while maximizing value for the various stakeholders they serve. These multiple stakeholders include customers and consumers, employees and contractors, vendors and suppliers, neighborhoods and communities, and shareholders and investors. The new expectations have grown out of the recognition of the interdependence between business and society, and a greater availability of information on how businesses operate in the United States and abroad. Consumers and the public have unprecedented access to information about working conditions, hiring practices, environmental impacts, salary and wage structures, and much more. Especially after the global financial crisis of 2008, and particularly among younger consumers and employees, there is a growing focus on values and purpose in business. Business has almost always been about purpose, but consumers, employees, and the public now are more likely to demand that the values of business align with their own values, and based on that alignment will make decisions about the companies they buy from, work for, and invest in. Employees, consumers, and the public are asking businesses to take into account the best interests of a variety of stakeholders and to create value for society as well as for business.

“Companies that fulfill their purpose and responsibilities to stakeholders reap rewards over the long-term. Companies that ignore them stumble and fail. This dynamic is becoming increasingly apparent as the public holds companies to more exacting standards. And it will continue to accelerate as millennials—who today represent 35 percent of the workforce—express new expectations of the companies they work for, buy from, and invest in.”

—Larry Fink

## The American Narrative on Business

Americans have a complex relationship with business and offer several critiques. First, they have long accused businesses of practicing greed. As the narrative goes, some business leaders think only about how their choices benefit themselves (i.e., their financial self-interest) and disregard any harm passed on to others or society. These businesses fail to recognize their dependence on society and its goods and services (such as educated employees, consumers with disposable incomes, and legal systems and protections). Americans have deep reservations about the size, scope, and influence of large, multi-unit firms. For example, a Gallup poll found a majority (63%) of U.S. adults is dissatisfied with the size and influence of major corporations, consistent with other Gallup findings in recent decades. A different Gallup poll showed that 70% of Americans have “a great deal” or “quite a lot” of confidence in small businesses, compared with 21% having confidence in large businesses. These differences are driven by a sense that leaders of large corporations have outsize influence over political processes, are accumulating greater wealth at the expense of wages, are relatively less accountable to the communities in which they operate, and are less likely to create local jobs.

Business operations are often tied to an array of negative externalities, for example, excessive consumption of resources, pollution, deskilled workers, and the creation of unhealthy levels of dependence on particular products and resources. In places where regulations are weak (e.g., minimal environmental protections), businesses may easily reap rewards while leaving significant harms or costs for communities to bear (e.g., contaminated water or soil) with little or no compensation for the externalities. For some stakeholders, the harms created by a given firm may well outweigh the benefits.

In addition to greed and negative externalities, critiques of business also focus on income inequality and lack of economic opportunity, which have been linked to unencumbered markets and government policies that favor business. Those who have power and resources, according to this critique, are more likely to benefit from successful (and even unsuccessful) businesses, while workers, mid-level managers, and even consumers, the public, and communities benefit less. These troubling trends have prompted many leaders—even strong pro-market leaders, including Jamie Dimon, Warren Buffett, and Larry Fink—to question the sustainability of capitalism, if a more equitable distribution of benefits cannot be implemented. Even those who consider capitalism in the early 21st century to be stronger than ever recognize that the perception (if not the reality) of capitalism in crisis is due to, among other factors, an uneven distribution of gains, with many of the benefits of a thriving capitalism going to the wealthiest individuals.

Equality of economic opportunity is a deeper challenge. Independent of the amount of benefit (or value) produced, a big part of the story of capitalism in the United States is the idea of opportunity—that is, the ability of people to “have a shot,” to improve their lot in life through hard work and creativity, and to become successful regardless of who they are or who they know or where they come from. The core of the American identity is based on social mobility (described in Chapter 2) and economic opportunity. Both are central to the notion of the American dream—that is, the notion that a person does not need to be well-born to have a chance to achieve or get ahead in this country. Although the values that support these sentiments are still alive and well and fueled by real-life success stories, the data increasingly suggest that the American dream is becoming harder to obtain for many Americans. In other wealthy nations, meanwhile, opportunities for economic advancement are greater than they are in the United States.

## Reinventing Business

Amid this shifting context of American society, some businesses are striving to reinvent themselves and redefine their roles in society. The operations of today’s firms, industries, and entire economies differ notably from those of the past. Three emerging dynamics are largely responsible for changes in the way companies operate their businesses: the growth of transparency, the increase in interdependence, and the focus on values.

First, people in today’s world have unprecedented and instant access to information from around the globe. Online rating systems, consumer-produced videos, and anonymous blog posts have helped to create an environment that makes it difficult for firms to shield activities from consumers, employees, competitors, and the public—even in widely dispersed operations. Access extends to the practices in which businesses engage and the partners that they choose—even in operations conducted in remote parts of the world (e.g., use of child labor, corrupt practices, or environmental damage). In past decades, such practices would become public knowledge mainly through investigations by the media. But with the high-level of transparency in today’s environment, these practices are being reported by people with firsthand knowledge. The rise of transparency has forced companies to be ready to face scrutiny—both at home and worldwide—for their practices and to feel the pressure of accountability.

Second, the recognition of interdependence and mutuality between business and society has increased with increasing healthcare costs, rising rates of obesity and addiction, and most graphically, with the coronavirus pandemic of 2020 that kept workers and customers at home and shuttered many businesses. Two similar themes are emerging in this context: (a) the recognition that the success of a business depends on the success of its stakeholders; and (b) the understanding that when the rewards of an enterprise are distributed among its participants, the enterprise is more likely to be compelling to those participants. This positive reciprocity increases the likelihood that the firm will be successful over time. Interdependence may be a simple relationship—a business creates a job, an employee produces value, and a consumer pays for that value. The recognition of the interdependence leads the company to share the profit when the employee produces exemplary value that consumers reward with purchases and loyalty. Mutuality is more purposeful and intentional and includes the creation of shared value and lasting benefits for those engaged. For example, a company chooses to locate in a particular community and create value for local residents (such as jobs, quality childcare, apprenticeships, and employment pathway programs). Local residents then reward the company with productivity and loyalty, allowing the company to efficiently produce a quality product and earn a robust profit (see Exemplar about Greyston Bakery). Interdependence and mutuality emphasize the relationship between business and society and encourage that relationship to be deeper and richer for the benefit of both society and business.

Third, consumers (and employees) are attentive to the values of a business, as discussed previously. Although ethics have always been integral to the operation of markets, people are becoming more concerned with how a company’s values align with their own values. Based on current estimates, $1 of every $5 invested in equity markets undergoes some kind of values vetting, and interest in this kind of vetting is growing rapidly. Businesses have always been concerned about reputation and protective of their brands. Transparency, interdependence and mutuality, and values each pose potential threats and opportunities to a business’s reputation and brand. Businesses are looking harder at these threats and opportunities and increasingly choosing to align values, policies, investments, and actions with the expectations of consumers and the public, while also solving business problems and meeting the needs of multiple stakeholders. Stakeholder theory provides a framework for understanding and implementing business strategies to effectively serve these needs.

### Stakeholder Theory and Practice

New models of capitalism, particularly stakeholder theory, are taking hold that better fit today’s trends and expectations of workers, consumers, and members of the public. These approaches support a richer notion of how business relates to stakeholders, including communities.

The concept of stakeholders in business emerged in the 1960s and 1970s and gained prominence in the 1980s and 1990s following initial publication in 1984 of Strategic Management: A Stakeholder Approach by R. Edward Freeman. Stakeholder theory argues that businesses will be in a stronger position to succeed if they take into account the needs and perspectives of all stakeholders, not only shareholders (who are one of several stakeholders). Just how many businesses and corporations adhere to a stakeholder approach is unknown. But extensive scholarship has been dedicated to understanding the business impact of engaging multiple stakeholders, and countless tools and resources have been developed to help businesses identify stakeholders and implement stakeholder engagement strategies. Even state legislatures took notice of stakeholder theory in the mid-1980s. Thirty-four states have enacted so-called “constituency” laws that explicitly give standing to core stakeholders (beyond shareholders) in important board-level business governance decisions.

Stakeholder theory begins with a simple premise: Businesses exist to create value for the groups who make the firm a “going concern”—that is, groups that are part of the cooperative scheme that allows a firm to come into being and be successful over time. In this view, core stakeholders include customers, suppliers, employees, the local community, and shareholders. Without the support and involvement of these stakeholders, the firm would not exist, and unless these stakeholders cooperate consistently and well, chances are the firm will not perform optimally. In return for their choice to engage with the firm, the company actively works to create value for each stakeholder, while simultaneously making all stakeholders better off.

Stakeholder theory begins with a simple premise: Businesses exist to create value for the groups who make the firm a “going concern”—that is, groups that are part of the cooperative scheme that allows a firm to come into being and be successful over time. In this view, core stakeholders include customers, suppliers, employees, the local community, and shareholders. Without the support and involvement of these stakeholders, the firm would not exist, and unless these stakeholders cooperate consistently and well, chances are the firm will not perform optimally. In return for their choice to engage with the firm, the company actively works to create value for each stakeholder, while simultaneously making all stakeholders better off.

Profits (and shareholder returns for publicly traded companies) are vital to business success, and most businesses begin with a purpose beyond just making money. Stakeholder firms also have an animating purpose, something noble and inspiring that is essential to the form of value they create. This commitment to a purpose and to creating value for each stakeholder, the theory holds, makes stakeholder firms more successful and sustainable over time. A small but growing number of studies has demonstrated that firms that consistently implement a stakeholder approach tend to achieve better outcomes, including greater innovation and higher profits over time.

“The 18 publicly traded companies out of the 28 [identified as the “most conscious” based on stated purpose, generosity of compensation, quality of customer service, investment in their communities, and impact on the environment] outperformed the S&P 500 index by a factor of 10.5 over the years 1996–2011. And why … should that be a surprise? Conscious companies treat their stakeholders better. As a consequence, their suppliers are happier to do business with them. Employees are more engaged, productive, and likely to stay. These companies are more welcome in their communities and their customers are more satisfied and loyal. The most conscious companies give more, and they get more in return. The inescapable conclusion: it pays to care, widely and deeply.”

—Tony Schwartz

In addition to financial rewards and stronger relationships with stakeholders, adopting a stakeholder approach offers potential benefits in the realm of trust, reciprocity, and understanding. For example, moral psychology research suggests that the logic of stakeholder theory helps to avoid many of the traps that are common to an exclusive focus on profits. For instance, although many people would like more money and more goods, most people care about fairness. Stakeholders who are treated fairly by a business are more likely to reciprocate. This dynamic is known as positive reciprocity, and when this dynamic is created across a firm and within stakeholder groups, it can create a virtuous cycle of benefits for business and society. Stakeholders can stop worrying about being taken advantage of and instead act in ways that make the firm and fellow stakeholders better off. On the other hand, the dynamic of negative reciprocity can deeply strain and erode the relationship between stakeholders and a firm. It can turn customers and suppliers away, for example, and prompt employees to underperform. A stakeholder approach helps firms to foster positive reciprocity and avoid negative reciprocity.

Firms are increasingly practicing stakeholder theory. They are

■ Recognizing primary stakeholder interests as joint and (mostly) aligned with business interests;
■ Emphasizing a purpose beyond (only) profits, while still caring about financial returns, and
■ Investing in stakeholder relationships (e.g., with suppliers, employees, customers, and the local community) with an eye toward strengthening business returns.

A few firms that have embraced this approach (or at least adopted the language and logic of stakeholder theory) include Costco, Eastman Chemical, Google, Salesforce, Starbucks, Unilever, Vanguard, and others. Each of these companies has implemented specific management strategies and practices aligned with the practice of stakeholder theory.

Stakeholders who are treated fairly by a business are more likely to reciprocate.

Stakeholder theory offers a constructive view of business, a way of understanding and operating a business as an institution that exists to serve multiple groups in society and to create value for people and communities. Stakeholders are interdependent, and firms create value through dynamic cooperation with and among these groups. To be successful over time, businesses must nurture these relationships and find ways to create new forms of value so that all stakeholders in the value chain are better off. If this happens, stakeholders will choose to engage with the firm and work to see it succeed. Thus, the theory holds, while firms must care about profits and shareholders to succeed and thrive, they also should serve a larger purpose and recognize that the very foundation of their profits is the stakeholder relationships that enable businesses to generate value for society and for themselves.

In practice, the many stakeholders of a business, including shareholders, may not have the same interests (shareholders are stakeholders but not all stakeholders are shareholders; many companies have no shareholders).^6^ Depending on the business, some interests of employees, customers, suppliers, and communities may align and some other interests may compete. The challenge for the business is to avoid tradeoffs among stakeholders and deploy strategies that keep all stakeholders engaged. While employees and suppliers (and sometime customers) may be tied to particular communities, shareholders tend to be physically, geographically, and socially separated from the needs and challenges of particular communities where businesses operate. Part of the challenge in getting those two entities to cooperate is being able to explain to shareholders how investments in communities are critical for making sure that the business can operate and thrive in the long term, even if the investment may not yield the best return on a stock price in the short term. More and more companies are taking this long-term view (Box 3.2), which was also encouraged in Business Roundtable’s revised statement on the purpose of a corporation.

6 Stakeholder theory applies primarily to publicly traded corporations, as a management strategy. But the theory also applies to any type of business or other organization, including government.

BOX 3.2 SODEXO’S STAKEHOLDER APPROACH

Since its founding in 1966, Sodexo has sought to create value for its multiple stakeholders, including customers, clients, employees, suppliers, communities, and shareholders. From its food services operations that serve private corporations, hospitals, healthcare facilities, schools, colleges and universities, senior living communities, sports and leisure venues, and government agencies to its facilities management, benefit and rewards, and home care operations, Sodexo strives to create value for all of its stakeholders and integrate actions that support health and wellbeing into the core of its business operations.

With its Better Tomorrow 2025 initiative, Sodexo considers environmental, social, and economic impacts as it establishes and implements its business goals, ensuring that Sodexo’s growth benefits:

■ Employees who work hard every day,
■ Clients and suppliers who seek relationships based on shared value,
■ Shareholders who want sustained long-term growth, and
■ Tens of millions of people served by Sodexo everyday—that is, people who hold the business accountable for having a positive impact on the community.

Sodexo uses data to determine where to focus its efforts and to measure results. Sodexo has had public, measurable, and audited corporate responsibility goals since 2009.

Here are two examples of how Sodexo strives to offer healthy and nourishing lifestyle choices to every one of its consumers every day:

■ In collaboration with the Partnership for a Healthier America, Sodexo implements Mindful by Sodexo, a healthy dining program, in 95% of its food service accounts, expanding healthier food choices in at least 25% of its hospitals, offering 17 million more free breakfast meals in primary and secondary schools, and increasing the selection of healthier, more nutritious options in its vending and K–12 lunch programs.
■ Sodexo offers healthier children’s meals at 40% of its food service accounts with American cultural destinations, such as aquariums, museums, ballparks, and other recreational facilities.

Sodexo also aims to source responsibly and provide management solutions that reduce its carbon emissions. The company focuses on four environmental actions: preventing food waste, promoting plant-based meal options, sourcing responsibly through local and short supply chains; and helping clients to reduce their emissions through better energy and waste management, for example:

■ Nearly all Sodexo site managers, chefs, and kitchen staff implement initiatives to cut food waste. Sodexo’s WasteWatch powered by Leanpath Program tracks food waste, monitors performance, and takes actions to drive reductions. The program captures data on daily food waste and measures pre- and post-consumer waste. In 2019, Sodexo avoided 584 tons of food waste at its sites, the equivalent of 3,689 metric tons of carbon dioxide.
■ Sodexo is committed to increasing food purchased in its clients’ communities from local producers and small businesses, contractually requiring its produce vendor partners to source local and seasonal foods whenever possible. Sodexo purchases more than 4 million gallons of locally sourced milk each year. In 2019, Sodexo spent $1 billion with small- and medium-sized enterprises in the United States.

For Sodexo, growing responsibly is about pursuing and tracking what it can do better, safer, healthier, and more sustainably for people and planet. It’s about how Sodexo can improve as a corporate citizen, meeting the needs of and creating value for all its stakeholders.

## Ties to Community Health, Wealth, and Well-Being

Challenging a simplistic, shareholder-centric view of business and adopting a stakeholder approach has important implications for community health, wealth, and well-being. Two themes make the connection: (1) creating value for stakeholders and (2) the interdependence and mutuality between business and society, including the interdependence among various stakeholders (including shareholders) and between each stakeholder and the business.

Stakeholders are people with a variety of needs, including access to clean air and water, nutritious food, safe work places and communities, green spaces, family-sustaining careers, education, and economic opportunity—all vital conditions (described in Chapter 1) that shape health, wealth, and well-being. Businesses investing in their employees, suppliers, and communities are already adding value in the form of jobs, income, health insurance (often), and goods and services of use to community members. Stakeholder firms demonstrate that businesses can go further (and get even more in return). Subsequent chapters in this report (Chapters 4 and 5) describe a variety of investments and strategies that businesses can deploy and of ways to partner to help solve some of the pressing community challenges that detract from health, wealth, and well-being—such as poverty, lack of education, lack of affordable housing, income inequality, and lack of economic opportunity. As businesses partner to raise the level of well-being in a community, they create greater business opportunities for themselves and more stakeholders to bring value to the business.

As businesses partner to raise the level of well-being in a community, they create greater business opportunities for themselves and more stakeholders to bring value to the business.

Moreover, stakeholders and businesses are interdependent and linked together in a larger ecosystem. Where people are healthy and the vital conditions for health are present, businesses have an easier time finding employees who will be productive, miss fewer days of work due to illness, and do more to contribute to the firm. Businesses in this environment also tend to find customers who are more likely to buy their products and investors who are more likely to want to buy their stock.

## The Role of Business in Well-Being

Opportunities for businesses to join in creating thriving communities can be divided into three areas: (1) the well-being of people (employee and dependent benefits, workplace policies and environment, customer well-being), (2) the well-being of places (vital conditions of a community, access to opportunity, broader community systems), and (3) equity, ensuring resources are focused on those most in need and everyone has the opportunity to thrive.

Investing in the well-being of employees has long been the purview of business. From providing safe working conditions, health insurance coverage, and paid sick leave to offering workplace health promotion, wellness or well-being programs, family-sustaining compensation, paid maternity leave, and profit sharing, companies that offer these conditions and benefits have seen the value of investing in employees and their dependents. Businesses can continue to strive to ensure these conditions and benefits are met for all employees and dependents.

Companies investing in place is less common and occurs most often in communities in which company headquarters are located (see Perspectives From Business Leaders). Companies may establish partnerships to create pathways to employment; build physical infrastructure, including green spaces and grocery stores; and invest in quality education. Companies can continue to make these kinds of improvements and expand opportunities in the communities they serve.

The most advanced businesses invest in people and place with an eye toward improving the lives of those who are not thriving and creating conditions for all people to prosper by adding customized supports for those who are least likely to thrive. Such investments have the potential to improve the health, wealth, and well-being of employees, families and consumers, and future employees and consumers. Some companies are tackling health, wealth, and well-being more broadly—in the context of (a) people in the wider community they may not directly touch and (b) the vital conditions required for all people to thrive in the places in which businesses operate or serve (see, for example, the Exemplar about Reinvestment Fund’s Gem City Market).

These roles are aligned with the purpose and meaning of business. Businesses exist to

■ Create sustained, long-term value for all stakeholders;
■ Fulfill a larger purpose as a means of making money;
■ Recognize the interdependencies between themselves and stakeholders; and
■ Seek ways to contribute positively to communities and stakeholders.

Firms take these actions because they help the business succeed, consumers expect them to, and it is the right thing to do. Stakeholder firms see the connection between community health, wealth, and well-being and their own prosperity over time. They also seek ways to improve community health, especially where it is most clearly linked to their stakeholders and the prosperity of the firm.

APPENDIX A TOOLS AND RESOURCES

Appendix A identifies tools and resources addressing topics explored in Chapter 3. The tools and resources were created by such businesses and organizations as DePaul University, Fisher Investments, U.S. Department of Housing and Urban Development, and others.

## HYATT HOTELS CORPORATION: An Opportunity Partnership

| Community Challenge \| Even before the coronavirus pandemic devastated the global economy in 2020, a high percentage of young adults (18- to 24-years of age) who were not in school were jobless. Being jobless at such a young age can set the stage for long-term unemployment or for taking fringe jobs that lack benefits or social security. Some young adults can become economically marginalized for the rest of their lives.
| Scenario \| It started at the top. Mark Hoplamazian, president and chief executive officer of Hyatt Hotels Corporation (Hyatt), saw the issue of young people being left out of the workforce and the economy as a primary driver of the widening skills, income, and wealth gaps. He believes that companies have a responsibility to help address such issues in the communities in which they operate.; Hyatt is a hospitality company that manages hotels and resorts. The company has a clear purpose—to care for people so they can be their best. “Our purpose of care applies to our colleagues, our guests, and our communities,” said Audrey Williams-Lee, senior vice president of Human Resources and Philanthropy. “There is a growing wealth and skills gap, and our [chief executive officer] wanted us to focus on a signature philanthropic cause that both aligned with our values and supported our communities.” Hyatt concluded that addressing the issue of unemployment among young adults who are not in school and not in the workforce (often called “Opportunity Youth”) would accomplish that goal, providing a diverse employment pipeline to spur future growth at Hyatt and to support communities in which Hyatt is located.
| Action Taken \| Williams-Lee and her team conducted research and interviewed community organizations that worked with youth globally. Hyatt worked with Grads of Life to design the RiseHY program. Launched in 2018, the RiseHY program seeks to hire 10,000 young adults by 2025. In its first year, Hyatt and its hotels had hired more than 16% of its 10,000-hirings goal.; To facilitate the RiseHY program, Hyatt focuses on four areas:; ■ Use a majority of the Hyatt Hotels Foundation’s philanthropic giving to fund RiseHY. “We were able to articulate very clearly who we were giving to,” Williams-Lee said. “And why we were supporting certain organizations.”; ■ Develop a network of community organizations focused on training and supporting opportunity youth for job readiness. The hospitality industry has an abundance of entry-level jobs. With such a network in place, Hyatt began to fill those positions with opportunity youth. Hyatt fosters a workplace where young people without prior experience can create a foundation for a life-long career, gain new skills, and advance in the organization.; ■ Use technology to help with hiring. For example, Hyatt uses a gamified tool (in 18 languages) to match the skills of young workers with the skills needed for potential hospitality roles. Hyatt also uses a virtual reality simulation to capture what life is like in a hotel. “This increases the quality of hires we bring into the program,” Williams-Lee said. “And it helps young people who have never been in a hotel understand what it’s like.” To help applicants decide which job to apply for, the simulation describes the different roles and helps candidates understand the responsibilities of each role.; ■ Work with community organizations to identify wraparound services. Such services can support young people when they are placed in a role in the company, and help managers at Hyatt Hotels understand how to help opportunity youth succeed.
| Key Takeaway \| Without a job, and with little hope of finding one, the self-worth of out-of-school teenagers and young adults plummets. A lack of confidence quickly translates to being less employable. In the end, unemployed young adults hurt all communities. But opportunity abounds as businesses (a) become more aware of young adults as a potential talent pipeline and (b) foster roles in their organizations for these workers. Several factors are critical to the success of Hyatt’s RiseHY program, including embracing a cause aligned with its purpose, the nature of the hospitality business, and locating its corporate philanthropy within the human resources department. This critical move ensures that corporate philanthropy and business success are aligned and reinforce each other. Together, these factors create opportunities for synergy between doing well and doing good.